# APPENDIX B EXCLUDED STUDIES

Exclude reasons: 1=Ineligible population, 2=Ineligible exposure, 3=Ineligible comparator, 4=Ineligible outcome, 5=Ineligible timing, 6=Ineligible study design, 7=Ineligible publication type, 8=Outdated or ineligible systematic review, 9=Non-English language, 10=Unable to locate full-text.

Citation | Exclude Reason
Acre A. Self-perceived precipitants of veteran homelessness. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2020;81(2-B):No-Specified. | E10
Amosu OG. Service members’ perspectives on veteran homelessness in Maryland and Virginia. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2022;83(4-B):No-Specified. | E4
Blodgett JC, Avoundjian T, Finlay AK, Prevalence of mental health disorders among justice-involved veterans. Epidemiologic reviews. 2015;37:163–176.25600416 | E8
Brignone E, Fargo JD, Blais RK, Gundlapalli AV. Applying Machine Learning to Linked Administrative and Clinical Data to Enhance the Detection of Homelessness among Vulnerable Veterans. AMIA Annual Symposium proceedings AMIA Symposium. 2018;2018:305–312.30815069 | E4
Brignone E, Fargo JD, Blais RK, Gundlapalli AV. Chronic Health Conditions Among US Veterans Discharged From Military Service for Misconduct. Preventing chronic disease. 2018;15:E122.30316307 | E4
Byrne T, Montgomery AE, Dichter ME. Homelessness among female veterans: A systematic review of the literature. Women & Health. 2013;53(6):572–596.23937730 | E8
Carlson EB, Garvert DW, Macia KS, Ruzek JI, Burling TA. Traumatic stressor exposure and post-traumatic symptoms in homeless veterans. Military Medicine. 2013;178(9):970–973.24005545 | E4
Creech SK, Johnson E, Borgia M, Bourgault C, Redihan S, O’Toole TP. IDENTIFYING MENTAL AND PHYSICAL HEALTH CORRELATES OF HOMELESSNESS AMONG FIRST-TIME AND CHRONICALLY HOMELESS VETERANS. Journal of Community Psychology. 2015;43(5):619–627. | E3
Cusack M, Montgomery AE. Examining the bidirectional association between veteran homelessness and incarceration within the context of permanent supportive housing. Psychol Serv. 2017;14(2):250–256.28481612 | E4
Denkin R. Trauma and posttraumatic stress disorder (PTSD) among a sub-sample of homeless veterans. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2004;64(9-B):4610. | E10
Edwards ER, Barnes S, Govindarajulu U, Geraci J, Tsai J. Mental health and substance use patterns associated with lifetime suicide attempt, incarceration, and homelessness: A latent class analysis of a nationally representative sample of U.S. veterans. Psychological Services. 2021;18(4):619–631.32852993 | E2
Gamache G, Rosenheck R, Tessler R. The proportion of veterans among homeless men: A decade later. Social Psychiatry and Psychiatric Epidemiology: The International Journal for Research in Social and Genetic Epidemiology and Mental Health Services. 2001;36(10):481–485. | E4
Hamilton AB, Poza I, Washington DL. “Homelessness and trauma go hand-in-hand”: Pathways to homelessness among women veterans. Women’s Health Issues. 2011;21(4, Suppl):S203–S209.21724142 | E4
Hilferty F, Katz I, Hooff M, Lawrence-Wood E. How many Australian veterans are homeless? Reporting prevalence findings and method from a national study. Australian Journal of Social Issues (John Wiley & Sons, Inc). 2021;56(1):114–127. | E1
Hines VA. Homelessness: Women veterans’ perspective. Dissertation Abstracts International Section A: Humanities and Social Sciences. 2010;70(9-A):3638. | E10
Jorden BJ. Rural veterans: Pathways to homelessness. Dissertation Abstracts International Section A: Humanities and Social Sciences. 2019;80(1-A(E)):No-Specified. | E4
Keene RE. The meaning of homelessness to homeless women veterans. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2013;73(11-B(E)):No-Specified. | E4
Kuehn BM. Research on homeless vets suggests ways to target services based on risk factors. JAMA. 2013;309(22):2313–2314.23757061 | E7
Macia KS, Blonigen DM, Shaffer PM, Cloitre M, Smelson DA. Trauma-related differences in socio-emotional functioning predict housing and employment outcomes in homeless veterans. Social Science & Medicine. 2021;281:N.PAG-N.PAG. | E10
Marcus SM, Weaver J, Lim S, Duan N, Gibbons RD, Rosenheck R. Assessing the causal effect of Section 8 housing vouchers as the active ingredient for decreasing homelessness in veterans with mental illness. Health services & outcomes research methodology. 2012;12(4):273–287. | E2
Metraux S, Cusack M, Byrne TH, Hunt-Johnson N, True G. Pathways into homelessness among post-9/11-era veterans. Special Issue: Homelessness Among Veterans, Other Adults, and Youth. 2017;14(2):229–237. | E2
Montgomery AE. Understanding the dynamics of homelessness among veterans receiving outpatient care: Lessons learned from universal screening. Annals of the American Academy of Political and Social Science. 2021;693(1):230–243. | E7
Montgomery AE, Fargo JD, Byrne TH. Impact of community investment in safety net services on rates of unsheltered homelessness among veterans. Journal of Sociology and Social Welfare. 2015;42(4):23–36. | E2
Montgomery AE, Fargo JD, Byrne TH, Kane V, Culhane DP. Universal Screening for Homelessness and Risk for Homelessness in the Veterans Health Administration. American Journal of Public Health. 2013;103(S2):S210–211.24148032 | E2
Pavao J, Turchik JA, Hyun JK, Military sexual trauma among homeless veterans. Journal of General Internal Medicine. 2013;28(Suppl 2):S536–S541.23807062 | E4
Pettey WBP, Toth DJA, Redd A, Carter ME, Samore MH, Gundlapalli AV. Using network projections to explore co-incidence and context in large clinical datasets: Application to homelessness among U.S. Veterans. Journal of biomedical informatics. 2016;61:203–213.27041237 | E4
Ramchand R, Rudavsky R, Grant S, Tanielian T, Jaycox L. Prevalence of, risk factors for, and consequences of posttraumatic stress disorder and other mental health problems in military populations deployed to Iraq and Afghanistan. Current psychiatry reports. 2015;17(5):37.25876141 | E8
Rivera-Rivera N, Villarreal AA. Homeless veterans in the Caribbean: Profile and housing failure. Rev Puertorriquena Psicol. 2021;32(1):64–73.35765409 | E4
Rosenheck R, Frisman L, Fontana A, Leda C. Combat exposure and PTSD among homeless veterans of three wars. Posttraumatic stress disorder: Acute and long-term responses to trauma and disaster. 1997:191–207. | E10
Rosenheck R, Leda C, Gallup P. Combat stress, psychosocial adjustment, and service use among homeless Vietnam veterans. Hospital & Community Psychiatry. 1992;43(2):145–149.1572610 | E2
Sundin EC, Baguley T. Prevalence of childhood abuse among people who are homeless in Western countries: A systematic review and meta-analysis. Social Psychiatry and Psychiatric Epidemiology: The International Journal for Research in Social and Genetic Epidemiology and Mental Health Services. 2015;50(2):183–194. | E8
Szymkowiak D, Montgomery AE, Tsai J, O’Toole TP. Frequent Episodic Utilizers of Veterans Health Administration Homeless Programs Use: Background Characteristics and Health Services Use. Journal of public health management and practice : JPHMP. 2022;28(1):E211–E218.33208718 | E4
Tessler R, Rosenheck R, Gamache G. Comparison of Homeless Veterans with Other Homeless Men in a Large Clinical Outreach Program. Psychiatric Quarterly. 2002;73(2):109.12025719 | E4
Tsai J, Pietrzak RH, Szymkowiak D. The Problem of Veteran Homelessness: An Update for the New Decade. American journal of preventive medicine. 2021;60(6):774–780.33583678 | E4
Tsai J, Kasprow WJ, Kane V, Rosenheck RA. National comparison of literally homeless male and female VA service users: Entry characteristics, clinical needs, and service patterns. Women’s Health Issues. 2014;24(1):e29–e35.24342077 | E4
Tsai J, Rosenheck RA. Risk factors for homelessness among US veterans. Epidemiologic reviews. 2015;37:177–195.25595171 | E8
US Department of Veterans Affairs. Homeless incidence and risk factors for becoming homeless in veterans. In: Office of Inspector General Washington, DC; 2012. | E7
van den Berk-Clark C, McGuire J. Elderly Homeless Veterans in Los Angeles: Chronicity and Precipitants of Homelessness. American Journal of Public Health. 2013;103(S2):S232–S238.24148059 | E4