# APPENDIX A SEARCH STRATEGY

## SYSTEMATIC REVIEWS

1. Search for systematic reviews: Among Veterans and other adults, what factors during childhood and adolescence are associated with homelessness during adulthood?; Date Searched: 03-14-2023
A. Bibliographic Databases: | # | Search Statement | Results
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to March 13, 2023 | 1 | Ill-Housed Persons/ or (homeless* or ill-housed or shelterless or unsheltered or unhoused).ti,ab,kf. | 15520
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to March 13, 2023 | 2 | Risk Factors/ or Protective Factors/ or (associat* or caus* or connect* or correlate* or effect* or expos* or factor* or impact* or indicator* or influenc* or lead* or link* or predict* or protective or relat* or risk*).ti,ab,kf. | 20098231
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to March 13, 2023 | 3 | 1 and 2 | 11331
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to March 13, 2023 | 5 | (systematic review.ti. or meta-analysis.pt. or meta-analysis.ti. or systematic literature review.ti. or this systematic review.tw. or pooling project.tw. or (systematic review.ti,ab. and review.pt.) or meta synthesis.ti. or meta-analy*.ti. or integrative review.tw. or integrative research review.tw. or rapid review.tw. or umbrella review.tw. or consensus development conference.pt. or practice guideline.pt. or drug class reviews.ti. or cochrane database syst rev.jn. or acp journal club.jn. or health technol assess.jn. or evid rep technol assess summ.jn. or jbi database system rev implement rep.jn. or (clinical guideline and management).tw. or ((evidence based.ti. or evidence-based medicine/ or best practice*.ti. or evidence synthesis.ti,ab.) and (((review.pt. or diseases category/ or behavior.mp.) and behavior mechanisms/) or therapeutics/ or evaluation studies.pt. or validation studies.pt. or guideline.pt. or pmcbook.mp.)) or (((systematic or systematically).tw. or critical.ti,ab. or study selection.tw. or ((predetermined or inclusion) and criteri*).tw. or exclusion criteri*.tw. or main outcome measures.tw. or standard of care.tw. or standards of care.tw.) and ((survey or surveys).ti,ab. or overview*.tw. or review.ti,ab. or reviews.ti,ab. or search*.tw. or handsearch.tw. or analysis.ti. or critique.ti,ab. or appraisal.tw. or (reduction.tw. and (risk/ or risk.tw.) and (death or recurrence).mp.)) and ((literature or articles or publications or publication or bibliography or bibliographies or published).ti,ab. or pooled data.tw. or unpublished.tw. or citation.tw. or citations.tw. or database.ti,ab. or internet.ti,ab. or textbooks.ti,ab. or references.tw. or scales.tw. or papers.tw. or datasets.tw. or trials.ti,ab. or meta-analy*.tw. or (clinical and studies).ti,ab. or treatment outcome/ or treatment outcome.tw. or pmcbook.mp.))) not (letter or newspaper article).pt. | 572201
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to March 13, 2023 | 6 | 4 and 5 | 462
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to March 13, 2023 | 7 | limit 6 to english language | 452
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to March 13, 2023 | 8 | limit 7 to last 7 years | 331
CDSR: Protocols and Reviews | 1 | MeSH descriptor: [Ill-Housed Persons] this term only | 434
CDSR: Protocols and Reviews | 2 | (homeless* or ill-housed or shelterless or unsheltered or unhoused):ti,ab,kw | 1154
CDSR: Protocols and Reviews | 3 | #1 OR #2 | 1154
CDSR: Protocols and Reviews | 4 | MeSH descriptor: [Risk Factors] this term only | 32657
CDSR: Protocols and Reviews | 5 | MeSH descriptor: [Protective Factors] this term only | 222
CDSR: Protocols and Reviews | 6 | (associat* or caus* or connect* or correlat* or effect* or expos* or factor* or impact* or indicator* or influenc* or lead* or link* or predict* or protective or relat* or risk*):ti,ab,kw | 1531568
CDSR: Protocols and Reviews | 7 | {OR #4-#6} | 1531568
CDSR: Protocols and Reviews | 8 | #3 AND #7 | 1042
CDSR: Protocols and Reviews | 9 | limit #8 to reviews | 13
CDSR: Protocols and Reviews | 10 | limit #9 to English language | 13
Ovid APA PsycInfo 1806 to February Week 4 2023 | 1 | exp Homeless/ or (homeless* or ill-housed or shelterless or unsheltered or unhoused).ti,ab. | 13184
Ovid APA PsycInfo 1806 to February Week 4 2023 | 2 | Risk Factors/ or Protective Factors/ or (associat* or caus* or connect* or correlat* or effect* or expos* or factor* or impact* or indicator* or influenc* or lead* or link* or predict* or protective or relat* or risk*).ti,ab. | 4055329
Ovid APA PsycInfo 1806 to February Week 4 2023 | 3 | 1 and 2 | 10621
Ovid APA PsycInfo 1806 to February Week 4 2023 | 4 | “Systematic Review”/ or Meta Analysis/ or Treatment Guidelines/ or (systematic review or meta-analys* or systematic literature review or meta-synthes* or drug class review* or practice guideline*).ti. or (this systematic review or pooling project or data pooling or integrative review or integrative research review or rapid review or umbrella review or ((inclusion or predetermined or pre-determined or exclusion) adj3 criter*)).tw. or “jbi database of systematic reviews and implementation reports”.jn. | 83183
Ovid APA PsycInfo 1806 to February Week 4 2023 | 5 | 3 and 4 | 230
Ovid APA PsycInfo 1806 to February Week 4 2023 | 6 | limit 5 to English language | 205
EBSCO SocIndex with Full Text | 1 | (DE “Homeless Persons” OR DE “African American Homeless Persons” OR DE “Hispanic American Homeless Persons” OR DE “Homeless Children” OR DE “Homeless Families” OR DE “Homeless Men” OR DE “Homeless Students” OR DE “Homeless Veterans” OR DE “Homeless Women” OR DE “Homeless Youth” OR DE “Native American Homeless Persons” OR DE “Older Homeless Persons” OR DE “Rogues & Vagabonds” OR DE “Tramps” OR DE “Homeless Camps” OR DE “Homeless Shelters” OR DE “Homelessness” OR DE “Squatters”) OR TI (homeless* or ill-housed or shelterless or unsheltered or unhoused) OR AB (homeless* or ill-housed or shelterless or unsheltered or unhoused) | 10314
EBSCO SocIndex with Full Text | 2 | DE “Protective Factors” OR TI (associat* or caus* or connect* or correlat* or effect* or expos* or factor* or impact* or indicator* or influenc* or lead* or link* or predict* or protective or relat* or risk*) OR AB (associat* or caus* or connect* or correlat* or effect* or expos* or factor* or impact* or indicator* or influenc* or lead* or link* or predict* or protective or relat* or risk*) | 1399661
EBSCO SocIndex with Full Text | 3 | S1 AND S2 | 6435
EBSCO SocIndex with Full Text | 4 | TI (“systematic review” or “meta-analysis” or “systematic literature review” or “meta-synthesis” or “drug class review” or “practice guideline” OR “practice guidelines”) OR AB (“this systematic review” or “pooling project” or “data pooling” or “integrative review” or “integrative research review” or “rapid review” or “umbrella review” or ((inclusion or predetermined or pre-determined or exclusion) N3 criter*))) | 8704
EBSCO SocIndex with Full Text | 5 | S3 AND S4 | 66
EBSCO SocIndex with Full Text | 6 | limit 5 to English language | 65

1. Search for current systematic reviews; Date Searched: 03-14-2023
B. Non-bibliographic databases | [underlined: Evidence] | [underlined: Results]
AHRQ: evidence reports, technology assessments, U.S Preventative Services Task Force Evidence Synthesis (https://www.ahrq.gov/research/findings/evidence-based-reports/search.html) | Search: homeless* OR housing OR ill-housed OR shelterless OR unhoused OR unsheltered | 0
CADTH (https://www.cadth.ca/) | Search: homeless* OR ill-housed OR shelterless OR unhoused OR unsheltered | 0
ECRI Institute (https://guidelines.ecri.org/) | Website unavailable. | n/a
HTA: Health Technology Assessments (https://www.ohsu.edu/library) (UP TO 2016) | Search: homeless* OR ill-housed OR shelterless OR unhoused OR unsheltered | 0
NHS Evidence (https://www.nice.org.uk/about/what-we-do/evidence-and-best-practice-resources/evidence-search/evidence-search-service-closure-information) | Search: homeless* OR ill-housed OR shelterless OR unhoused OR unsheltered | 0
EPPI-Centre (http://eppi.ioe.ac.uk/cms/Default.aspx?tabid=62) | Search: homeless* OR ill-housed OR shelterless OR unhoused OR unsheltered | 0
NLM (https://www.ncbi.nlm.nih.gov/books) | Search: (homeless* OR ill-housed OR shelterless OR unhoused OR unsheltered) AND (associat* or caus* or connect* or correlat* or effect* or expos* or factor* or impact* or indicator* or influenc* or lead* or link* or predict* or protective or relat* or risk*); - Who Are the Rural Homeless? (https://www.ncbi.nlm.nih.gov/books/NBK218242/#ddd00166) From Homelessness, Health, and Human Needs; - A Critical Review of the Literature Regarding Homelessness Among Veterans (https://www.ncbi.nlm.nih.gov/books/NBK55705/) | 2
VA Products - VATAP, PBM and HSR&D publications | A http://www.hsrd.research.va.aov/research/default.cfm; - Identifying and Measuring Risk for Homelessness Among Veterans (https://www.hsrd.research.va.gov/research/abstracts.cfm?Project_ID=2141704104); B http://www.research.va.gov/research_topics/; - Risk Factors for Homelessness Among US Veterans (https://pubmed.ncbi.nlm.nih.gov/25595171/); - Military Misconduct and Homelessness Among US Veterans Separated from Active Duty, 2001-2012 (https://pubmed.ncbi.nlm.nih.gov/26305655/); - One-Year Incidence and Predictors of Homelessness Among 300,000 US Veterans Seen in Specialty Mental Health Care (https://pubmed.ncbi.nlm.nih.gov/28481605/); - Differential Risk for Homelessness Among US Male and Female Veterans With a Positive Screen for Military Sexual Trauma (https://pubmed.ncbi.nlm.nih.gov/27096847/); C https://va.dimensions.ai/discover/publication; - Risk and Resilience Factors in Youth Homelessness in Western Countries (https://va.dimensions.ai/auth/base/login?redirect=%2Fdetails%2Fpublication%2Fpub.1140006025%3Fsearch_mode%3Dcontent%26search_text%3Dhomeless%252A%2BAND%2Brisk%252A%2BAND%2Breview%252A%26search_type%3Dkws%26search_field%3Dtext_search%26and_subset_scope_va%3D1); - Homelessness Among Female Veterans (https://va.dimensions.ai/auth/base/login?redirect=%2Fdetails%2Fpublication%2Fpub.1032548910%3Fsearch_mode%3Dcontent%26search_text%3Dhomeless%252A%2BAND%2Brisk%252A%2BAND%2Breview%252A%26search_type%3Dkws%26search_field%3Dtext_search%26and_subset_scope_va%3D1); - Risk Factors for Homelessness Among US Veterans (https://va.dimensions.ai/details/publication/pub.1048636430?search_mode=content&search_text=homeless*%20AND%20risk*%20AND%20review*&search_type=kws&search_field=text_search&and_subset_scope_va=1) | 8

2. Search for systematic reviews currently under development (includes forthcoming reviews & protocols); Date Searched: 03-14-2023
D. Under development: | Evidence: | Results:
AHRQ topics in development (EPC Status Report) | Email Charli Armstrong Charlotte.Armstrong1@va.gov | 0
PROSPERO (SR registry) (https://www.crd.york.ac.uk/PROSPERO/) | - ADHD and Autism in the Homeless Population (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=247213); ○ See review question 2.; - Estimating Rates of Intellectual Disability and Borderline Intelligence in English-Speaking Populations of Individuals Experiencing Homelessness (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=373216); - Predictors for Homelessness and Predictors for Getting Out of Homelessness (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=13119); - Prevalance of Adverse Childhood Experiences (ACEs) and Associations with Health and Functioning Among Adults Experiencing Homelessness (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=218741); - Prevalance of Mental Disorders Among Homeless Youth (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=282307); - The Association of Traumatic Brain Injury with Neurologic and Psychiatric Illness Among Individuals Experiencing Homelessness (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=171932); - The Prevalance of Adverse Childhood Experiences (ACEs) Among Homeless Youth (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=233449); - The Prevalance of Mental Disorders Among Homeless People in Western Countries (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=85216); - Traumatic Brain Injury in Homeless and Marginally Housed Individuals (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=119678) | 9

## PRIMARY STUDIES

5. Search for primary literature: Among Veterans, what factors during in-service and post-service periods are associated with post-service homelessness?; Date searched: 03-14-2023
MEDLINE
# | Search Statement | Results
1 | Ill-Housed Persons/ or (homeless* or ill-housed or shelterless or unsheltered or unhoused).ti,ab,kf. | 15520
2 | Veterans/ or veteran*.ti,ab,kf. | 46611
3 | 1 and 2 | 830
4 | limit 3 to English language | 830
Cochrane
# | Search Statement | Results
1 | MeSH descriptor: [Ill-Housed Persons] this term only | 434
2 | (homeless* or ill-housed or shelterless or unsheltered or unhoused):ti,ab,kw | 1154
3 | #1 OR #2 | 1154
4 | MeSH descriptor: [Veterans] this term only | 1449
5 | veteran*:ti,ab | 6740
6 | #9 OR #10 | 6849
7 | #3 AND #11 | 95
8 | limit #8 to English language | 95
PsycInfo
# | Search Statement | Results
1 | exp Homeless/ or (homeless* or ill-housed or shelterless or unsheltered or unhoused).ti,ab. | 13184
2 | Military Veterans/ or veteran*.ti,ab. | 26549
3 | 1 and 2 | 694
4 | limit 3 to English language | 669
SocIndex
# | Search Statement | Results
1 | (DE “Homeless Persons” OR DE “African American Homeless Persons” OR DE “Hispanic American Homeless Persons” OR DE “Homeless Children” OR DE “Homeless Families” OR DE “Homeless Men” OR DE “Homeless Students” OR DE “Homeless Women” OR DE “Homeless Youth” OR DE “Native American Homeless Persons” OR DE “Older Homeless Persons” OR DE “Rogues & Vagabonds” OR DE “Tramps” OR DE “Homeless Camps” OR DE “Homeless Shelters” OR DE “Homelessness” OR DE “Squatters”) OR TI (homeless* or ill-housed or shelterless or unsheltered or unhoused) OR AB (homeless* or ill-housed or shelterless or unsheltered or unhoused) | 10304
2 | DE “Veterans” OR TI veteran* OR AB veteran* | 7614
3 | S1 AND S2 | 225
4 | DE “Homeless Veterans” | 64
5 | S3 OR S4 | 236
6 | limit 5 to English language | 235