# REFERENCES

1 Fusaro VA, Levy HG, Shaefer HL. Racial and ethnic disparities in the lifetime prevalence of homelessness in the United States. Demography. 2018;55(6):2119–2128.30242661
2 Tsai J, Pietrzak RH, Szymkowiak D. The problem of veteran homelessness: An update for the new decade. American journal of preventive medicine. 2021;60(6):774–780.33583678
3 Montgomery AE, Dichter ME, Thomasson AM, Fu X, Roberts CB. Demographic characteristics associated with homelessness and risk among female and male veterans accessing VHA outpatient care. Womens Health Issues. Jan-Feb 2015;25(1):42–8. doi:10.1016/j.whi.2014.10.003 25498763
4 Tsai J, Mitchell L, Nakashima J, Blue-Howells J. Unmet needs of homeless U.S. veterans by gender and race/ethnicity: Data from five annual surveys. Psychol Serv. Feb 2023;20(1):149–156. doi:10.1037/ser0000557 34780210
5 Garcia C, Doran K, Kushel M. Homelessness And Health: Factors, Evidence, Innovations That Work, And Policy Recommendations. Health Aff (Millwood). Feb 2024;43(2):164–171. doi:10.1377/hlthaff.2023.01049 38315930
6 Cusack M, Montgomery AE, Sorrentino AE, Dichter ME, Chhabra M, True G. Journey to Home: development of a conceptual model to describe Veterans' experiences with resolving housing instability. Housing Studies. 2020;35(2):310–332.
7 Tannis C, Rajupet S. Differences in disease prevalence among homeless and non-homeless veterans at an urban VA hospital. Chronic Illn. Sep 2022;18(3):589–598. doi:10.1177/17423953211023959 34162270
8 Tsai J, Link B, Rosenheck RA, Pietrzak RH. Homelessness among a nationally representative sample of US veterans: prevalence, service utilization, and correlates. Soc Psychiatry Psychiatr Epidemiol. Jun 2016;51(6):907–16. doi:10.1007/s00127-016-1210-y 27075492
9 Iheanacho T, Stefanovics E, Rosenheck R. Opioid use disorder and homelessness in the Veterans Health Administration: The challenge of multimorbidity. J Opioid Manag. May/Jun 2018;14(3):171–182. doi:10.5055/jom.2018.0447 30044482
10 Manhapra A, Stefanovics E, Rosenheck R. The association of opioid use disorder and homelessness nationally in the veterans health administration. Drug Alcohol Depend. Jun 1 2021;223:108714. doi:10.1016/j.drugalcdep.2021.108714 33865213
11 Buchholz JR, Malte CA, Calsyn DA, Associations of housing status with substance abuse treatment and service use outcomes among veterans. Psychiatr Serv. Jul 2010;61(7):698–706. doi:10.1176/ps.2010.61.7.698 20592005
12 Baggett TP, O'Connell JJ, Singer DE, Rigotti NA. The unmet health care needs of homeless adults: a national study. Am J Public Health. Jul 2010;100(7):1326–33. doi:10.2105/ajph.2009.180109 20466953
13 Gundlapalli AV, Jones AL, Redd A, Characteristics of the Highest Users of Emergency Services in Veterans Affairs Hospitals: Homeless and Non-Homeless. Stud Health Technol Inform. 2017;238:24–27.28679878
14 Gundlapalli AV, Redd A, Bolton D, Patient-aligned Care Team Engagement to Connect Veterans Experiencing Homelessness With Appropriate Health Care. Medical care. 2017;55 Suppl 9 Suppl 2:S104–S110. doi:10.1097/MLR.0000000000000770
15 O'Toole TP, Johnson EE, Borgia M, Population-Tailored Care for Homeless Veterans and Acute Care Use, Cost, and Satisfaction: A Prospective Quasi-Experimental Trial. Preventing chronic disease. 2018;15:E23. doi:10.5888/pcd15.170311 29451116
16 O'Toole TP, Johnson EE, Redihan S, Borgia M, Rose J. Needing Primary Care But Not Getting It: The Role of Trust, Stigma and Organizational Obstacles reported by Homeless Veterans. Journal of health care for the poor and underserved. 2015;26(3):1019–31. doi:10.1353/hpu.2015.0077 26320930
17 Fudge M, McDonough D. Secretaries of HUD, VA joint statement on ending Veteran homelessness. Washington, DC: US Department of Housing and Urban Development. 2021;
18 Homelessness USICo. Opening doors: Federal strategic plan to prevent and end homelessness. US Interagency Council on Homelessness; 2015.
19 Increased Investments in Ending Veteran Homelessness Are Paying Off. National Alliance to End Homelessness. . https://endhomelessness.org/resource/increased-investments-ending-veteran-homelessness-paying-off/
20 Nelson RE, Byrne TH, Suo Y, Association of temporary financial assistance with housing stability among US veterans in the supportive services for veteran families program. JAMA Network Open. 2021;4(2):e2037047–e2037047.33566108
21 About the Homeless Programs Office. Department of Veterans Affairs. https://www.va.gov/homeless/about_homeless_programs.asp
22 Tsai J, Byrne TH. National utilization patterns of Veterans Affairs homelessness programs in the era of housing first. Psychiatric services. 2019;70(4):309–315.30651057
23 VA program highlighted as a model of excellence in caring for homeless Veterans. Department of Veterans Affairs. https://news.va.gov/35162/va-program-highlighted-model-excellence-caring-homeless-veterans/
24 Sousa T, Andrichik A, Prestera E, Rush K, Tano C, Wheeler M. The 2023 annual homelessness assessment report (AHAR) to congress: US Department of Housing and Urban Development. 2023.
25 Patient-Aligned Care Teams (PACT). Department of Veterans Affairs. https://www.hsrd.research.va.gov/research_topics/pact.cfm
26 Patient Care Services: Patient Aligned Care Team (PACT). Department of Veterans Affairs https://www.patientcare.va.gov/primarycare/PACT.asp
27 VA Homeless Programs: Homeless Patient Aligned Care Teams. Department of Veterans Affairs. https://www.va.gov/HOMELESS/HPACT.asp
28 Tsai J, Havlik J, Howell BA, Johnson E, Rosenthal D. Primary Care for Veterans Experiencing Homelessness: a Narrative Review of the Homeless Patient Aligned Care Team (HPACT) Model. Journal of general internal medicine. 2023;38(3):765–783. doi:10.1007/s11606-022-07970-y 36443628
29 O'Toole TP, Johnson EE, Aiello R, Kane V, Pape L. Tailoring Care to Vulnerable Populations by Incorporating Social Determinants of Health: the Veterans Health Administration's "Homeless Patient Aligned Care Team" Program. Preventing chronic disease. 2016;13:E44. doi:10.5888/pcd13.150567 27032987
30 Guyatt GH, Oxman AD, Vist GE, GRADE: an emerging consensus on rating quality of evidence and strength of recommendations. Bmj. Apr 26 2008;336(7650):924–6. doi:10.1136/bmj.39489.470347.AD 18436948
31 Jones AL, Hausmann LRM, Haas GL, A national evaluation of homeless and nonhomeless veterans' experiences with primary care. Psychological services. 2017;14(2):174–183. doi:10.1037/ser0000116 28481602
32 Jones AL, Hausmann LRM, Kertesz SG, Providing Positive Primary Care Experiences for Homeless Veterans Through Tailored Medical Homes. Lippincott Williams and Wilkins; 2019:270–278.
33 Jones AL, Kelley AT, Suo Y, Trends in Health Service Utilization After Enrollment in an Interdisciplinary Primary Care Clinic for Veterans with Addiction, Social Determinants of Health, or Other Vulnerabilities. Journal of general internal medicine. 2023;38(1):12–20. doi:10.1007/s11606-022-07456-x 35194740
34 Chinchilla M, Gabrielian S, Hellemann G, Glasmeier A, Green M. Determinants of community integration among formerly homeless veterans who received supportive housing. Community & Social Services 3373 Military Psychology 3800. Frontiers in Psychiatry. 2019;10doi:10.3389/fpsyt.2019.00472
35 Johnson EE, Borgia M, Rose J, O'Toole TP. No wrong door: Can clinical care facilitate veteran engagement in housing services? Psychological services. 2017;14(2):167–173. doi:10.1037/ser0000124 28481601
36 O'Toole TP, Buckel L, Bourgault C, Applying the chronic care model to homeless veterans of a population approach to primary care on utilization and clinical outcomes. Health & Mental Health Services 3370 Military Psychology 3800. American Journal of Public Health. 2010;100(12):2493–2499. doi:10.2105/AJPH.2009.179416 20966377
37 O'Toole TP, Johnson EE, Borgia ML, Rose J. Tailoring Outreach Efforts to Increase Primary Care Use Among Homeless Veterans: Results of a Randomized Controlled Trial. Journal of general internal medicine. 2015;30(7):886–98. Comment in: J Gen Intern Med. 2015 Jul;30(7):868–9 PMID: 25788245 [https://www.ncbi.nlm.nih.gov/pubmed/25788245]. doi:10.1007/s11606-015-3193-x 25673574
38 Chang ET, Zulman DM, Nelson KM, Use of General Primary Care, Specialized Primary Care, and Other Veterans Affairs Services among High-Risk Veterans. Article. JAMA Network Open. 2020;3(6):E208120. doi:10.1001/jamanetworkopen.2020.8120 32597993
39 Gabrielian S, Jones AL, Hoge AE, Enhancing Primary Care Experiences for Homeless Patients with Serious Mental Illness: Results from a National Survey. Journal of primary care & community health. 2021;12:2150132721993654. doi:10.1177/2150132721993654
40 Jones AL, Chu K, Rose DE, Quality of Depression Care for Veterans Affairs Primary Care Patients with Experiences of Homelessness. Journal of general internal medicine. 2023;38(11):2436–2444. doi:10.1007/s11606-023-08077-8 36810631
41 Jones AL, Hausmann LRM, Kertesz S, Differences in Experiences With Care Between Homeless and Nonhomeless Patients in Veterans Affairs Facilities With Tailored and Nontailored Primary Care Teams. Medical care. 2018;56(7):610–618. doi:10.1097/MLR.0000000000000926 29762272
42 Jones AL, Thomas R, Hedayati DO, Saba SK, Conley J, Gordon AJ. Patient predictors and utilization of health services within a medical home for homeless persons. Substance abuse. 2018;39(3):354–360. doi:10.1080/08897077.2018.1437500 29412071
43 Kertesz SG, deRussy AJ, Kim Y- I, Comparison of Patient Experience Between Primary Care Settings Tailored for Homeless Clientele and Mainstream Care Settings. Medical care. 2021;59(6):495–503. doi:10.1097/MLR.0000000000001548 33827104
44 Kertesz SG, Holt CL, Steward JL, Comparing Homeless Persons' Care Experiences in Tailored Versus Nontailored Primary Care Programs. American Journal of Public Health. 2013;103(S2):S331–9. doi:10.2105/AJPH.2013.301481 24148052
45 O'Toole TP, Bourgault C, Johnson EE, New to care: demands on a health system when homeless veterans are enrolled in a medical home model. American journal of public health. 2013;103 Suppl 2:S374–9. doi:10.2105/AJPH.2013.301632
46 Trivedi AN, Jiang L, Johnson EE, Lima JC, Flores M, O'Toole TP. Dual Use and Hospital Admissions among Veterans Enrolled in the VA's Homeless Patient Aligned Care Team. Health services research. 2018;53 Suppl 3:5219–5237. doi:10.1111/1475-6773.13034 30151996
47 Riggs KR, Hoge AE, DeRussy AJ, Prevalence of and Risk Factors Associated With Nonfatal Overdose Among Veterans Who Have Experienced Homelessness. JAMA Netw Open. Mar 2 2020;3(3):e201190. doi:10.1001/jamanetworkopen.2020.1190 32181829
48 Pinchbeck EW. Convenient primary care and emergency hospital utilisation. J Health Econ. Dec 2019;68:102242. doi:10.1016/j.jhealeco.2019.102242 31605834
49 van den Berg MJ, van Loenen T, Westert GP. Accessible and continuous primary care may help reduce rates of emergency department use. An international survey in 34 countries. Fam Pract. Feb 2016;33(1):42–50. doi:10.1093/fampra/cmv082 26511726
50 Sabety A, Gruber J, Bae JY, Sood R. Reducing frictions in health care access: The ActionHealthNYC experiment for undocumented immigrants. American Economic Review: Insights. 2023;5(3):327–346.
51 Kertesz SG, deRussy AJ, Hoge AE, Organizational and patient factors associated with positive primary care experiences for veterans with current or recent homelessness. Health Services Research. 2024;
52 Browne K, Roseman D, Shaller D. Section 2: Why Improve Patient Experience?
53 Tsai J, Szymkowiak D, Jutkowitz E. Developing an operational definition of housing instability and homelessness in Veterans Health Administration's medical records. PLoS One. 2022;17(12):e0279973. doi:10.1371/journal.pone.0279973 36584201
54 Crone B, Metraux S, Sbrocco T. Health Service Access Among Homeless Veterans: Health Access Challenges Faced by Homeless African American Veterans. J Racial Ethn Health Disparities. Oct 2022;9(5):1828–1844. doi:10.1007/s40615-021-01119-z 34402040
55 VA Health Systems Research: Randomized Program Evaluations. U.S. Department of Veterans Affairs. https://www.hsrd.research.va.gov/research/portfolio_description.cfm?Sulu=32
56 Hemming K, Haines TP, Chilton PJ, Girling AJ, Lilford RJ. The stepped wedge cluster randomised trial: rationale, design, analysis, and reporting. Bmj. Feb 6 2015;350:h391. doi:10.1136/bmj.h391 25662947
57 Christian NJ, Havlik J, Tsai J. The Use of Mobile Medical Units for Populations Experiencing Homelessness in the United States: A Scoping Review. J Gen Intern Med. Jun 2024;39(8):1474–1487. doi:10.1007/s11606-024-08731-9 38528232
58 Wong MS, Gabrielian S, Lynch KE, Healthcare service utilization for formerly homeless veterans in permanent supportive housing: Do neighborhoods matter? Psychol Serv. Aug 2022;19(3):471–479. doi:10.1037/ser0000561 34081525