# ACKNOWLEDGMENTS

The authors are grateful to Becky Baltich Nelson, MLS, MS, for literature searching and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Thomas O'Toole, MD
  Deputy AUSH Clinical Services
  Veterans Health Administration

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Jack Tsai, PhD
  Research Director
  National Center on Homelessness Among Veterans
- Jillian Weber, PhD, RN
  National Program Manager, Homeless-PACT
  Veterans Health Administration