# DISCUSSION

Establishing and engaging Veterans experiencing housing insecurity with primary care provides an opportunity to manage the complex medical and social needs of these Veterans. The present review synthesized available evidence on the benefits of primary care and homeless-tailored primary care for Veterans experiencing housing insecurity across a range of health care utilization and disease outcomes. We identified 4 studies that examined the effect of receiving primary care compared with not receiving primary care and 16 studies that compared homeless-tailored primary care to usual primary care. All the studies enrolled Veterans experiencing housing insecurity, but only 1 study analyzed Veterans exclusively from a named homeless program (HUD-VASH). The most frequently evaluated outcomes were emergency department use, satisfaction, inpatient, and special care use. Key findings include:

Effect of Engaging Veterans Experiencing Housing Insecurity in Primary Care

► Engaging Veterans experiencing housing insecurity in any primary care may significantly reduce hospitalizations and emergency department visits (moderate confidence).
► Among Veterans experiencing housing insecurity, primary care visits may be high after initial engagement in primary care and then decrease over time (low confidence).
► Studies provided insufficient evidence (no conclusion) for housing or community integration outcomes for housing-insecure Veterans who are versus are not established in primary care.
► The studies did not evaluate specialty care utilization, cost and return on investment, Veteran experience or satisfaction, or disease-specific outcomes.

Effect of Homeless-Tailored Primary Care versus Usual Primary Care

► Homeless-tailored primary care may reduce inpatient hospitalizations and emergency department visits and increase appropriate use of emergency care (low confidence).
► Studies provided insufficient evidence (no conclusion) on the effect of homeless-tailored compared to usual primary care on primary care utilization or overall specialty care utilization.
► Homeless-tailored primary care may reduce mental health and substance use visits (low confidence).
► Patient experiences may be better for housing-insecure Veterans in homeless-tailored primary care compared to usual primary care (low confidence).
► Homeless-tailored primary care may increase primary care costs and reduce emergency department and overall health care costs (low confidence).
► There is no evidence for a difference in disease-specific outcomes for Veterans in homeless-tailored primary care compared to usual care (low confidence).
► The studies did not evaluate housing and community integration outcomes.

Only 4 studies evaluated the effect (or association) of primary care (ie, yes or no primary care) on outcomes for Veterans experiencing housing insecurity. Two of the 4 studies included Veterans who were previously not established with primary care and 2 studies compared Veterans who did or did not use primary care. Importantly, 2 of these studies were not originally designed to investigate the effect of primary care on outcomes. The studies identified fewer emergency department visits, as well as fewer inpatient admissions for Veterans experiencing housing insecurity engaged in primary care compared to those without primary care engagement. This finding is consistent with the broader literature that has concluded that increased access to primary care is generally associated with less use of acute care.^48, 49^ Establishing and engaging Veterans in primary care likely prevents some acute events through better chronic disease management and diverting patients with low health needs that can be treated in primary care rather than the emergency deparment.^48, 50^ Although the 4 studies did not evaluate cost, the findings of reduced acute care may translate into cost savings and a positive return on investment for engaging Veterans experiencing housing insecurity in primary care. One study found that for Veterans newly established in primary care, primary care use was initially high and then decreased over time. Although the study did not provide an explanation for this result, this finding may point to a high number of unmet health care needs in the population. These needs may be addressed during the initial primary care visits and then stabilize over time. Furthermore, studies provided insufficient evidence to determine the effect of engaging in primary care on housing or community integration outcomes, and no studies examined the effect of primary care on specialty care use or chronic disease management for Veterans experiencing housing insecurity.

More studies compared homeless-tailored primary care (either HPACT or a model of homeless-tailored primary care) to general or usual primary care. Studies likely focused on this comparison because VA providers (at the national and medical center levels) have implemented multiple models of homeless-tailored primary care, which can be compared to usual primary care. Models of homeless-tailored primary care have been labeled differently in the literature, but generally consist of high staff-to-patient ratios, traditional primary care services, non-medical social services, and outreach.^51^ Homeless-tailored primary care may reduce inpatient hospitalizations and emergency department visits and increase appropriate use of emergency care. Of note, the studies did not consistently report whether hospitalizations or emergency department visits were for a specific cause or represented all-cause utilization. The reductions in acute care occurred despite insufficient evidence for primary care utilization or overall specialty care utilization for Veterans in homeless-tailored primary care compared to usual primary care. One study found that primary care costs were higher for those in HPACT compared to PACT, but emergency department and overall costs were lower. Again, studies were not designed nor reported data to fully understand the mechanism through which homeless-tailored primary care affects outcomes. Importantly, Veterans in homeless-tailored primary care had higher experience or satisfaction scores indicating that they rated the added services or attitudes typically provided with tailored care higher than usual care. Studies of the general population have demonstrated that satisfaction with health care is important and associated with better patient outcomes.^52^ We concluded that tailored primary care may reduce mental health and substance use services. This may be because homeless-tailored primary care includes these services as part of their model of care. However, an alternative explanation is that Veterans in HPACT may not receive the same referrals for services as non-HPACT Veterans.

## STRENGTHS AND LIMITATIONS OF THE EVIDENCE BASE

The overall evidence base has important methodological limitations. First, the studies varied considerably in design and aims, precluding simple summarization across studies or meta-analysis. Second, the studies used different terms to define the population of Veterans experiencing housing insecurity. Some studies labeled the population as homeless, while others used terms such as patients with homeless experiences, homeless-experienced, and people who have experienced homelessness.

Sometimes when the term “homeless” was used, it was unclear whether this meant homelessness at the time of inclusion into the study or a history of (prior) homelessness. Moving forward, there should be an eye towards consistent language to describe the population of “homeless” Veterans.

Third, the studies varied in their method of identifying relevant Veterans, with most studies using a combination of ICD codes and VA homeless service use or enrollment in HPACT or specialized primary care. In some cases, simply relying on ICD codes and homeless service use may not provide a full count of Veterans experiencing housing insecurity.^53^ Moreover, the studies used different lookback periods when defining their inclusion criteria. Longer lookback periods will include more Veterans with a history of homelessness, but comparing someone who was homeless 3 years ago versus within the last year may not be comparable. Using program enrollment data is a strong approach but, in some cases, can still leave challenges with identifying a comparable comparison group.

Fourth, studies did not examine whether the benefits of primary care were consistent across important subpopulations of Veterans, many of which are disproportionately impacted by homelessness. Individuals experiencing homelessness may already face barriers to accessing appropriate health care, and those who are racial or ethnic minorities may encounter additional cultural or systemic barriers to appropriate health care utilization.^54^ In addition, female Veterans may be more likely to experience housing insecurity and have more health and social unmet needs.^3, 4^ Furthermore, the intersectionality between race and gender (and sexual and gender identity) may have important implications for these subpopulations. Subgroup analyses by race and ethnicity, gender, sexual identity, and other sociodemographic factors could provide a better understanding of how primary care access or tailored primary care use may differentially affect these groups.

Fifth, although of importance to operational partners, studies were inconsistent in whether they reported cost, return on investment, disease-specific outcomes, and housing outcomes.

Lastly, the evidence on the effect of establishing Veterans experiencing housing insecurity in primary care has additional unique challenges. It is typically not practical, and may not be ethical, to randomize Veterans to receive or not receive primary care. Thus, investigators must rely on observational data (mostly VA electronic medical records) to compare Veterans who do and do not engage in care. Even when controlling for confounders with robust VA data, the potential for selection bias is still likely to be high when investigating primary care as an exposure. Factors such as degree of treatment readiness and treatment engagement, history of stigmatization, contributing impacts of other social drivers of health, and co-occurring conditions can impact Veterans’ engagement in primary care. Because of this, it may be challenging to draw conclusion from the current evidence without the need for several caveats to these results. Importantly, 2 of the 4 studies examining the effect of primary care exposure were designed to investigate a different question but reported sufficient data to allow us to extract relevant data for the purposes of this review.^34, 35^

Challenges for addressing selection bias persist for studies evaluating the effect of homeless-tailored primary care versus usual primary care. In multiple studies, there were concerns related to the representativeness of the comparator group or the use of crude unadjusted analyses. To address selection bias, some studies made use of natural variation in time and/or location of implementation of homeless-tailored primary care. For example, 1 study compared Veterans in homeless-tailored primary care to a historical comparison group,^36^ and 4 studies compared Veterans in medical centers that did or did not offer HPACT.^14,32,36,41^ However, in these studies there were still challenges with finding a comparable exposure time for the comparison group.

## IMPLICATIONS FOR VA POLICY AND PRACTICE

There is a VHA priority to support Veterans’ whole health. For Veterans experiencing housing insecurity, this includes primary care, housing, and treatment of medical and mental health conditions. We found that establishing and engaging Veterans experiencing housing insecurity in primary care was associated with lower emergency department use, including inappropriate emergency department use and fewer hospitalizations. In addition, Veterans enrolled in a homeless-tailored primary care felt more “satisfied” or had more positive experiences with their care. Because of the reduction in emergency and inpatient visits and efficient use of outpatient care, there is clear value in establishing Veterans experiencing housing insecurity in primary care. Although homeless-tailored primary care has some additional benefits over usual primary care, it is commonly accepted that any primary care is better than none.

Engaging and retaining Veterans experiencing housing insecurity in VA care is important because this population has housing, social, and medical needs that may be difficult to address outside the VA in a community setting. In comparison, the VA is uniquely able to provide these Veterans with comprehensive supports to address housing, social, and medical needs. The VA is positioned to enroll Veterans experiencing housing insecurity in primary care. The multiple VA programs to end Veteran homelessness typically have formal intake assessments, enrollments in programming, and multiple contacts with staff. During intake or other contacts with homeless program staff, there is an opportunity to refer Veterans to primary care. VA decision-makers should consider developing a formal protocol that facilitates referrals between homeless program staff and primary care staff. Any formal protocol should be evaluated using rigorous implementation science methods. Evaluating efforts to strengthen connections between programs may require adding additional questions or items to homeless program intake assessments, but adding items to program intake will need to be balanced against staff time and burden.

## STRENGTHS AND LIMITATIONS OF THE SYSTEMATIC REVIEW PROCESS

Our review represents the most up-to-date report evaluating the effect of establishing Veterans experiencing housing insecurity in primary care and the effect of tailored primary care compared to usual primary care. We used a custom search and uniform screening protocol to identify studies relevant to the key questions of this review, and the review team included individuals with both methodological and topic expertise. We did not differentiate between different tailored primary care programs and instead evaluated them as a single group. In addition, we did not differentiate between the types of usual primary care, which consisted of programs described as PACT and general internal medicine primary care. Care provided across these programs (both intervention and usual care) may be different, making it challenging to understand what aspects of tailored primary care affect outcomes. Further, because many of these studies utilized the same VA data (medical centers with HPACT) or national Veteran surveys, the same Veterans may be included in more than one of the identified studies. Lastly, many studies were not designed to directly investigate the effect of primary care. As a result, it was necessary to exclude information from some comparison groups (such as from studies that compared Veterans experiencing housing insecurity to stably housed Veterans) and to evaluate some NRCSs as single group studies. Related, we may have missed some studies where the effect of primary care for Veterans experiencing housing insecurity was not the aim of the study and instead the study only used primary care as a covariate in a regression model.

## FUTURE RESEARCH

The evidence base regarding the effect of establishing Veterans experiencing housing insecurity in primary care is small. Although it is not practical or ethical to randomize Veterans to primary care, there are opportunities for qualitative research to understand barriers and facilitators to accessing care and the perceived benefits of primary care.

Investigating homeless-tailored primary care compared to usual primary care may be an ideal scenario for site-level randomization (ie, randomized at the Medical Center level),^55, 56^ such as that used in VA’s Partnered Evidence-Based Policy Resource Center random program evaluation model. Cluster or site-level randomized trials may allow for higher quality studies while reducing the ethical considerations surrounding randomizing Veterans to homeless-tailored primary care or usual primary care. Future studies evaluating homeless-tailored primary care should also focus on describing the specific features of the tailored primary care model and understanding the aspects of tailored primary care that create value. For example, Multiphase Optimization Strategy (MOST) framework is one approach to understand the different features of homeless-tailored primary care that are most effective. Further, there was limited information for several outcomes of interest, including data on costs and disease-specific outcomes. Additional cost and cost-effectiveness data would be particularly powerful to help understand the resources required to deliver homeless-tailored primary care. For studies conducted in the VA, cost data may be relatively easy to evaluate (obtained from routinely captured VA data) and would not increase participant burden with surveys.

Additionally, there have also been several adaptations to HPACT, including the use of Mobile Medical Units, which may increase access to care for underserved communities.^57^ Future studies should explore the impact of these HPACT adaptations. There is also a need for future studies to consider the contextual factors that influence care, such as neighborhood factors and transportation access.^58^ Identified studies were too dissimilar to permit meta-analyses. While future studies should build on existing evidence, they should also be designed to be comparable to each other. VA researchers and staff should consider prospectively planning studies together or develop consensus about the best study designs to use and most actionable outcomes to assess.

## CONCLUSIONS

Findings from this review highlight the potential value of establishing and engaging Veterans experiencing housing insecurity in primary care and more specifically homeless-tailored primary care. Benefits of primary care for Veterans experiencing housing insecurity include reducing hospitalizations and emergency department visits. Although these studies did not evaluate cost, the reductions in acute care may translate to cost savings and a return on investment. In addition, homeless-tailored primary care may provide some additional benefits over usual primary care for Veterans experiencing housing insecurity, including reduced inpatient hospitalizations and emergency department visits and increased appropriate use of emergency care, overall cost savings, and better experiences with care. Homeless-tailored primary care may reduce the use of mental health and substance treatment, but this could be because homeless-tailored primary care includes these services in its model of care or because referral practices differ for Veterans who are versus are not enrolled in HPACT. Additional data are needed on the effect of engagement in primary care on disease and community integration outcomes, and on cost and return on investment of homeless-tailored primary care. Future studies should also aim to understand the specific features of homeless-tailored primary care and how they affect outcomes.