# METHODS

## TOPIC DEVELOPMENT

We worked with representatives from the VHA Office of the Assistant Undersecretary for Health -Clinical Services and our technical expert panel (TEP) to refine the key questions (KQ). We focused on studies that included Veterans experiencing housing insecurity (literal homelessness, history of homelessness or at risk for homelessness) and examined the effect of receiving primary care on Veteran-reported outcomes (eg, satisfaction), clinical outcomes (eg, binary indicators for chronic disease management), health service use outcomes (eg, emergency department use), and housing outcomes (eg, loss of housing). We evaluated these outcomes separately for Veterans enrolled in VA homeless programs (HUD-VASH, HCHV, GPD, SSVF, DCHV, HVCES, CWT, HCRV, or VJO) that provide housing or social support. In addition, we evaluated the effect of receiving primary care on outcomes for all Veterans experiencing housing insecurity regardless of enrollment in any VA homeless program.

## KEY QUESTIONS AND PROTOCOL

The following KQs were the focus of this review:

Key Question 1 | Among Veterans enrolled in VA programs for those experiencing housing insecurity^a^, what is the effect of receiving primary care through PACT and/or HPACT on Veteran-reported, clinical, health service use, and housing outcomes?
Key Question 2 | Among Veterans experiencing homelessness or at risk for homelessness, what is the effect of PACT and/or HPACT on Veteran-reported clinical, health service use and housing outcomes?

Notes.

a VA homeless programs include US Department of Housing and Urban Development-VA Supportive Housing (HUD-VASH), Health Care for Homeless Veterans (HCHV), Grant and Per Diem (GPD), Supportive Services for Veteran Families (SSVF), Domiciliary Care for Homeless Veterans (DCHV), Homeless Veteran Community Employment Services (HVCES), Compensated Work Therapy (CWT), Health Care for Re-entry Veterans (HCRV), or Veteran Justice Outreach (VJO).

A protocol for this review was registered on the PROSPERO international prospective register of systematic reviews (CRD42024537730 (https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42024537730)). The review followed the PRISMA guidelines. A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in the Appendix.

## SEARCHING AND STUDY SELECTION

We searched Ovid Medline, Cochrane, PsycINFO, CINAHL, Scopus, and ClinicalTrials.gov from inception until March 26, 2024. We used Medical Subject Headings (MeSH) and free text terms relevant to homelessness, VA supportive housing programs, primary care, patient aligned care teams, and Veterans (see Appendix A for complete search strategies). We ensured that known relevant publications were captured by our searches. Additional citations were sought from hand-searching reference lists of relevant systematic reviews and consultation with content experts.

Citations were uploaded into EndNote and deduplicated. We screened citations in Systematic Review Data Repository (SRDR+) (https://srdrplus.ahrq.gov/). To ensure a common understanding of the eligibility criteria, we ran a pilot round of 100 citations, where all team members screened the title and abstract of the same citations, and conflicts were resolved as a group. After this, citations were screened in duplicate, and conflicts were resolved by group discussion or by the lead researcher. Abstracts accepted at the screening phase underwent full-text review by 2 independent reviewers, with conflicts resolved by an additional team member. Appendix B lists the studies excluded at full-text review phase, along with the reason for their exclusion.

Study eligibility criteria are shown in Table 1. In brief, eligible studies included US Veterans experiencing housing insecurity. For KQ 1, we focused on studies of Veterans enrolled in HUD-VASH, HCHV, GPD, SSVF, DCHV, HVCES, CWT, HCRV, or VJO (VA programs that provide Veterans experiencing housing insecurity with various services and supports; eg, HUD-VASH provides Veterans with a housing voucher and wrap-around clinical support; CWT provides Veterans with vocational rehabilitation). For KQ 2, we focused on studies of Veterans experiencing housing insecurity regardless of enrollment in any specific VA homeless program. Both KQs focused on Veterans aged 18 and older.

Eligible studies evaluated the effect of VA primary care including PACT or HPACT on prioritized outcomes (described below). Studies were excluded if they consisted of home-based primary care, Geriatric PACT (GERIPACT), community primary care (ie, primary care outside the VA), or TriCare. Comparators of interest included Veterans experiencing housing insecurity not receiving primary care or not enrolled in PACT or HPACT, usual primary care (eg, standard VA primary care or PACT), or no comparator. We analyzed Veteran-reported outcomes such as unmet medical needs, unmet supportive care needs, or satisfaction with VA; disease-specific outcomes, including binary indicators of chronic disease management and referrals to specialty services (present or absent); food insecurity outcomes; health care utilization outcomes; and housing outcomes. Based on consultation with the nominator and technical expert panel, continuous measures of chronic disease management were excluded (eg, change in hemoglobin A1C). We included randomized controlled trials (RCT), non-randomized comparative studies (NRCS), and non-comparative (single group) studies of any design except case reports/series and qualitative research. We required at least 10 participants per intervention (eg, PACT or HPACT). If an RCT reported a comparison of interest (eg, PACT vs usual primary care) that was not randomized, we evaluated the study as a NRCS. If a RCT or NRCS included 1 eligible arm and 1 noneligible arm (eg, non-Veterans), we included the eligible arm as a “single group” study.

Table 1 Eligibility Criteria

| Inclusion Criteria | Exclusion Criteria
Population | KQ 1: US Veterans enrolled in HUD-VASH, HCHV, GPD, SSVF, DCHV, HVCES, CWT, HCRV or VJO; KQ 2: US Veterans experiencing housing insecurity (homelessness, history of homelessness or at risk for experiencing homelessness) | <18 years of age
Intervention | Receipt of primary care including PACT or HPACT, or usual primary care in the VA | Enrollment in home-based primary care, GERIPACT, community primary care, or TriCare
Comparator | KQ 1: Veterans not receiving primary care or not enrolled in PACT or HPACT, or no comparator; KQ 2: Alternative program (ie, HPACT vs. PACT), other or no health care (ie, neither HPACT nor PACT), or no comparator | - Non-Veteran comparison groups; - Health care exclusively outside the VA; - Stably housed Veterans
Outcomes | Veteran-reported outcomes; - Unmet medical or supportive care needs; - Experience/satisfaction with VA; Disease-specific outcomes; - Binary indicators for chronic disease quality measures (eg, proportion of Veterans with diabetes meeting care management goals); - Referrals to specialty care and receipt of mental health and substance use treatment; Food insecurity; Health service use and housing; - Emergency department, inpatient care, or acute psychiatric hospitalization; - Housing outcomes (eg, loss of supportive housing or positive transition out of supportive housing); - Utilization of homeless service programs; - Return on investment or cost effectiveness | - Continuous measures of chronic disease management
Timing | Any
Setting | Any
Study Design | RCTs; NRCS; Single group (including baseline and follow-up, and noncomparative) studies | - Case report/case series; - Qualitative research studies; - Protocols
Other | >10 people meeting inclusion criteria

Abbreviations. CWT=Compensated Work Therapy; DCHV=Domiciliary Care for Homeless Veterans; GERIPACT=Geriatric Patient Aligned Care Teams; GPC=Grant and Per Diem; HCHV=Health Care for Homeless Veterans; HCRV=Health Care for Re-entry Veterans; HUD-VASH=US Department of Housing and Urban Development-VA Supportive Housing; HVCES=Homeless Veteran Community Employment Services; KQ=key question; NRCS=non-randomized comparative study; PACT=Patient Aligned Care Teams; SSVF=Supportive Services for Veteran Families; VJO=Veteran Justice Outreach.

## DATA EXTRACTION, ASSESSMENT, AND SYNTHESIS

We created a data extraction form in SRDR+. We extracted the following data from eligible studies: study design, sample size, and study participant characteristics at baseline, primary care program type, and outcomes of interest. All data was extracted by 1 reviewer and then confirmed by a second reviewer, with consultation from other team members as needed.

Study risk of bias was independently assessed by 1 reviewer and confirmed by a second using questions derived from the Cochrane Risk of Bias tool for RCTs and Risk of Bias In Non-randomized Studies – of Intervention tool for other study design (Appendix C). For all study designs, we also evaluated whether the article was free of discrepancies and whether patient eligibility criteria, protocols, setting, and outcome assessment were reported clearly. For RCTs, we considered the methods of randomization and allocation concealment and whether intention-to-treat analysis was used. For NRCSs, we evaluated the similarity of patients in the treated and comparison groups and the strategies used to deal with potential confounders. Studies with low overall risk of bias had no concerns in all domains or unclear risk of bias in 1 domain. Studies with moderate overall risk of bias had unclear risk of bias for ≥2 domains and high risk of bias for only 1 domain. Studies with high overall risk of bias had concerns in ≥2 domains. In general, single group studies that do not explore within-group changes from before to after an exposure are vulnerable to biases and provide limited information on treatment effects (eg, of primary care on outcomes for Veterans experiencing housing insecurity). Therefore, results of single group studies that did not include within-group comparisons were considered at high risk of bias.

We conducted a narrative synthesis of the evidence. We aimed to meta-analyze quantitative data, but this was not feasible. We compared results in study groups using odds ratios (OR) for dichotomous outcomes. When a study had 0 events in 1 group, we calculated risk differences (RD). We compared continuous data using mean differences (MD) between interventions. Adjusted analyses were preferentially extracted over unadjusted (crude) comparisons. We assessed the certainty of evidence following the GRADE (Grading of Recommendations Assessment, Development and Evaluation) approach.^30^ We compiled key study findings in evidence profiles, which provide the basis for determination of certainty of evidence and summarize conclusions for outcomes. Within each outcome, we considered the study design, the number of studies and participants, methodological limitations, directness of the evidence, precision of the findings, consistency across studies, and other issues. Single group studies without pre and post data were excluded from our GRADE assessments. For outcomes with insufficient evidence, the summary finding for that outcome is “no conclusion.”