# BACKGROUND

Veterans experiencing housing insecurity (collectively Veterans with a history of homelessness, currently experiencing homelessness, or at risk for homelessness) are a vulnerable population in which racial and ethnic minorities are disproportionately represented.^i^ ^1,2^ Most Veterans experiencing housing insecurity are male, but female Veterans may be more likely to experience housing insecurity and have more unmet health and social needs.^3,4^ Although placing Veterans experiencing housing insecurity in permanent housing is the priority, these Veterans still have a need for health care. Conceptually, housing security and health are interrelated.^5^ Housing insecurity may lead to increased risk of poor social and health outcomes due to stress, poor access to clean water and proper hygiene, and exposure to the elements.^5^ Simultaneously, poor health, financial difficulties, and untreated substance misuse can lead to housing insecurity.^6^

Physical illness, mental illness, and substance use diagnoses are all more common among Veterans experiencing housing insecurity than matched stably housed people.^7–10^ Medical and social needs of Veterans experiencing housing insecurity can be managed with outpatient care.^11–13^ In addition, several studies have found that connecting Veterans experiencing housing insecurity with primary care may result in more appropriate (and less costly) health service utilization.^14, 15^ However, Veterans experiencing housing insecurity may be hesitant to seek primary care services due to factors such as lack of trust of the health care system or concerns about stigma.^16^ Hesitancy to seek primary care may also contribute to Veterans experiencing housing insecurity using acute care more than stably housed Veterans.^11–13^

Ending Veteran homelessness is a priority of the US Department of Veteran Affairs (VA).^17, 18^ To end Veteran homelessness, the VA has invested billions of dollars in specialized homeless services including the US Department of Housing and Urban Development-VA Supportive Housing (HUD-VASH), Health Care for Homeless Veterans (HCHV), Grant and Per Diem (GPD), Supportive Services for Veteran Families (SSVF), Domiciliary Care for Homeless Veterans (DCHV), Homeless Veteran Community Employment Services (HVCES), Compensated Work Therapy (CWT), Health Care for Re-entry Veterans (HCRV), and Veteran Justice Outreach (VJO).^19–23^ These investments may have contributed to the 47% decrease in the number of homeless Veterans seen between 2010 to 2017.^19^ However, recent data suggest a reversal in this trend. Between 2022 and 2023, there was a 7.4% increase in homelessness among Veterans.^24^

To improve Veteran care, the VA implemented the Patient Aligned Care Team (PACT) initiative in 2010. PACT is a team-based method of care that encourages collaboration and coordination between health care providers while building a partnership with Veterans.^25–27^ Teams of health care professionals work with Veterans to provide needed health care services.^25^ Since the implementation of the PACT initiative, several programs have been developed for specialized populations, including Homeless Patient Aligned Care Teams (HPACT). HPACT functions in a similar way to traditional PACT but incorporate additional team members such as social workers, substance use counselors, and homeless program staff, who offer services that can help lead to permanent supportive housing.^27,28^ In addition, HPACT may also include walk-in clinics or extended hours, integrated services such mental health services, continuity of care across the VA and community agencies through team-based care, and staff with specialized training in homeless care.^29^

Given that Veterans experiencing housing insecurity have a high prevalence of a variety of physical and behavioral health diagnoses, it is important to understand the effect of establishing primary care on these individuals’ health and housing stability. Therefore, the Veterans Health Administration (VHA) Office of the Assistant Undersecretary for Health - Clinical Services requested the following systematic review to examine the impact of primary care services, including PACT and HPACT, on health care utilization and other outcomes in Veterans experiencing housing insecurity.

i Studies used inconsistent terminology to describe the population of Veterans experiencing homelessness or at risk of homelessness. Throughout the report we chose to use the term “Veterans experiencing housing insecurity.”