# PEER REVIEW COMMENTS AND RESPONSES

Comment Number | Reviewer Number | Reviewer Comment | Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 2 | Yes | Thank you.
3 | 3 | Yes | Thank you.
4 | 5 | Yes | Thank you.
5 | 7 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
6 | 1 | No | Thank you.
7 | 2 | No | Thank you.
8 | 3 | No | Thank you.
9 | 5 | No | Thank you.
10 | 7 | No | Thank you.
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
11 | 1 | No | Thank you.
12 | 2 | No | Thank you.
13 | 3 | No | Thank you.
14 | 5 | No | Thank you.
15 | 7 | No | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
16 | 1 | Overall, I think this was a good review and I appreciated that the GRADE approach was used to gauge the level of confidence in different findings. A few minor comments | Thank you.
17 | 1 | I think Key Question #1 could perhaps be stated a bit simpler? The question is posed with a several of names of different programs, perhaps come up with a simpler way to phrase the Key Question for readers to quickly understand the scope and not be drowned in the abbreviations and program names? | Thank you. We revised Key Question 1 per the reviewer’s suggestion.; Among Veterans enrolled in VA programs for those experiencing housing insecurity^a^, what is the effect of receiving primary care through PACT and/or HPACT on Veteran-reported, clinical, health service use, and housing outcomes?; Footnote ^a^ states the specific VA homeless programs.
18 | 1 | This work was described as a systematic review but were certain review guidelines used such as Cochrane, Campbell, PRISMA, and if not, that’s okay but should be stated either way. | Thank you. We have added the following statement to the Methods section:; The review followed the PRISMA guidelines.
19 | 1 | Since there are new adaptations developed in HPACT with the deployment of Mobile Medical Units (MMUs), it may be worth mentioning they are new so new no research has been conducted on them although they hold potential as new ways to provide primary care in communities. | Thank you. We have added the following text to the Future Research section of the discussion:; Additionally, there have also been several adaptations to HPACT, including the use of Mobile Medical Units, which may increase access to care for underserved communities. Future studies should explore the impact of these HPACT adaptations.
20 | 1 | In the Implications for VA Policy and Practice, it’s not clear how the findings are relevant to MISSION Act and of course, there is a lot of concern/scrutiny around community care right now in VA but not sure the relation or implications of the findings that speak to that. | Thank you. We agree with this comment and have removed the sentence about the Mission Act in this report.
21 | 1 | The Conclusions paragraph seemed to state findings with a bit more confidence then the evidence warrants, e.g., cost savings. There is also some redundancy so suggest revising the Conclusions to succinctly state the conclusions accurately. | Thank you. We revised the Conclusion per this comment.
22 | 2 | The report is thorough, well-written and objective. The team working on this needs to be commended as they clearly met and exceeded the goals of the project. | Thank you.
23 | 2 | My only concern (less specific to this review as to the literature overall) is that less discernible factors such as degree of treatment readiness and treatment engagement, history of stigmatization, contributing impacts of other social drivers of health and co-occurring conditions which may manifest in whether the veteran is new patient or already established patient when being compared, all likely impact the primary outcomes of these studies and, when not measured, also introduce inherent biases to any comparison group included in this research review. While this is implied as a bias, I feel it needs to be more explicitly stated as an inherent reason why some conclusions can not be drawn. Additionally, the ethical considerations inherent in this work do introduce challenges to truly having an matched comparator group or being able to manage an intervention objectively. These are upfront limitations to all of this research are addressed to some degree in the limitations section on page 37 - however, I feel could be better acknowledged and/or explicitly noted as the basis for no conclusions being drawn as opposed to negative results (if and when that was the case). | Thank you and we agree. We edited the text to call out the challenges noted by the reviewer. Examples of our edits are below.; Factors such as degree of treatment readiness and treatment engagement, history of stigmatization, contributing impacts of other social drivers of health and co-occurring conditions can impact Veterans’ engagement in primary care. Because of this, it may be challenging to draw conclusion from the current evidence without the need for several caveats to these results.
24 | 2 | The specific description of reference 21 (Gundlapalli et al on emergency department utilization) was difficult to follow in the text. Albeit I had challenges when it first was published as well and had to meet with the authors to explain it better to me but some simplification/clarity on outcomes and subgroup qualifiers may help with readability. | Thank you and we agree. We have edited the description of ref 21 for clarity.
25 | 2 | There are some typos on page 21 (line 59) and page 5 (lines 55 and 58). | Thank you. We have fixed these typos.
26 | 3 | I appreciate this comprehensive evidence synthesis report regarding the impacts of engaging housing insecure Veterans in primary care - housing is so often considered the key outcome in VA’s homeless program, the report nicely highlights the importance of primary care in VA’s whole health approach to vulnerable Veterans, and makes clear the value of strengthening linkages between VA’s homeless programs and medical services. Overall, I found the report to be well-written and comprehensive. I appreciated the comment in the discussion about the need to move towards consistent language to describe the population named as housing insecure in the report. | Thank you.
27 | 3 | I did think the authors made the assumption that the readers had some fundamental knowledge of the topic at play (probably not an unreasonable assumption), and that some of the assumed knowledge might benefit from being described in the background introduction. More specifically, a variety of outcomes are discussed throughout the report, including service use (inpatient and outpatient), housing, food insecurity, experience / satisfaction, community integration - a conceptual framework that shows how these domains all fit together, and why they are relevant, would have anchored the report for the reader from the get go. In addition, there is a significant focus on comparing PACT versus HPACT - a worthy comparison. However, though there is a relatively simple description of HPACT, more details about HPACT as a model would be helpful. | Thank you. We revised the Introduction to note the relationship between housing and health / social outcomes.; Conceptually, housing security and health are interrelated. Housing insecurity may lead to increased risk of poor social and health outcomes due to stress, poor access to clean water and proper hygiene, and exposure to the elements. Simultaneously, poor health, financial difficulties, untreated substance misuse can lead to housing insecurity.; The Introduction now includes more details about HPACT.; HPACT functions in a similar way to traditional PACT but incorporate additional team members such as social workers, substance use counselors, and homeless program staff who offer services that can help lead to permanent supportive housing. In addition, HPACT may also include walk-in clinics or extended hours, integrated services such mental health services, continuity of care across the VA and community agencies through team-based care, and staff with specialized training in homeless care.
28 | 3 | The title of the report refers more broadly to engaging housing insecure Veterans in VHA health care - but, the focus is primary care. Might it be helpful to make that clear in the title? | Thank you. We have updated the title to state:; Engaging Veterans Experiencing Homelessness in Primary Care: A Systematic Review
29 | 3 | KQ1 is interested in that it is specific to a range of VA homeless program participants - I believe that the list of programs of interest is nearly all encompassing of homeless programs. Are any left out? It might be helpful to have clarity that the KQ1 is focused on Veterans engaged in VA homeless services, across the breadth of services, and then listing out the individual programs included | Thank you. We edited Key Question 1 for clarity.; Among Veterans enrolled in VA programs for those experiencing housing insecurity^a^, what is the effect of PACT and/or HPACT on Veteran-reported clinical, health service use and housing outcomes?; Footnote ^a^ states the specific VA homeless programs.
30 | 3 | Throughout the report, one of the more salient findings is that primary care engagement decreases hospitalizations - is this all hospitalizations? Med/surg hospitalizations? Psychiatry hospitalizations? Perhaps this distinction isn’t made in the literature but it would be helpful to define hospitalizations for the reader | Thank you. In the results section we note when findings are related to a cause specific hospitalization or all cause hospitalization. In addition, we revised the discussion to note that some studies did not clearly report whether acute care utilization was for a specific cause or represented all causes.; The studies did not consistently indicate the reason for hospitalization.
31 | 3 | A temporal change in primary care use is described at several points in the report, specifically with regards to Veterans in homeless programs initially perhaps using primary care in higher rates at first, and then this decreasing, which is consistent with my experience. It would be helpful for the authors to speculate why this may be happening, and also to talk about the potential relevance of temporal trends in primary care use as it isn’t intuitive that this is aligned with either of the KQs | Thank you. We edited the text in the discussion section to address this point:; Although the study did not provide an explanation for this result, this finding may point to a high number of unmet health care needs in the population. These needs may be addressed during the initial primary care visits and then stabilize over time.
32 | 3 | At several points, the report discusses “appropriate ED utilization” - on page 20, line 34, there is no definition of appropriateness that I could find. There was a comment about substance abuse related visits but unclear how that relates to appropriateness. Later on, on page 26, line 54, the authors refer to ACSC conditions, which is how I thought this would be defined from the get go. Then, on page 27, line 23, appropriate comes up again but I’m not sure if the reference is still to ACSC conditions, or some other definition | Thank you. The studies reported different measures of appropriate emergency department use or alternatively inappropriate emergency department use. Sometimes studies used well known measures and other times studies did not clearly report the measure used to define appropriate use. In the results section we describe how each study defines appropriate or inappropriate emergency use.
33 | 3 | Page 25, line 7, talks about physician primary care encounters. At first pass, I thought the reference was physicians versus physician extenders (e.g., NPs, PAs) but the rest of the sentence made it sound like the term physician was a term used to encompass all prescribing providers as opposed to nurse visits | Thank you. This study reported data from primary care provider (PCP)-specific visits and PCP and nursing visits combined. We have updated the text for clarification:; One NRCS found significantly more primary care physician encounters...; The overall number of combined primary care physician and nursing visits ...
34 | 3 | At several points, the notion of a “general internal medicine” comparison group is raised (page 25, line 24; page 28, line 57; page 29, line 29) - is this prior to PACT implementation? How does general internal medicine differ from HPACT. | Thank you. Studies used different terms to describe primary care. For clarity we have added the specification of “non-tailored” general internal medicine throughout.
35 | 3 | There is a sense in the executive summary as well as implications of the main report that with the one-stop shop model of HPACT, with embedded mental health, less specialty MH care was needed than in traditional PACT. But later, page 30, line 59, it sounds like psychiatry/psychology visit rates were similar and really the HPACT patients had fewer group therapy visits (these can account for an enormous amount of visits and might explain the finding). It seems that the conclusion from the way it is written is that actually it’s not that HPACT has embedded mental health, but rather that in HPACT Veterans are not getting referred to group therapy. You can skew the valence of this in several ways, depending on how you want to think about it. | Thank you. We agree that there are several possible interpretations of why Veterans in HPACT have fewer mental health care. We revised the text to comment on the proposed alternative explanation.; One explanation for reduced mental health and substance use care is that homeless-tailored primary care includes these services as part of their model of care. However, an alternative explanation is that those in HPACT may not receive the same referrals for services as non-HPACT Veterans.
36 | 3 | The report talks about satisfaction / experience. But, in the discussion section, the notion of “feeling engaged in care” is seemingly made equivalent to satisfaction / experience. I would just check that parallel nomenclature is used throughout. | Thank you. We revised the text for consistency and the sentence now states:; In addition, Veterans enrolled in a homeless-tailored primary care felt more “satisfied” or had more positive experiences with their care.
37 | 5 | Thank you for the opportunity to review this manuscript.; Minor comments:; Page 10, line 45 - consider adding emphasis on HPACT model reducing barriers to care for homeless veterans while incorporating additional team members | Thank you, we have added the following text to the background section to further describe HPACT:; HPACT functions in a similar way to traditional PACT but incorporate additional team members such as social workers, substance use counselors, and homeless program staff who offer services that can help lead to permanent supportive housing. In addition, HPACT may also include walk-in clinics or extended hours, integrated services such mental health services, continuity of care across the VA and community agencies through team-based care, and staff with specialized training in homeless care.
38 | 5 | Page 21, line 59 - “HAPCT” should be HPACT. | Thank you. We have corrected this typo.
39 | 5 | Page 36, line 7 - “...associated with less use of acute...” acute what? (care?) | Thank you. We have added “care” to the end of this sentence.
40 | 5 | Page 38, lines 20–26 - For awareness, there is a question in the formal HOMES assessment (intake form, entry for VA homeless programs) asking about healthcare and if referral for care needed. | Thank you. We have updated this sentence to include this information:; VA decision makers should consider developing a formal protocol that facilitates transitions between homeless program staff and primary care staff. Any formal protocol should be evaluated using rigorous implementation science methods.
41 | 7 | This paper did a nice job describing the literature related to primary care use among Veterans experiencing housing instability. Although I noted that I am not aware of existing literature that looks specifically at this issue, it is important to note that much of the published literature related to health services use among Veterans with experience of housing instability does include primary care (and other services) utilization as correlates of a variety of outcomes including housing, mortality, etc. | Thank you for this comment. We edited the text to note the challenges with examining the association of receiving primary care on outcomes, and that many studies among Veterans experiencing housing insecurity include primary care use as a covariate rather than the primary exposure of focus. We also note in the Limitations that we may have missed studies that only included primary care as a covariate in a regression model.; Related, we may have missed some studies where the effect of primary care for Veterans experiencing housing insecurity was not the aim of the study and instead the study only used primary care as a covariate in a regression model.
42 | 7 | Throughout: This is simply semantics, but I would recommend a term other than “housing insecure Veterans” for several reasons: (1) person-first language is preferred (i.e., Veterans experiencing housing insecurity), and (2) placing “housing” as a unit modifier is sometimes confusing as it is also a verb. In the discussion, the authors mention inconsistent language across the papers reviewed for this report; however, the authors have chosen an additional way to refer to Veterans experiencing housing instability. Perhaps pick one of the options that occurs frequently and use that consistently throughout. In addition, it may be useful to address this issue up front as I had several questions about who this population really was as I read through the background, results, etc. (including on page 10, line 22). | Thank you. We have updated the terminology in the text to “Veterans experiencing housing insecurity” throughout.
43 | 7 | In the Key Findings (page 1) and Background (page 10) sections, the authors hint at Housing First, which prioritizes housing, and then states that quality health care for Veterans experiencing housing instability is also warranted. This seems unnecessary and unnuanced. Part of Housing First is to make available all of these needed services but not necessarily require them. I think that including these broad statements, and briefly focusing on permanent supportive housing (including on page 35, line 53), confuses the issue a bit. | Thank you and we agree. We revised the text throughout to reflect this comment.
44 | 7 | The Background (page 10) seems a bit naive. Again, I don’t think it’s accurate to state that the VA was “guided by Housing First” to invest in homeless services. Rather, these investments were guided by leadership declaring homelessness a priority and specific enhancements to VA homeless services were influenced by Housing First. I think that the authors can mention the reduction in homelessness as reported in the Annual Homeless Assessment Report to Congress, but we do not have the data make a causal link; there is very likely an association, but we cannot say with total confidence. | Thank you. We have edited the Background to reflect this and previous comment. We now specifically note that VA investments in homeless services [underlined: may] have contributed to a decrease in the number of Veterans experiencing homelessness.
45 | 7 | Page 1, line 11: Define “at first.” Is this after becoming homeless or being identified as homeless or following recent/new engagement in primary care? | Thank you. We have edited this text, which now states:; Among Veterans experiencing housing insecurity, primary care visits may be high after initial engagement in primary care and then decrease over time (low confidence).
46 | 7 | Page 2, line 39: Adding assessment items to HOMES may actually require quite a bit of burden. | Thank you. We have removed this part of the sentence.
47 | 7 | Page 11, sentence beginning on line 9: I think that a word is missing on line 13 (“Veteran-reported” what?). | Thank you. This was referencing Veteran-reported outcomes. We revised the text for clarity.
48 | 7 | Page 16, line 20: What is the difference between services to address social determinants of health and social services? | Thank you. We edited the sentence for clarity.; Homeless-tailored primary care was labeled differently in the literature (eg, HPACT, homeless oriented primary care, and integrated primary care) but typically consisted of a combination of physical health care, mental health care, substance use treatment, and social services for Veterans experiencing housing insecurity.
49 | 7 | Page 17, line 39: Studies evaluate the Veterans or their care? | Thank you. We have specified “care” in this sentence.
50 | 7 | Page 22, line 35: I’m not sure I understand this statement. Does this mean that there was not a difference in the amount of utilization? Or Veterans’ utilization of regular primary care vs tailored primary was not associated with improvement in outcomes? Maybe there is a word missing? Similar issue on page 35, lines35–36. | Thank you. The referenced statements note the available studies provided insufficient evidence (meaning we could not make a conclusion) for the specified outcomes. We revised the text for clarity.
51 | 7 | Page 35, line 6: What was the comparator? | Thank you. The text now states:; We identified 4 studies that examined the effect of receiving primary care compared with not receiving primary care...
52 | 7 | Page 35, line 17: In any primary care? Tailored or otherwise? | Thank you. We have specified “any” primary care as this included, but was not specific to, tailored care.