# APPENDIX H CONTINUOUS OUTCOMES

## H1. Primary Care

Author, Year, PMID | Outcome Details | Sample/Groups | Timepoint | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size, p-value
Jones, 2018, 29412071 | Primary care | HPACT | 0–12 months before enrollment | 179 | 1.56 (2.56) | MD (95% CI); 1.13 (0.57; 1.69), p=0.0001^a^
Jones, 2018, 29412071 | Primary care | HPACT | 0–12 months after enrollment | 179 | 2.69 (2.80) | MD (95% CI); 1.13 (0.57; 1.69), p=0.0001^a^
Gundlapalli, 2017, 28806373 | Medicine primary | HPACT, High utilizers | 6 months before enrollment | 511 | 0.1 (NR) | MD = −0.012^a^; p=0.015
Gundlapalli, 2017, 28806373 | Medicine primary | HPACT, High utilizers | 6 months after enrollment | 511 | 0.088 (NR) | MD = −0.012^a^; p=0.015
Gundlapalli, 2017, 28806373 | Medicine primary | HPACT site Nonenrolled, High utilizers | First 6 months of data | 2787 | 0.063 (NR) | MD = −0.014^a^; p=NR; Difference-in-differences HPACT versus nonenrolled 0.002^a^, p<0.001
Gundlapalli, 2017, 28806373 | Medicine primary | HPACT site Nonenrolled, High utilizers | Second 6 months of data | 2787 | 0.049 (NR) | MD = −0.014^a^; p=NR; Difference-in-differences HPACT versus nonenrolled 0.002^a^, p<0.001
Gundlapalli, 2017, 28806373 | Medicine primary | Usual care, High utilizers | First 6 months of data | 1689 | 0.034 (NR) | MD = 0.012^a^; p=NR; Difference-in-differences HPACT versus usual care −0.02^a^, p=0.23
Gundlapalli, 2017, 28806373 | Medicine primary | Usual care, High utilizers | Second 6 months of data | 1689 | 0.046 (NR) | MD = 0.012^a^; p=NR; Difference-in-differences HPACT versus usual care −0.02^a^, p=0.23
O’Toole, 2010, 20966377 | Primary care visits | HOPC | First 6 months of data | 79 | 5.96 (4.13) | MD = −3.95^a^; p<0.01
O’Toole, 2010, 20966377 | Primary care visits | HOPC | Second 6 months of data | 79 | 2.01 (3.56) | MD = −3.95^a^; p<0.01
O’Toole, 2010, 20966377 | Primary care visits | GIM | First 6 months of data | 98 | 1.63 (1.26) | MD = −0.32^a^; p=0.1
O’Toole, 2010, 20966377 | Primary care visits | GIM | Second 6 months of data | 98 | 1.31 (1.17) | MD = −0.32^a^; p=0.1
O’Toole, 2010, 20966377 | Primary care visits | HOPC | Second 6 months of data | 79 | 2.01 (3.56) | MD (95% CI); 0.7 (−0.01 ; 1.46)^a^; P=0.05
O’Toole, 2010, 20966377 | Primary care visits | GIM | Second 6 months of data | 98 | 1.31 (1.17) | MD (95% CI); 0.7 (−0.01 ; 1.46)^a^; P=0.05
O’Toole, 2018, 29451116 | Primary care provider-specific visits | HPACT | June 2012–January 2014 | 183 | 5.1(4.1) | p=0.001; MD (95% CI)^a^; 1.5 (0.5; 2.5)
O’Toole, 2018, 29451116 | Primary care provider-specific visits | PACT | June 2012–January 2014 | 83 | 3.6 (2.8) | p=0.001; MD (95% CI)^a^; 1.5 (0.5; 2.5)
O’Toole, 2018, 29451116 | Primary care provider and nursing visits | HPACT | June 2012–January 2014 | 183 | 8.8 (7.1) | p=0.06; MD (95% CI)^a^; 1.7 (−0.10 ; 3.5)
O’Toole, 2018, 29451116 | Primary care provider and nursing visits | PACT | June 2012–January 2014 | 83 | 7.1 (6.4) | p=0.06; MD (95% CI)^a^; 1.7 (−0.10 ; 3.5)

Notes.

a Calculated by the research team.

Abbreviations. CI=confidence interval; GIM=general internal medicine; HOPC=homeless oriented primary care; HPACT=homeless patient aligned care teams; MD=mean difference; N=number; NR=not reported; PACT=patient aligned care teams; SD=standard deviation.

## H2. Primary Care (Non-Comparative)

Author, Year, PMID | Outcome Details | Sample/Groups | Timepoint | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size, p-value
O’Toole, 2013, 24148042 | Primary care visits | Homeless PACT | First 6 months | 127 | 8.4 (5.0) | NA
O’Toole, 2016, 27032987 | Primary care visits | HPACT | October 2013 – March 2014 | 3,543 | 3.4 (NR) | NA
Chang, 2020, 32597993 | Any primary care visit | Those receiving homeless specialized primary care | October 2015- September 2016 | 2,746 | 7.7 (8.1) | NA

Abbreviations. HPACT=homeless patient aligned care teams; N=number; NA=not applicable; NR=not reported; SD=standard deviation.

## H3. Emergency Department

Author, Year, PMID | Outcome Details | Group/Comparators | Timepoint | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size, p-value
Jones, 2018, 29412071 | Any emergency department visit | HPACT | 0–12 months before enrollment | 179 | 1.13 (1.99) | MD (95% CI); 0.15(−0.28; 0.58); p=0.4938^a^
Jones, 2018, 29412071 | Any emergency department visit | HPACT | 0–12 months after enrollment | 179 | 1.28 (2.15) | MD (95% CI); 0.15(−0.28; 0.58); p=0.4938^a^
Jones, 2018, 29412071 | Inappropriate emergency department visit | HPACT | 0–12 months before enrollment | 179 | 0.55 (1.41) | MD (95% CI); −0.08 (−0.32; 0.16), p=0.5294^a^
Jones, 2018, 29412071 | Inappropriate emergency department visit | HPACT | 0–12 months after enrollment | 179 | 0.47 (0.95) | MD (95% CI); −0.08 (−0.32; 0.16), p=0.5294^a^
O’Toole, 2016, 27032987 | Emergency department visits | HPACT | 6 months before enrollment | 3,543 | 3,022 (NR) | Change in emergency department visits from pre to post; −19%
O’Toole, 2016, 27032987 | Emergency department visits | HPACT | 6 months after enrollment | 3,543 | 2,477 (NR) | Change in emergency department visits from pre to post; −19%
Gundlapalli, 2017, 28806373 | Emergency department visits- mean per veteran; HPACT compared with usual care | Usual care - 0 visits | 6 months before enrollment | 23,542 | 0.57 (NR) | Pre-post difference = −0.30
Gundlapalli, 2017, 28806373 | Emergency department visits- mean per veteran; HPACT compared with usual care | Usual care - 0 visits | 6 months after enrollment | 23,542 | 0.27 (NR) | Pre-post difference = −0.30
Gundlapalli, 2017, 28806373 | Emergency department visits- mean per veteran; HPACT compared with usual care | HPACT - 0 visits | 6 months before | 3,987 | 0.34 (NR) | Pre-post difference = 0.14; Adj Difference-in-differences; Usual care versus HPACT; 0.44, p < 0.05
Gundlapalli, 2017, 28806373 | Emergency department visits- mean per veteran; HPACT compared with usual care | HPACT - 0 visits | 6 months after enrollment | 3,987 | 0.48 (NR) | Pre-post difference = 0.14; Adj Difference-in-differences; Usual care versus HPACT; 0.44, p < 0.05
Gundlapalli, 2017, 28806373 | Emergency department visits- mean per veteran; HPACT compared with usual care | Usual care – 1 visit | 6 months before | 23,542 | 1.04 (NR) | Pre-post difference = 0.56
Gundlapalli, 2017, 28806373 | Emergency department visits- mean per veteran; HPACT compared with usual care | Usual care – 1 visit | 6 months after enrollment | 23,542 | 1.60 (NR) | Pre-post difference = 0.56
Gundlapalli, 2017, 28806373 | Emergency department visits- mean per veteran; HPACT compared with usual care | HPACT - 1 visit | 6 months before | 3,987 | 1.47 (NR) | Pre-post difference = −0.58; Adj Difference-in-differences; Usual care versus HPACT; −1.13, p < 0.05
Gundlapalli, 2017, 28806373 | Emergency department visits- mean per veteran; HPACT compared with usual care | HPACT - 1 visit | 6 months after enrollment | 3,987 | 0.89 (NR) | Pre-post difference = −0.58; Adj Difference-in-differences; Usual care versus HPACT; −1.13, p < 0.05
Gundlapalli, 2017, 28806373 | Emergency department visits- mean per veteran; HPACT compared with usual care | Usual care – 2 or more visits | 6 months before | 23,542 | 2.10 (NR) | Pre-post difference = 2.09
Gundlapalli, 2017, 28806373 | Emergency department visits- mean per veteran; HPACT compared with usual care | Usual care – 2 or more visits | 6 months after enrollment | 23,542 | 4.19 (NR) | Pre-post difference = 2.09
Gundlapalli, 2017, 28806373 | Emergency department visits- mean per veteran; HPACT compared with usual care | HPACT – 2 or more visits | 6 months before | 3,987 | 1.47 (NR) | Pre-post difference = −2.34; Adj Difference-in-differences; Usual care versus HPACT; −4.43, p < 0.05
Gundlapalli, 2017, 28806373 | Emergency department visits- mean per veteran; HPACT compared with usual care | HPACT – 2 or more visits | 6 months after enrollment | 3,987 | 0.89 (NR) | Pre-post difference = −2.34; Adj Difference-in-differences; Usual care versus HPACT; −4.43, p < 0.05
Gundlapalli, 2017, 28806373 | Emergency department visits mean per veteran; H-PACT compared with nonenrolled | HPACT - 0 visits | 6 months before | 3,987 | 0.32 (NR) | Pre-post difference = 0.13
Gundlapalli, 2017, 28806373 | Emergency department visits mean per veteran; H-PACT compared with nonenrolled | HPACT - 0 visits | 6 months after enrollment | 3,987 | 0.46 (NR) | Pre-post difference = 0.13
Gundlapalli, 2017, 28806373 | Emergency department visits mean per veteran; H-PACT compared with nonenrolled | Nonenrolled – 0 visits | 6 months before | 24,363 | 0.19 (NR) | Pre-post difference = 0.42; Adj Difference-in-differences; Usual care versus HPACT nonenrolled; 0.29, p < 0.05
Gundlapalli, 2017, 28806373 | Emergency department visits mean per veteran; H-PACT compared with nonenrolled | Nonenrolled – 0 visits | 6 months after enrollment | 24,363 | 0.62 (NR) | Pre-post difference = 0.42; Adj Difference-in-differences; Usual care versus HPACT nonenrolled; 0.29, p < 0.05
Gundlapalli, 2017, 28806373 | Emergency department visits mean per veteran; H-PACT compared with nonenrolled | HPACT - 1 visit | 6 months before | 3,987 | 1.40 (NR) | Pre-post difference = −0.55
Gundlapalli, 2017, 28806373 | Emergency department visits mean per veteran; H-PACT compared with nonenrolled | HPACT - 1 visit | 6 months after enrollment | 3,987 | 0.85 (NR) | Pre-post difference = −0.55
Gundlapalli, 2017, 28806373 | Emergency department visits mean per veteran; H-PACT compared with nonenrolled | Nonenrolled – 1 visit | 6 months before | 24,363 | 1.31 (NR) | Pre-post difference = −0.35; Adj Difference-in-differences; Usual care versus HPACT; −0.20, p < 0.05
Gundlapalli, 2017, 28806373 | Emergency department visits mean per veteran; H-PACT compared with nonenrolled | Nonenrolled – 1 visit | 6 months after enrollment | 24,363 | 0.96 (NR) | Pre-post difference = −0.35; Adj Difference-in-differences; Usual care versus HPACT; −0.20, p < 0.05
Gundlapalli, 2017, 28806373 | Emergency department visits mean per veteran; H-PACT compared with nonenrolled | HPACT – 2 or more visits | 6 months before | 3,987 | 4.51 (NR) | Pre-post difference = −2.24
Gundlapalli, 2017, 28806373 | Emergency department visits mean per veteran; H-PACT compared with nonenrolled | HPACT – 2 or more visits | 6 months after enrollment | 3,987 | 2.28 (NR) | Pre-post difference = −2.24
Gundlapalli, 2017, 28806373 | Emergency department visits mean per veteran; H-PACT compared with nonenrolled | Nonenrolled – 2 or more visits | 6 months before | 24,363 | 3.81 (NR) | Pre-post difference = −1.95; Adj Difference-in-differences; Usual care versus HPACT; −0.29, p < 0.05
Gundlapalli, 2017, 28806373 | Emergency department visits mean per veteran; H-PACT compared with nonenrolled | Nonenrolled – 2 or more visits | 6 months after enrollment | 24,363 | 1.86 (NR) | Pre-post difference = −1.95; Adj Difference-in-differences; Usual care versus HPACT; −0.29, p < 0.05
Gundlapalli, 2017, 28806373 | Emergency and urgent care visits mean per veteran per month | HPACT, High utilizers | 6 months before | 511 | 0.12 (NR) | MD = −0.061^a^; p<0.001
Gundlapalli, 2017, 28806373 | Emergency and urgent care visits mean per veteran per month | HPACT, High utilizers | 6 months after enrollment | 511 | 0.059 (NR) | MD = −0.061^a^; p<0.001
Gundlapalli, 2017, 28806373 | Emergency and urgent care visits mean per veteran per month | HPACT nonenrolled, High utilizers | First 6 months of data | 2,787 | 0.083 (NR) | MD = −0.042^a^; p = NR; Difference-in-differences; HPACT versus nonenrolled; −0.02^a^, p=0.27
Gundlapalli, 2017, 28806373 | Emergency and urgent care visits mean per veteran per month | HPACT nonenrolled, High utilizers | Second 6 months of data | 2,787 | 0.041 (NR) | MD = −0.042^a^; p = NR; Difference-in-differences; HPACT versus nonenrolled; −0.02^a^, p=0.27
Gundlapalli, 2017, 28806373 | Emergency and urgent care visits mean per veteran per month | Usual care, High utilizers | First 6 months of data | 1,689 | 0.029 (NR) | MD = 0.029; p = NR; Difference-in-differences; HPACT versus usual care; −0.09^a^, p=0.89
Gundlapalli, 2017, 28806373 | Emergency and urgent care visits mean per veteran per month | Usual care, High utilizers | Second 6 months of data | 1,689 | 0.058 (NR) | MD = 0.029; p = NR; Difference-in-differences; HPACT versus usual care; −0.09^a^, p=0.89
O’Toole, 2010, 20966377 | Emergency department visits | HOPC | First 6 months of data | 79 | 1.62 (2.53) | MD (95% CI); −0.55 (−0.1.32; 0.22)^a^; p=0.06
O’Toole, 2010, 20966377 | Emergency department visits | HOPC | Second 6 months of data | 79 | 1.07 (2.35) | MD (95% CI); −0.55 (−0.1.32; 0.22)^a^; p=0.06
O’Toole, 2010, 20966377 | Emergency department visits | GIM | First 6 months of data | 98 | 1.21 (1.91) | MD (95% CI); −0.46 (−0.91; −0.01)^a^; p=0.05
O’Toole, 2010, 20966377 | Emergency department visits | GIM | Second 6 months of data | 98 | 0.75 (1.17) | MD (95% CI); −0.46 (−0.91; −0.01)^a^; p=0.05
O’Toole, 2010, 20966377 | Emergency department visits | HOPC | Second 6 months of data | 79 | 1.07 (2.35) | MD (95% CI); 0.32 (−0.22; 0.86)^a^; P=0.27
O’Toole, 2010, 20966377 | Emergency department visits | GIM | Second 6 months of data | 98 | 0.75 (1.17) | MD (95% CI); 0.32 (−0.22; 0.86)^a^; P=0.27
O’Toole, 2010, 20966377 | Emergency Department Visits (Non-Emergency Care) | HOPC | First 6 months of data | 79 | 0.38 (1.13) | MD (95% CI); −0.18 (−0.46; 0.10)^a^; p=0.22
O’Toole, 2010, 20966377 | Emergency Department Visits (Non-Emergency Care) | HOPC | Second 6 months of data | 79 | 0.20 (0.60) | MD (95% CI); −0.18 (−0.46; 0.10)^a^; p=0.22
O’Toole, 2010, 20966377 | Emergency Department Visits (Non-Emergency Care) | GIM | First 6 months of data | 98 | 0.42 (1.00) | MD (95% CI); −0.13 (−0.36; 0.10)^a^; p=0.26
O’Toole, 2010, 20966377 | Emergency Department Visits (Non-Emergency Care) | GIM | Second 6 months of data | 98 | 0.29 (0.59) | MD (95% CI); −0.13 (−0.36; 0.10)^a^; p=0.26
O’Toole, 2010, 20966377 | Emergency Department Visits (Non-Emergency Care) | HOPC | Second 6 months of data | 79 | 0.20 (0.60) | MD (95% CI); −0.09 (−0.27; 0.09)^a^; P=0.29
O’Toole, 2010, 20966377 | Emergency Department Visits (Non-Emergency Care) | GIM | Second 6 months of data | 98 | 0.29 (0.59) | MD (95% CI); −0.09 (−0.27; 0.09)^a^; P=0.29
O’Toole, 2010, 20966377 | Emergency Department Visits (Substance Abuse-Related) | HOPC | First 6 months of data | 79 | 0.46 (1.15) | MD (95C%); −0.03 (−0.49; 0.43)^a^; p<.99
O’Toole, 2010, 20966377 | Emergency Department Visits (Substance Abuse-Related) | HOPC | Second 6 months of data | 79 | 0.43 (1.74) | MD (95C%); −0.03 (−0.49; 0.43)^a^; p<.99
O’Toole, 2010, 20966377 | Emergency Department Visits (Substance Abuse-Related) | GIM | First 6 months of data | 98 | 0.21 (0.64) | MD (95% CI); −0.10 (−0.25; 0.05)^a^; p=0.13
O’Toole, 2010, 20966377 | Emergency Department Visits (Substance Abuse-Related) | GIM | Second 6 months of data | 98 | 0.11 (0.42) | MD (95% CI); −0.10 (−0.25; 0.05)^a^; p=0.13
O’Toole, 2010, 20966377 | Emergency Department Visits (Substance Abuse-Related) | HOPC | Second 6 months of data | 79 | 0.43 (1.74) | MD (95% CI); 0.32 (−0.04; 0.68)^a^; p=0.06
O’Toole, 2010, 20966377 | Emergency Department Visits (Substance Abuse-Related) | GIM | Second 6 months of data | 98 | 0.11 (0.42) | MD (95% CI); 0.32 (−0.04; 0.68)^a^; p=0.06
O’Toole, 2018, 29451116 | Emergency department visits | HPACT | June 2012–January 2014 | 183 | 2.6 (4.4) | MD (95% CI); −0.3 (−1.4; 0.8)^a^; p=0.57
O’Toole, 2018, 29451116 | Emergency department visits | PACT | June 2012–January 2014 | 83 | 2.9 (3.9) | MD (95% CI); −0.3 (−1.4; 0.8)^a^; p=0.57
O’Toole, 2018, 29451116 | Emergency department visits for ambulatory-care-sensitive conditions | HPACT | June 2012–January 2014 | 183 | 0 (0.2) | MD (95% CI); −0.2 (−0.3 ; −0.1)^a^; p=0.04
O’Toole, 2018, 29451116 | Emergency department visits for ambulatory-care-sensitive conditions | PACT | June 2012–January 2014 | 83 | 0.2 (0.6), | MD (95% CI); −0.2 (−0.3 ; −0.1)^a^; p=0.04

Notes.

a Calculated by the research team.

Abbreviations. CI=confidence interval; GIM=general internal medicine; HOPC=homeless oriented primary care; HPACT=homeless patient aligned care teams; MD=mean difference; N=number; NR=not reported; PACT=patient aligned care teams; SD=standard deviation.

## H4. Emergency Department (Non-Comparative)

Author, Year, PMID | Outcome Details | Group/Comparators | Timepoint | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size, p-value
Chang, 2020, 32597993 | Emergency room visit | Those receiving homeless specialized primary care | October 2015-September 2016 | 2,746 | 2.2 (4.2) | NA
O’Toole, 2013, 24148042 | Emergency department visits | Homeless PACT | First 6 months | 127 | 1.0 | NA

Abbreviations. N=number; NA=not applicable; PACT=patient aligned care teams; SD=standard deviation.

## H5. Hospitalization/Inpatient

Author, Year, PMID | Outcome Details | Group/Comparators | Timepoint | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size, p-value
Jones, 2018, 29412071 | Inpatient stay | HPACT | 0–12 months before enrollment | 179 | 0.74 (1.43) | MD (95% CI); −0.04 (−0.35; 028); p=0.8032^a^
Jones, 2018, 29412071 | Inpatient stay | HPACT | 0–12 months after enrollment | 179 | 0.70 (1.60) | MD (95% CI); −0.04 (−0.35; 028); p=0.8032^a^
O’Toole, 2016, 27032987 | Hospitalizations | HPACT | 6 months before enrollment | 3,543 | 812 (NR) | Change in hospitalizations from pre to post; −34.7%
O’Toole, 2016, 27032987 | Hospitalizations | HPACT | 6 months after enrollment | 3,543 | 530 (NR) | Change in hospitalizations from pre to post; −34.7%
O’Toole, 2016, 27032987 | Hospitalizations | HPACT | Second 6 months of data | 1,689 | 0.004 (NR) | Change in hospitalizations from pre to post; −34.7%
O’Toole, 2010, 20966377 | Hospitalization admissions/person | HOPC | First 6 months of data | 79 | 0.46 (0.85) | MD (95% CI); 0.01 (0.32; 0.34)^a^; 0.02 p=0.94
O’Toole, 2010, 20966377 | Hospitalization admissions/person | HOPC | Second 6 months of data | 79 | 0.47 (1.21) | MD (95% CI); 0.01 (0.32; 0.34)^a^; 0.02 p=0.94
O’Toole, 2010, 20966377 | Hospitalization admissions/person | GIM | First 6 months of data | 86 | 0.30 (0.72) | MD (95% CI); −0.15 (−0.32; 0.02)^a^; p=0.11
O’Toole, 2010, 20966377 | Hospitalization admissions/person | GIM | Second 6 months of data | 86 | 0.15 (0.48) | MD (95% CI); −0.15 (−0.32; 0.02)^a^; p=0.11
O’Toole, 2010, 20966377 | Hospitalization admissions/person | HOPC | Second 6 months of data | 79 | 0.47 (1.21) | MD (95% CI); 0.32 (0.04 ; 0.60)^a^; p = 0.0247
O’Toole, 2010, 20966377 | Hospitalization admissions/person | GIM | Second 6 months of data | 86 | 0.15 (0.48) | MD (95% CI); 0.32 (0.04 ; 0.60)^a^; p = 0.0247
O’Toole, 2018, 29451116 | Hospitalizations | HPACT | June 2012–January 2014 | 183 | 0.4 (0.8) | MD (95% CI)^a^; −0.2 (−0.5; 0.1); p=0.06
O’Toole, 2018, 29451116 | Hospitalizations | PACT | June 2012–January 2014 | 83 | 0.6 (1.2) | MD (95% CI)^a^; −0.2 (−0.5; 0.1); p=0.06
O’Toole, 2018, 29451116 | Hospitalizations (not a VA Hospital) | HPACT | June 2012–January 2014 | 183 | 0 (0.1) | MD (95% CI)^a^; −0.1 (−1.5; 1.3); p=0.29
O’Toole, 2018, 29451116 | Hospitalizations (not a VA Hospital) | PACT | June 2012–January 2014 | 83 | 0.1 (9.7) | MD (95% CI)^a^; −0.1 (−1.5; 1.3); p=0.29

Notes.

a Calculated by the research team.

Abbreviations. CI=confidence interval; GIM=general internal medicine; HOPC=homeless oriented primary care; HPACT=homeless patient aligned care teams; MD=mean difference; N=number; NR=not reported; PACT=patient aligned care teams; SD=standard deviation.

## H6. Hospitalization/Inpatient (Non-Comparative)

Author, Year, PMID | Outcome Details | Group/Comparators | Timepoint | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size, p-value
Trivedi, 2018, 30151996 | Total VA-and Medicare -financed acute care hospitalizations | Veterans with higher reliance | 12 months | 1,211 | 1.49 (1.26; 1.71) | NA
Trivedi, 2018, 30151996 | VA-financed acute care hospitalizations | Veterans with higher reliance | 12 months | 1,211 | 0.63 (0.48; 0.78) | NA
Trivedi, 2018, 30151996 | Medicare-financed acute care hospitalizations | Veterans with higher reliance | 12 months | 1,211 | 0.85 (0.72; 0.98) | NA
Trivedi, 2018, 30151996 | Medicare acute hospitalizations | Veterans with higher reliance- Overall | 12 months | 1,211 | 0.71 (0.60; 0.82)^a^ | NA
Trivedi, 2018, 30151996 | VA acute hospitalizations | Veterans with higher reliance-Overall | 12 months | 1,211 | 0.55 (0.39; 0.71)^a^ | NA
Trivedi, 2018, 30151996 | Medicare acute hospitalizations | Veterans with higher reliance-Low intensity (0–22 visits) | 12 months | 1,211 | 0.21 (0.12; 0.31)^a^ | NA
Trivedi, 2018, 30151996 | VA acute hospitalizations | Veterans with higher reliance-Low intensity (0–22 visits) | 12 months | 1,211 | 0.27 (0.11; 0.43)^a^ | NA
Trivedi, 2018, 30151996 | Medicare acute hospitalizations | Veterans with higher reliance- Medium intensity (23–55 visits) | 12 months | 1,211 | 0.64 (0.51; 0.78)^a^ | NA
Trivedi, 2018, 30151996 | VA acute hospitalizations | Veterans with higher reliance- Medium intensity (23–55 visits) | 12 months | 1,211 | 0.50 (0.26; 0.73)^a^ | NA
Trivedi, 2018, 30151996 | Medicare acute hospitalizations | Veterans with higher reliance- High intensity (>55 visits) | 12 months | 1,211 | 1.31 (1.04; 1.58)^a^ | NA
Trivedi, 2018, 30151996 | VA acute hospitalizations | Veterans with higher reliance- High intensity (>55 visits) | 12 months | 1,211 | 1.17 (0.70; 1.63)^a^ | NA

Notes.

a Adjusted mean annual hospitalizations.

Abbreviations. N=number; NA=not applicable; SD=standard deviation.

## H7. Specialized Care/Other

Author, Year, PMID | Outcome Details | Group/Comparators | Follow-up | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size, p-value
Jones, 2018, 29412071 | Medical specialist | HPACT | 0–12 months before enrollment | 179 | 1.28 (2.18) | MD (95% CI); 1.44 (0.31; 2.56), p=0.0122^a^
Jones, 2018, 29412071 | Medical specialist | HPACT | 0–12 months after enrollment | 179 | 2.72 (7.33) | MD (95% CI); 1.44 (0.31; 2.56), p=0.0122^a^
Jones, 2018, 29412071 | Mental health specialist | HPACT | 0–12 months before enrollment | 179 | 2.97 (5.25) | MD (95% CI); 0.14 (−0.98; 1.25), p=0.8054^a^
Jones, 2018, 29412071 | Mental health specialist | HPACT | 0–12 months after enrollment | 179 | 3.11 (5.49) | MD (95% CI); 0.14 (−0.98; 1.25), p=0.8054^a^
Jones, 2018, 29412071 | Addiction specialist visit | HPACT | 0–12 months before enrollment | 179 | 0.31 (0.71) | MD (95% CI); −0.07 (−0.22; 0.08), p=0.3550^a^
Jones, 2018, 29412071 | Addiction specialist visit | HPACT | 0–12 months after enrollment | 179 | 0.24 (0.72) | MD (95% CI); −0.07 (−0.22; 0.08), p=0.3550^a^
Gundlapalli, 2017, 28806373 | Dental service | HPACT, High utilizers | 6 months before enrollment | 511 | 0.013 (NR) | MD = 0.001^a^; p = 0.97
Gundlapalli, 2017, 28806373 | Dental service | HPACT, High utilizers | 6 months after enrollment | 511 | 0.014 (NR) | MD = 0.001^a^; p = 0.97
Gundlapalli, 2017, 28806373 | Dental service | HPACT nonenrolled, High utilizers | First 6 months of data | 2,787 | 0.013 (NR) | MD = −0.001^a^; p = NR; Difference-in-differences; HPACT versus nonenrolled; 0.002^a^, p=0.0059
Gundlapalli, 2017, 28806373 | Dental service | HPACT nonenrolled, High utilizers | Second 6 months of data | 2,787 | 0.012 (NR) | MD = −0.001^a^; p = NR; Difference-in-differences; HPACT versus nonenrolled; 0.002^a^, p=0.0059
Gundlapalli, 2017, 28806373 | Dental service | Usual care, High utilizers | First 6 months of data | 1,689 | 0.0037 (NR) | MD = 0.0015^a^; p = NR; Difference-in-differences; HPACT versus usual care; −0.0004^a^, p=0.056
Gundlapalli, 2017, 28806373 | Dental service | Usual care, High utilizers | Second 6 months of data | 1,689 | 0.0052 (NR) | MD = 0.0015^a^; p = NR; Difference-in-differences; HPACT versus usual care; −0.0004^a^, p=0.056
Gundlapalli, 2017, 28806373 | Diagnostic (laboratory and imaging) | HPACT, High utilizers | 6 months before enrollment | 511 | 0.19 (NR) | MD = −0.05^a^; p=0.039
Gundlapalli, 2017, 28806373 | Diagnostic (laboratory and imaging) | HPACT, High utilizers | 6 months after enrollment | 511 | 0.14 (NR) | MD = −0.05^a^; p=0.039
Gundlapalli, 2017, 28806373 | Diagnostic (laboratory and imaging) | HPACT nonenrolled, High utilizers | First 6 months of data | 2,787 | 0.15 (NR) | MD = −0.05^a^; p = NR; Difference-in-differences; HPACT versus nonenrolled; 0^a^, p=0.016
Gundlapalli, 2017, 28806373 | Diagnostic (laboratory and imaging) | HPACT nonenrolled, High utilizers | Second 6 months of data | 2,787 | 0.10 (NR) | MD = −0.05^a^; p = NR; Difference-in-differences; HPACT versus nonenrolled; 0^a^, p=0.016
Gundlapalli, 2017, 28806373 | Diagnostic (laboratory and imaging) | Usual care, High utilizers | First 6 months of data | 1,689 | 0.063 (NR) | MD = 0.028; p = NR; Difference-in-differences; HPACT versus usual care; −0.078^a^, p=0.64
Gundlapalli, 2017, 28806373 | Diagnostic (laboratory and imaging) | Usual care, High utilizers | Second 6 months of data | 1,689 | 0.091 (NR) | MD = 0.028; p = NR; Difference-in-differences; HPACT versus usual care; −0.078^a^, p=0.64
Gundlapalli, 2017, 28806373 | Medical specialty | HPACT, High utilizers | 6 months before enrollment | 511 | 0.059 (NR) | MD = −0.007^a^; p=0.24
Gundlapalli, 2017, 28806373 | Medical specialty | HPACT, High utilizers | 6 months after enrollment | 511 | 0.052 (NR) | MD = −0.007^a^; p=0.24
Gundlapalli, 2017, 28806373 | Medical specialty | HPACT nonenrolled, High utilizers | First 6 months of data | 2,787 | 0.058 (NR) | MD = −0.009^a^; p = NR; Difference-in-differences; HPACT versus nonenrolled; 0.002^a^, p=0.0022
Gundlapalli, 2017, 28806373 | Medical specialty | HPACT nonenrolled, High utilizers | Second 6 months of data | 2,787 | 0.049 (NR) | MD = −0.009^a^; p = NR; Difference-in-differences; HPACT versus nonenrolled; 0.002^a^, p=0.0022
Gundlapalli, 2017, 28806373 | Medical specialty | Usual care, High utilizers | First 6 months of data | 1,689 | 0.027 (NR) | MD = 0.009^a^; p = NR; Difference-in-differences; HPACT versus usual care; −0.016^a^, p=0.42
Gundlapalli, 2017, 28806373 | Medical specialty | Usual care, High utilizers | Second 6 months of data | 1,689 | 0.036 (NR) | MD = 0.009^a^; p = NR; Difference-in-differences; HPACT versus usual care; −0.016^a^, p=0.42
Gundlapalli, 2017, 28806373 | Mental health | HPACT, High utilizers | 6 months before enrollment | 511 | 0.2 (NR) | MD = −0.04^a^; p=0.0031
Gundlapalli, 2017, 28806373 | Mental health | HPACT, High utilizers | 6 months after enrollment | 511 | 0.16 (NR) | MD = −0.04^a^; p=0.0031
Gundlapalli, 2017, 28806373 | Mental health | HPACT nonenrolled, High utilizers | First 6 months of data | 2,787 | 0.16 (NR) | MD = −0.04^a^; p=NR; Difference-in-differences; HPACT versus nonenrolled; 0^a^, p=0.22
Gundlapalli, 2017, 28806373 | Mental health | HPACT nonenrolled, High utilizers | Second 6 months of data | 2,787 | 0.12 (NR) | MD = −0.04^a^; p=NR; Difference-in-differences; HPACT versus nonenrolled; 0^a^, p=0.22
Gundlapalli, 2017, 28806373 | Mental health | Usual care, High utilizers | First 6 months of data | 1,689 | 0.084 (NR) | MD = 0.026^a^; p=NR; Difference-in-differences; HPACT versus usual care; −0.066^a^, p=0.88
Gundlapalli, 2017, 28806373 | Mental health | Usual care, High utilizers | Second 6 months of data | 1,689 | 0.11 (NR) | MD = 0.026^a^; p=NR; Difference-in-differences; HPACT versus usual care; −0.066^a^, p=0.88
Gundlapalli, 2017, 28806373 | Rehabilitation | HPACT, High utilizers | 6 months before enrollment | 511 | 0.062 (NR) | MD = −0.014^a^; p=0.0068
Gundlapalli, 2017, 28806373 | Rehabilitation | HPACT, High utilizers | 6 months after enrollment | 511 | 0.048 (NR) | MD = −0.014^a^; p=0.0068
Gundlapalli, 2017, 28806373 | Rehabilitation | HPACT nonenrolled, High utilizers | First 6 months of data | 2,787 | 0.062 (NR) | MD = −0.014^a^; p=NR; Difference-in-differences; HPACT versus nonenrolled; 0^a^, p=0.014
Gundlapalli, 2017, 28806373 | Rehabilitation | HPACT nonenrolled, High utilizers | Second 6 months of data | 2,787 | 0.048 (NR) | MD = −0.014^a^; p=NR; Difference-in-differences; HPACT versus nonenrolled; 0^a^, p=0.014
Gundlapalli, 2017, 28806373 | Rehabilitation | Usual care, High utilizers | First 6 months of data | 1,689 | 0.037 (NR) | MD = 0.012^a^; p=NR; Difference-in-differences; HPACT versus usual care; −0.026^a^, p=0.049
Gundlapalli, 2017, 28806373 | Rehabilitation | Usual care, High utilizers | Second 6 months of data | 1,689 | 0.049 (NR) | MD = 0.012^a^; p=NR; Difference-in-differences; HPACT versus usual care; −0.026^a^, p=0.049
Gundlapalli, 2017, 28806373 | Social work | HPACT, High utilizers | 6 months before enrollment | 511 | 0.038 (NR) | MD = −0.012^a^; p=0.008
Gundlapalli, 2017, 28806373 | Social work | HPACT, High utilizers | 6 months after enrollment | 511 | 0.026 (NR) | MD = −0.012^a^; p=0.008
Gundlapalli, 2017, 28806373 | Social work | HPACT nonenrolled, High utilizers | First 6 months of data | 2,787 | 0.033 (NR) | MD = −0.013^a^; p=NR; Difference-in-differences; HPACT versus nonenrolled; 0.001^a^, p=0.062
Gundlapalli, 2017, 28806373 | Social work | HPACT nonenrolled, High utilizers | Second 6 months of data | 2,787 | 0.02 (NR) | MD = −0.013^a^; p=NR; Difference-in-differences; HPACT versus nonenrolled; 0.001^a^, p=0.062
Gundlapalli, 2017, 28806373 | Social work | Usual care, High utilizers | First 6 months of data | 1,689 | 0.0094 (NR) | MD = 0.0066^a^; p=NR; Difference-in-differences; HPACT versus usual care; −0.0186^a^, p=0.24
Gundlapalli, 2017, 28806373 | Social work | Usual care, High utilizers | Second 6 months of data | 1,689 | 0.016 (NR) | MD = 0.0066^a^; p=NR; Difference-in-differences; HPACT versus usual care; −0.0186^a^, p=0.24
Gundlapalli, 2017, 28806373 | Homeless Care | HPACT, High utilizers | 6 months before enrollment | 511 | 0.18 (NR) | MD = 0.02^a^; p<0.001
Gundlapalli, 2017, 28806373 | Homeless Care | HPACT, High utilizers | 6 months after enrollment | 511 | 0.20 (NR) | MD = 0.02^a^; p<0.001
Gundlapalli, 2017, 28806373 | Homeless Care | HPACT nonenrolled, High utilizers | First 6 months of data | 2,787 | 0.12 (NR) | MD = −0.01^a^; p = NR; Difference-in-differences; HPACT versus nonenrolled; 0.03^a^, p<0.001
Gundlapalli, 2017, 28806373 | Homeless Care | HPACT nonenrolled, High utilizers | Second 6 months of data | 2,787 | 0.11 (NR) | MD = −0.01^a^; p = NR; Difference-in-differences; HPACT versus nonenrolled; 0.03^a^, p<0.001
Gundlapalli, 2017, 28806373 | Homeless Care | Usual care, High utilizers | First 6 months of data | 1,689 | 0.046 (NR) | MD = 0.024^a^; p = NR; Difference-in-differences; HPACT versus usual care; −0.004^a^, p<0.001
Gundlapalli, 2017, 28806373 | Homeless Care | Usual care, High utilizers | Second 6 months of data | 1,689 | 0.07 | MD = 0.024^a^; p = NR; Difference-in-differences; HPACT versus usual care; −0.004^a^, p<0.001
Gundlapalli, 2017, 28806373 | Substance abuse | HPACT, High utilizers | 6 months before enrollment | 511 | 0.2 (NR) | MD = −0.05^a^; p=0.72
Gundlapalli, 2017, 28806373 | Substance abuse | HPACT, High utilizers | 6 months after enrollment | 511 | 0.15 (NR) | MD = −0.05^a^; p=0.72
Gundlapalli, 2017, 28806373 | Substance abuse | HPACT nonenrolled, High utilizers | First 6 months of data | 2,787 | 0.16 (NR) | MD = −0.05^a^; p=NR; Difference-in-differences; HPACT versus nonenrolled; 0^a^, p=0.47
Gundlapalli, 2017, 28806373 | Substance abuse | | Second 6 months of data | 2,787 | 0.11 (NR) | MD = −0.05^a^; p=NR; Difference-in-differences; HPACT versus nonenrolled; 0^a^, p=0.47
Gundlapalli, 2017, 28806373 | Substance abuse | Usual care, High utilizers | First 6 months of data | 1,689 | 0.05 (NR) | MD = 0.018^a^; p=NR; Difference-in-differences; HPACT versus usual care; −0.068^a^, p=0.14
Gundlapalli, 2017, 28806373 | Substance abuse | Usual care, High utilizers | Second 6 months of data | 1,689 | 0.068 (NR) | MD = 0.018^a^; p=NR; Difference-in-differences; HPACT versus usual care; −0.068^a^, p=0.14
Gundlapalli, 2017, 28806373 | Surgery | HPACT, High utilizers | 6 months before enrollment | 511 | 0.0084 (NR) | MD = −0.0032 ^a^; p=0.019
Gundlapalli, 2017, 28806373 | Surgery | HPACT, High utilizers | 6 months after enrollment | 511 | 0.0052 (NR), | MD = −0.0032 ^a^; p=0.019
Gundlapalli, 2017, 28806373 | Surgery | HPACT nonenrolled, High utilizers | First 6 months of data | 2,787 | 0.0059 (NR) | MD =−0.0019^a^; p=NR; Difference-in-differences; HPACT versus nonenrolled; −0.001^a^, p=0.32
Gundlapalli, 2017, 28806373 | Surgery | HPACT nonenrolled, High utilizers | Second 6 months of data | 2,787 | 0.004 (NR) | MD =−0.0019^a^; p=NR; Difference-in-differences; HPACT versus nonenrolled; −0.001^a^, p=0.32
Gundlapalli, 2017, 28806373 | Surgery | Usual care, High utilizers | First 6 months of data | 1,689 | 0.003 (NR) | MD = 0.001^a^; p=NR; Difference-in-differences; HPACT versus usual care; −0.004^a^, p=0.83
Gundlapalli, 2017, 28806373 | Surgery | Usual care, High utilizers | | | | MD = 0.001^a^; p=NR; Difference-in-differences; HPACT versus usual care; −0.004^a^, p=0.83
Gundlapalli, 2017, 28806373 | Surgical specialty | HPACT, High utilizers | 6 months before enrollment | 511 | 0.031 (NR) | MD = −0.009^a^; p=0.76
Gundlapalli, 2017, 28806373 | Surgical specialty | HPACT, High utilizers | 6 months after enrollment | 511 | 0.022 (NR) | MD = −0.009^a^; p=0.76
Gundlapalli, 2017, 28806373 | Surgical specialty | HPACT nonenrolled, High utilizers | First 6 months of data | 2,787 | 0.024 (NR) | MD = −0.006^a^; p=NR; Difference-in-differences; HPACT versus nonenrolled; −0.003^a^, p=0.6
Gundlapalli, 2017, 28806373 | Surgical specialty | HPACT nonenrolled, High utilizers | Second 6 months of data | 2,787 | 0.018 (NR) | MD = −0.006^a^; p=NR; Difference-in-differences; HPACT versus nonenrolled; −0.003^a^, p=0.6
Gundlapalli, 2017, 28806373 | Surgical specialty | Usual care, High utilizers | First 6 months of data | 1,689 | 0.01 (NR) | MD = 0.005^a^; p=NR; Difference-in-differences; HPACT versus usual care; −0.01^a^, p=0.17
Gundlapalli, 2017, 28806373 | Surgical specialty | Usual care, High utilizers | Second 6 months of data | 1,689 | 0.015 (NR) | MD = 0.005^a^; p=NR; Difference-in-differences; HPACT versus usual care; −0.01^a^, p=0.17
O’Toole, 2018, 29451116 | Specialty care visits | HPACT | June 2012–January 2014 | 183 | 3.1 (5.0) | MD (95% CI)^a^; −0.5 (−1.8 ; 0.8); p=0.41
O’Toole, 2018, 29451116 | Specialty care visits | PACT | June 2012–January 2014 | 83 | 3.6 (4.5) | MD (95% CI)^a^; −0.5 (−1.8 ; 0.8); p=0.41
O’Toole, 2018, 29451116 | Social work visits | HPACT | June 2012–January 2014 | 183 | 4.6 (3.7) | MD (95% CI)^a^; 1.9 (1.0 ; 2.8); p=0.001
O’Toole, 2018, 29451116 | Social work visits | PACT | June 2012–January 2014 | 83 | 2.7 (2.1) | MD (95% CI)^a^; 1.9 (1.0 ; 2.8); p=0.001
O’Toole, 2018, 29451116 | Mental health care visits | HPACT | June 2012–January 2014 | 183 | 8.8 (11.8) | MD (95% CI)^a^; −4.6 (−7.9 ; −1.3); p=0.01
O’Toole, 2018, 29451116 | Mental health care visits | PACT | June 2012–January 2014 | 83 | 13.4 (14.3) | MD (95% CI)^a^; −4.6 (−7.9 ; −1.3); p=0.01
O’Toole, 2018, 29451116 | 30-day prescription drug fills | HPACT | June 2012–January 2014 | 183 | 40.5 (39.5) | MD (95% CI)^a^; −18.3 (−29.9 ; −6.7); p=0.001
O’Toole, 2018, 29451116 | 30-day prescription drug fills | PACT | June 2012–January 2014 | 83 | 58.8 (53.9) | MD (95% CI)^a^; −18.3 (−29.9 ; −6.7); p=0.001

Notes.

a Calculated by the research team.

Abbreviations. CI=confidence interval; GIM=general internal medicine; HOPC=homeless oriented primary care; MD=mean difference; N=number; NR=not reported; SD=standard deviation.

## H8. Specialized Care/Other (Non-Comparative)

Author, Year, PMID | Outcome Details | Group/Comparators | Follow-up | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size, p-value
O’Toole, 2013, 24148042 | Mental health care | Homeless PACT | First 6 months | 127 | 12.0 | NA
O’Toole, 2013, 24148042 | Specialty care | Homeless PACT | First 6 months | 127 | 6.9 | NA
O’Toole, 2016, 27032987 | Specialty clinic visits | HPACT | October 2013 – March 2014 | 3,543 | 1.5 (NR) | NA
O’Toole, 2016, 27032987 | HPACT member visits (excluding PCP visits) | HPACT | October 2013 – March 2014 | 3,543 | 5.9 (NR) | NA
Chang, 2020, 32597993 | Mental health care visit | Those receiving homeless specialized primary care | October 2015-September 2016 | 2,746 | 34.9 (39.1) | NA
Chang, 2020, 32597993 | Specialty care visit | Those receiving homeless specialized primary care | October 2015-September 2016 | 2,746 | 2.6 (4.0) | NA
Chang, 2020, 32597993 | Other visits | Those receiving homeless specialized primary care | October 2015-September 2016 | 2,746 | 15.4 (18.9) | NA

Abbreviations. N=number; NA=not applicable; PACT=patient aligned care teams; PCP=primary care provider; SD=standard deviation.

## H9. Patient Experience/Satisfaction

Author, Year, PMID | Outcome Details | Group/Comparators | Timepoint | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size, p-value
O’Toole, 2018, 29451116 | Staff are respectful | HPACT | June 2012–January 2014 | 183 | 1.5 (0.7) | MD (95% CI)^a^; 0.1 (−0.1; 0.3); p=0.66
O’Toole, 2018, 29451116 | Staff are respectful | PACT | June 2012–January 2014 | 83 | 1.4 (0.6) | MD (95% CI)^a^; 0.1 (−0.1; 0.3); p=0.66
O’Toole, 2018, 29451116 | Staff are sensitive do needs | HPACT | June 2012–January 2014 | 183 | 1.6 (0.9) | MD (95% CI)^a^; 0 (−0.2; 0.2); p=0.84
O’Toole, 2018, 29451116 | Staff are sensitive do needs | PACT | June 2012–January 2014 | 83 | 1.6 (0.9) | MD (95% CI)^a^; 0 (−0.2; 0.2); p=0.84
O’Toole, 2018, 29451116 | Staff not as competent as staff in non-VA care | HPACT | June 2012–January 2014 | 183 | 4.3 (1.1) | MD (95% CI)^a^; 0.3 (0.01; 0.6); p=0.07
O’Toole, 2018, 29451116 | Staff not as competent as staff in non-VA care | PACT | June 2012–January 2014 | 83 | 4.0 (1.2) | MD (95% CI)^a^; 0.3 (0.01; 0.6); p=0.07
O’Toole, 2018, 29451116 | Care is helpful | HPACT | June 2012–January 2014 | 183 | 1.3 (0.7) | MD (95% CI)^a^; −0.1 (−0.3; 0.1); p=0.20
O’Toole, 2018, 29451116 | Care is helpful | PACT | June 2012–January 2014 | 83 | 1.4 (0.9) | MD (95% CI)^a^; −0.1 (−0.3; 0.1); p=0.20
O’Toole, 2018, 29451116 | Care is better than elsewhere | HPACT | June 2012–January 2014 | 183 | 1.4 (0.8) | MD (95% CI)^a^; −0.2 (−0.4; 0.02); p=0.36
O’Toole, 2018, 29451116 | Care is better than elsewhere | PACT | June 2012–January 2014 | 83 | 1.6 (0.9) | MD (95% CI)^a^; −0.2 (−0.4; 0.02); p=0.36
O’Toole, 2018, 29451116 | Long wait | HPACT | June 2012–January 2014 | 183 | 3.6 (1.3) | MD (95% CI)^a^; 0.2 (−0.1; 0.5); p=0.31
O’Toole, 2018, 29451116 | Long wait | PACT | June 2012–January 2014 | 83 | 3.4 (1.3) | MD (95% CI)^a^; 0.2 (−0.1; 0.5); p=0.31
O’Toole, 2018, 29451116 | More affordable that non-VA care | HPACT | June 2012–January 2014 | 183 | 1.2 (0.7) | MD (95% CI)^a^; 0.1 (−0.1; 0.3); p=0.54
O’Toole, 2018, 29451116 | More affordable that non-VA care | PACT | June 2012–January 2014 | 83 | 1.1 (0.4), | MD (95% CI)^a^; 0.1 (−0.1; 0.3); p=0.54
O’Toole, 2018, 29451116 | All questions answered | HPACT | June 2012–January 2014 | 183 | 1.6 (1.0) | MD (95% CI)^a^; −0.2 (−0.5; 0.1); p=0.36
O’Toole, 2018, 29451116 | All questions answered | PACT | June 2012–January 2014 | 83 | 1.8 (1.0) | MD (95% CI)^a^; −0.2 (−0.5; 0.1); p=0.36
O’Toole, 2018, 29451116 | Included in care decisions | HPACT | June 2012–January 2014 | 183 | 1.6 (1.0) | MD (95% CI)^a^; −0.1 (−0.4; 0.2); p=0.85
O’Toole, 2018, 29451116 | Included in care decisions | PACT | June 2012–January 2014 | 83 | 1.7 (1.0) | MD (95% CI)^a^; −0.1 (−0.4; 0.2); p=0.85
O’Toole, 2018, 29451116 | Provider listens to you | HPACT | June 2012–January 2014 | 183 | 1.5 (0.9) | MD (95% CI)^a^; −0.1 (−0.3; 0.1); p=0.31
O’Toole, 2018, 29451116 | Provider listens to you | PACT | June 2012–January 2014 | 83 | 1.6 (1.0) | MD (95% CI)^a^; −0.1 (−0.3; 0.1); p=0.31
O’Toole, 2018, 29451116 | Get everything you need without being sent elsewhere | HPACT | June 2012–January 2014 | 183 | 1.8 (1.1) | MD (95% CI)^a^; −0.2 (−0.5; 0.1); p=0.26
O’Toole, 2018, 29451116 | Get everything you need without being sent elsewhere | PACT | June 2012–January 2014 | 83 | 2.0 (1.2) | MD (95% CI)^a^; −0.2 (−0.5; 0.1); p=0.26
O’Toole, 2018, 29451116 | Treated better because homeless | HPACT | June 2012–January 2014 | 183 | 3.5 (1.6) | MD (95% CI)^a^; −0.1 (−0.5; 0.3); p=0.66
O’Toole, 2018, 29451116 | Treated better because homeless | PACT | June 2012–January 2014 | 83 | 3.6 (1.4) | MD (95% CI)^a^; −0.1 (−0.5; 0.3); p=0.66
O’Toole, 2018, 29451116 | Treated worse because homeless | HPACT | June 2012–January 2014 | 183 | 4.2 (1.3) | MD (95% CI)^a^; −0.1 (−0.4; 0.2); p=0.65
O’Toole, 2018, 29451116 | Treated worse because homeless | PACT | June 2012–January 2014 | 83 | 4.3 (1.2) | MD (95% CI)^a^; −0.1 (−0.4; 0.2); p=0.65
O’Toole, 2018, 29451116 | Hard time getting there | HPACT | June 2012–January 2014 | 183 | 3.6 (1.5) | MD (95% CI)^a^; −0.2 (−0.6; 0.2); p=0.44
O’Toole, 2018, 29451116 | Hard time getting there | PACT | June 2012–January 2014 | 83 | 3.8 (1.4) | MD (95% CI)^a^; −0.2 (−0.6; 0.2); p=0.44
O’Toole, 2018, 29451116 | Too much bureaucracy | HPACT | June 2012–January 2014 | 183 | 3.5 (1.5) | MD (95% CI)^a^; 0.2 (−0.2; 0.6); p=0.34
O’Toole, 2018, 29451116 | Too much bureaucracy | PACT | June 2012–January 2014 | 83 | 3.3 (1.5) | MD (95% CI)^a^; 0.2 (−0.2; 0.6); p=0.34
Kertesz, 2021, 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores and Unfavorable experiences - Relationship | HPACT | 2015–2017 | 3394 | 3.20 (0.56) | MD (95% CI)^a^; 0.11 (0.08; 0.14); p<0.001
Kertesz, 2021, 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores and Unfavorable experiences - Relationship | Mainstream PACT | 2015–2017 | 2372 | 3.09 (0.60) | MD (95% CI)^a^; 0.11 (0.08; 0.14); p<0.001
Kertesz, 2021, 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores and Unfavorable experiences - Cooperation | HPACT | 2015–2017 | 3394 | 2.79 (0.74) | MD (95% CI)^a^; 0.14 (0.10; 0.18); p<0.001
Kertesz, 2021, 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores and Unfavorable experiences - Cooperation | Mainstream PACT | 2015–2017 | 2372 | 2.65 (0.79) | MD (95% CI)^a^; 0.14 (0.10; 0.18); p<0.001
Kertesz, 2021, 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores and Unfavorable experiences – Access/Coordination | HPACT | 2015–2017 | 3394 | 3.07 (0.52) | MD (95% CI)^a^; 0.12 (0.09; 0.15); p<0.001
Kertesz, 2021, 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores and Unfavorable experiences – Access/Coordination | Mainstream PACT | 2015–2017 | 2372 | 2.95 (0.55) | MD (95% CI)^a^; 0.12 (0.09; 0.15); p<0.001
Kertesz, 2021, 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores and Unfavorable experiences – Specific needs | HPACT | 2015–2017 | 3394 | 3.02 (0.61) | MD (95% CI)^a^; 0.2 (0.17; 0.23); p<0.001
Kertesz, 2021, 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores and Unfavorable experiences – Specific needs | Mainstream PACT | 2015–2017 | 2372 | 2.82 (0.67) | MD (95% CI)^a^; 0.2 (0.17; 0.23); p<0.001
Kertesz, 2021, 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores -Relationship, Weighted and Adjusted Estimate (SE) | HPACT | 2015–2017 | 3394 | 3.21 (0.03) | p<.001
Kertesz, 2021, 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores -Relationship, Weighted and Adjusted Estimate (SE) | Mainstream PACT | 2015–2017 | 2372 | 3.05 (0.03) | p<.001
Kertesz, 2021 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores -Cooperation, Weighted and Adjusted Estimate (SE) | HPACT | 2015–2017 | 3394 | 2.82 (0.04) | p<.001
Kertesz, 2021 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores -Cooperation, Weighted and Adjusted Estimate (SE) | Mainstream PACT | 2015–2017 | 2372 | 2.64 (0.04) | p<.001
Kertesz, 2021 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores - Access/Coordination, Adjusted Estimate (SE) | HPACT | 2015–2017 | 3394 | 3.07 (0.03) | p<.001
Kertesz, 2021 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores - Access/Coordination, Adjusted Estimate (SE) | Mainstream PACT | 2015–2017 | 2372 | 2.92 (0.03) | p<.001
Kertesz, 2021 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores - Homeless-specific needs, Adjusted Estimate (SE) | HPACT | 2015–2017 | 3394 | 3.01 (0.03) | p<.001
Kertesz, 2021 33827104 | Primary Care Quality-Homeless (PCQ-H) Scores - Homeless-specific needs, Adjusted Estimate (SE) | Mainstream PACT | 2015–2017 | 2372 | 2.79 (0.03) | p<.001
Kertesz, 2013, 24148052 | Primary Care Quality Homeless Scores - Relationship | Tailored | January 2011–March 2012 | 94 | 3.38 (0.97) | MD (95% CI); −0.13 (−0.44; 0.18),; p=0.4123^a^
Kertesz, 2013, 24148052 | Primary Care Quality Homeless Scores - Relationship | Mainstream VA | January 2011–March 2012 | 312 | 3.25 (1.44)^a^ | MD (95% CI); −0.13 (−0.44; 0.18),; p=0.4123^a^
Kertesz, 2013, 24148052 | Primary Care Quality-Homeless Scores - Cooperation | Tailored | January 2011–March 2012 | 94 | 2.96 (1.45) | MD (95% CI); −0.10 (−0.46; 0.26),; p=0.5840^a^
Kertesz, 2013, 24148052 | Primary Care Quality-Homeless Scores - Cooperation | Mainstream VA | January 2011–March 2012 | 312 | 2.86 (1.58)^a^ | MD (95% CI); −0.10 (−0.46; 0.26),; p=0.5840^a^
Kertesz, 2013, 24148052 | Primary Care Quality-Homeless Scores - Access/coordination | Tailored | January 2011–March 2012 | 94 | 3.19 (0.97) | MD (95% CI); −0.04 (−0.34; 0.26),; p=0.7959^a^
Kertesz, 2013, 24148052 | Primary Care Quality-Homeless Scores - Access/coordination | Mainstream VA | January 2011–March 2012 | 312 | 3.15 (1.40)^a^ | MD (95% CI); −0.04 (−0.34; 0.26),; p=0.7959^a^
Kertesz, 2013, 24148052 | Primary Care Quality-Homeless Scores - Homeless-specific | Tailored | January 2011–March 2012 | 94 | 3.38 (1.07) | MD (95% CI); −0.19 (−0.45 ; 0.07),; p=0.1488^a^
Kertesz, 2013, 24148052 | Primary Care Quality-Homeless Scores - Homeless-specific | Mainstream VA | January 2011–March 2012 | 312 | 3.19 (1.13)^a^ | MD (95% CI); −0.19 (−0.45 ; 0.07),; p=0.1488^a^

Notes.

a Calculated by the research team.

Abbreviations. CI=confidence interval; HPACT=homeless patient aligned care teams; MD=mean difference; N=number; NR=not reported; PACT=patient aligned care teams; SE=standard error; SD=standard deviation.

## H10. Cost

Author, Year, PMID | Outcome Details | Group/Comparators | Follow-up | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size, p-value
O’Toole, 2018, 29451116 | Costs – Overall | HPACT | June 2012–January 2014 | 183 | 28,036 (27,036) | MD (95% CI)^a^; −9,352 (−17,281; −1,422); p=0.04
O’Toole, 2018, 29451116 | Costs – Overall | PACT | June 2012–January 2014 | 83 | 37,415 (36,872) | MD (95% CI)^a^; −9,352 (−17,281; −1,422); p=0.04
O’Toole, 2018, 29451116 | Costs – Specialty care | HPACT | June 2012–January 2014 | 183 | 1,824 (3,838) | MD (95% CI)^a^; −56 (−1.002; 890); p=0.90
O’Toole, 2018, 29451116 | Costs – Specialty care | PACT | June 2012–January 2014 | 83 | 1,880 (3,131) | MD (95% CI)^a^; −56 (−1.002; 890); p=0.90
O’Toole, 2018, 29451116 | Costs – Mental Health-related substance abuse treatment | HPACT | June 2012–January 2014 | 183 | 3,378 (4,759) | MD (95% CI)^a^; −1,392 (−2,658; −125); p=0.03
O’Toole, 2018, 29451116 | Costs – Mental Health-related substance abuse treatment | PACT | June 2012–January 2014 | 83 | 4,770 (5,084) | MD (95% CI)^a^; −1,392 (−2,658; −125); p=0.03
O’Toole, 2018, 29451116 | Costs – Non VA-based care | HPACT | June 2012–January 2014 | 183 | 19 (252) | MD (95% CI)^a^; −1,016 (−2,222; 190); p=0.27
O’Toole, 2018, 29451116 | Costs – Non VA-based care | PACT | June 2012–January 2014 | 83 | 1,035 (8,298) | MD (95% CI)^a^; −1,016 (−2,222; 190); p=0.27
O’Toole, 2018, 29451116 | Costs – Prescription drugs | HPACT | June 2012–January 2014 | 183 | 1,698 (2,441) | MD (95% CI)^a^; −1,483 (−3,232; 266); p=0.25
O’Toole, 2018, 29451116 | Costs – Prescription drugs | PACT | June 2012–January 2014 | 83 | 3,181 (11,483) | MD (95% CI)^a^; −1,483 (−3,232; 266); p=0.25
O’Toole, 2018, 29451116 | Costs – Hospitalizations | HPACT | June 2012–January 2014 | 183 | 5,530 (18,138) | MD (95% CI)^a^; −4,899 (−10,188 ; 390); p=0.10
O’Toole, 2018, 29451116 | Costs – Hospitalizations | PACT | June 2012–January 2014 | 83 | 10,429 (24,427) | MD (95% CI)^a^; −4,899 (−10,188 ; 390); p=0.10
O’Toole, 2018, 29451116 | Costs- Emergency department | HPACT | June 2012–January 2014 | 183 | 1,978 (3,627) | MD (95% CI); −257 (−1,239 ; 725)^a^; p=0.6071
O’Toole, 2018, 29451116 | Costs- Emergency department | PACT | June 2012–January 2014 | 83 | 2,235 (4,076) | MD (95% CI); −257 (−1,239 ; 725)^a^; p=0.6071
O’Toole, 2018, 29451116 | Costs- Emergency department for ambulatory care-sensitive conditions | HPACT | June 2012–January 2014 | 183 | 19 (165) | MD (95% CI); −86 (−169 ; −2)^a^; p=0.04
O’Toole, 2018, 29451116 | Costs- Emergency department for ambulatory care-sensitive conditions | PACT | June 2012–January 2014 | 83 | 105 (517) | MD (95% CI); −86 (−169 ; −2)^a^; p=0.04
O’Toole, 2018, 29451116 | Costs – Primary Care | HPACT | June 2012–January 2014 | 183 | 2,947 (2,511) | p=0.03; MD (95% CI)^a^; 681 (45 ; 1,316)
O’Toole, 2018, 29451116 | Costs – Primary Care | PACT | June 2012–January 2014 | 83 | 2,266 (2,266) | p=0.03; MD (95% CI)^a^; 681 (45 ; 1,316)

Notes.

a Calculated by the research team.

Abbreviations. CI=confidence interval; HPACT=homeless patient aligned care teams; MD=mean difference; N=number; PACT=patient aligned care teams; SD=standard deviation.