# APPENDIX G CATEGORICAL OUTCOMES

## G1. Primary Care

Author, Year, PMID | Outcome Definition | Sample/Groups | Timepoint | n/N (%) | Effect size, p-value
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Primary Care Visits | HPACT | 7–12 months before enrollment | 49/179 (27) | aOR (95% CI):; 0–6 months after HPACT enrollment vs 0–6 months before = 4.91 (2.94, 8.20); 7–12 months after HPACT enrollment vs 0–6 months before = 2.30 (1.42, 3.72)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Primary Care Visits | HPACT | 0–6 months before enrollment | 70/179 (39) | aOR (95% CI):; 0–6 months after HPACT enrollment vs 0–6 months before = 4.91 (2.94, 8.20); 7–12 months after HPACT enrollment vs 0–6 months before = 2.30 (1.42, 3.72)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Primary Care Visits | HPACT | 0–6 months after enrollment | 124/179 (69) | aOR (95% CI):; 0–6 months after HPACT enrollment vs 0–6 months before = 4.91 (2.94, 8.20); 7–12 months after HPACT enrollment vs 0–6 months before = 2.30 (1.42, 3.72)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Primary Care Visits | HPACT | 7–12 months after enrollment | 99/179 (55) | aOR (95% CI):; 0–6 months after HPACT enrollment vs 0–6 months before = 4.91 (2.94, 8.20); 7–12 months after HPACT enrollment vs 0–6 months before = 2.30 (1.42, 3.72)

Abbreviations. aOR=adjusted odds ratio; CI=confidence interval; HPACT=homeless patient aligned care teams; N=number.

## G2. Emergency Department

Author, Year, PMID | Outcome Definition | Sample/Groups, Comparisons | Timepoint | n/N (%) | Effect size, p-value
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Any emergency department visit | HPACT | 7–12 months before enrollment | 40/179 (22) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.57 (0.34, 0.94); 7–12 months after HPACT enrollment vs 0–6 months before = 0.55 (0.33, 0.91)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Any emergency department visit | HPACT | 0–6 months before enrollment | 77/179 (43) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.57 (0.34, 0.94); 7–12 months after HPACT enrollment vs 0–6 months before = 0.55 (0.33, 0.91)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Any emergency department visit | HPACT | 0–6 months after enrollment | 60/179 (34 | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.57 (0.34, 0.94); 7–12 months after HPACT enrollment vs 0–6 months before = 0.55 (0.33, 0.91)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Any emergency department visit | HPACT | 7–12 months after enrollment | 59/179 (33) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.57 (0.34, 0.94); 7–12 months after HPACT enrollment vs 0–6 months before = 0.55 (0.33, 0.91)
Gundlapalli, 2017 | Emergent emergency department care needed: Not preventable/Avoidable, % of total visits | HPACT Enrolled | 6 months before enrollment | nr/NR (8.7) | NR, p=0.01
Gundlapalli, 2017 | Emergent emergency department care needed: Not preventable/Avoidable, % of total visits | HPACT Enrolled | 6 months after enrollment | nr/NR (10) | NR, p=0.01
Gundlapalli, 2017 | Emergent emergency department care needed: Not preventable/Avoidable, % of total visits | HPACT Site Nonenrolled | First 6 months of data | nr/NR (5.6) | NR, p=0.39
Gundlapalli, 2017 | Emergent emergency department care needed: Not preventable/Avoidable, % of total visits | HPACT Site Nonenrolled | Second 6 months of data | nr/NR (5.8) | NR, p=0.39
Gundlapalli, 2017 | Emergent emergency department care needed: Not preventable/Avoidable, % of total visits | Usual Care Site | First 6 months of data | nr/NR (8.4) | NR, p=0.01
Gundlapalli, 2017 | Emergent emergency department care needed: Not preventable/Avoidable, % of total visits | Usual Care Site | Second 6 months of data | nr/NR (9.1) | NR, p=0.01
Gundlapalli, 2017 | Emergent emergency department care needed: Preventable/Avoidable, % of total visits | HPACT Enrolled | 6 months before enrollment | nr/NR (5.1) | NR, p=0.53
Gundlapalli, 2017 | Emergent emergency department care needed: Preventable/Avoidable, % of total visits | HPACT Enrolled | 6 months after enrollment | nr/NR (5.3) | NR, p=0.53
Gundlapalli, 2017 | Emergent emergency department care needed: Preventable/Avoidable, % of total visits | HPACT Site Nonenrolled | First 6 months of data | nr/NR (3.7) | NR, p=0.16
Gundlapalli, 2017 | Emergent emergency department care needed: Preventable/Avoidable, % of total visits | HPACT Site Nonenrolled | Second 6 months of data | nr/NR (3.9) | NR, p=0.16
Gundlapalli, 2017 | Emergent emergency department care needed: Preventable/Avoidable, % of total visits | Usual Care Site | First 6 months of data | nr/NR (4.1) | NR, p=0.75
Gundlapalli, 2017 | Emergent emergency department care needed: Preventable/Avoidable, % of total visits | Usual Care Site | Second 6 months of data | nr/NR (4) | NR, p=0.75
Gundlapalli, 2017 | Emergent/Primary care treatable, % of total visits | HPACT Enrolled | 6 months before enrollment | nr/NR (12.9) | NR, p=0.92
Gundlapalli, 2017 | Emergent/Primary care treatable, % of total visits | HPACT Enrolled | 6 months after enrollment | nr/NR (12.8) | NR, p=0.92
Gundlapalli, 2017 | Emergent/Primary care treatable, % of total visits | HPACT Site Nonenrolled | First 6 months of data | nr/NR (12) | NR, p=0.002
Gundlapalli, 2017 | Emergent/Primary care treatable, % of total visits | HPACT Site Nonenrolled | Second 6 months of data | nr/NR (12.9) | NR, p=0.002
Gundlapalli, 2017 | Emergent/Primary care treatable, % of total visits | Usual Care Site | First 6 months of data | nr/NR (13.4) | NR, p=0.04
Gundlapalli, 2017 | Emergent/Primary care treatable, % of total visits | Usual Care Site | Second 6 months of data | nr/NR (14.1) | NR, p=0.04
Gundlapalli, 2017 | Nonemergent, % of total visits | HPACT Enrolled | 6 months before enrollment | nr/NR (22.3) | NR, p=0.004
Gundlapalli, 2017 | Nonemergent, % of total visits | HPACT Enrolled | 6 months after enrollment | nr/NR (24.4) | NR, p=0.004
Gundlapalli, 2017 | Nonemergent, % of total visits | HPACT Site Nonenrolled | First 6 months of data | nr/NR (24) | NR, p<0.001
Gundlapalli, 2017 | Nonemergent, % of total visits | HPACT Site Nonenrolled | Second 6 months of data | nr/NR (25.9) | NR, p<0.001
Gundlapalli, 2017 | Nonemergent, % of total visits | Usual Care Site | First 6 months of data | nr/NR (26.5) | NR, p=1.00
Gundlapalli, 2017 | Nonemergent, % of total visits | Usual Care Site | Second 6 months of data | nr/NR (26.5) | NR, p=1.00
Gundlapalli, 2017 | Unclassified, % of total visits | HPACT Enrolled | 6 months before enrollment | nr/NR (51.1) | NR, p<0.001
Gundlapalli, 2017 | Unclassified, % of total visits | HPACT Enrolled | 6 months after enrollment | nr/NR (47.5) | NR, p<0.001
Gundlapalli, 2017 | Unclassified, % of total visits | HPACT Site Nonenrolled | First 6 months of data | nr/NR (54.8) | NR, p<0.001
Gundlapalli, 2017 | Unclassified, % of total visits | HPACT Site Nonenrolled | Second 6 months of data | nr/NR (51.6) | NR, p<0.001
Gundlapalli, 2017 | Unclassified, % of total visits | Usual Care Site | First 6 months of data | nr/NR (47.7) | NR, p=0.01
Gundlapalli, 2017 | Unclassified, % of total visits | Usual Care Site | Second 6 months of data | nr/NR (46.3) | NR, p=0.01
Gundlapalli, 2017 | Emergent emergency department care needed: Not preventable/Avoidable, % of total visits | HPACT Enrolled, High Utilizers | 6 months before enrollment | nr/NR (9) | NR, p=0.91
Gundlapalli, 2017 | Emergent emergency department care needed: Not preventable/Avoidable, % of total visits | HPACT Enrolled, High Utilizers | 6 months after enrollment | nr/NR (8.9) | NR, p=0.91
Gundlapalli, 2017 | Emergent emergency department care needed: Not preventable/Avoidable, % of total visits | HPACT Site Nonenrolled, High utilizers | First 6 months of data | nr/NR (5) | NR, p=0.60
Gundlapalli, 2017 | Emergent emergency department care needed: Not preventable/Avoidable, % of total visits | HPACT Site Nonenrolled, High utilizers | Second 6 months of data | nr/NR (5.5) | NR, p=0.60
Gundlapalli, 2017 | Emergent emergency department care needed: Not preventable/Avoidable, % of total visits | Usual Care Site, High utilizers | First 6 months of data | nr/NR (8.5) | NR, p=0.03
Gundlapalli, 2017 | Emergent emergency department care needed: Not preventable/Avoidable, % of total visits | Usual Care Site, High utilizers | Second 6 months of data | nr/NR (9.5) | NR, p=0.03
Gundlapalli, 2017 | Emergent emergency department care needed: Preventable/Avoidable, % of total visits | HPACT Enrolled, High Utilizers | 6 months before enrollment | nr/NR (6.2) | NR, p=0.56
Gundlapalli, 2017 | Emergent emergency department care needed: Preventable/Avoidable, % of total visits | HPACT Enrolled, High Utilizers | 6 months after enrollment | nr/NR (5.8) | NR, p=0.56
Gundlapalli, 2017 | Emergent emergency department care needed: Preventable/Avoidable, % of total visits | HPACT Site Nonenrolled, High utilizers | First 6 months of data | nr/NR (4.2) | NR, p=0.72
Gundlapalli, 2017 | Emergent emergency department care needed: Preventable/Avoidable, % of total visits | HPACT Site Nonenrolled, High utilizers | Second 6 months of data | nr/NR (3.9) | NR, p=0.72
Gundlapalli, 2017 | Emergent emergency department care needed: Preventable/Avoidable, % of total visits | Usual Care Site, High ED utilizers | First 6 months of data | nr/NR (4.7) | NR, p=0.21
Gundlapalli, 2017 | Emergent emergency department care needed: Preventable/Avoidable, % of total visits | Usual Care Site, High ED utilizers | Second 6 months of data | nr/NR (5.2) | NR, p=0.21
Gundlapalli, 2017 | Emergent/Primary care treatable, % of total visits | HPACT Enrolled, High Utilizers | 6 months before enrollment | nr/NR (12.5) | NR, p=0.10
Gundlapalli, 2017 | Emergent/Primary care treatable, % of total visits | HPACT Enrolled, High Utilizers | 6 months after enrollment | nr/NR (11.2) | NR, p=0.10
Gundlapalli, 2017 | Emergent/Primary care treatable, % of total visits | HPACT Site Nonenrolled, High utilizers | First 6 months of data | nr/NR (10) | NR, p=0.53
Gundlapalli, 2017 | Emergent/Primary care treatable, % of total visits | HPACT Site Nonenrolled, High utilizers | Second 6 months of data | nr/NR (10.8) | NR, p=0.53
Gundlapalli, 2017 | Emergent/Primary care treatable, % of total visits | Usual Care Site, High utilizers | First 6 months of data | nr/NR (13.7) | NR, p=0.07
Gundlapalli, 2017 | Emergent/Primary care treatable, % of total visits | Usual Care Site, High utilizers | Second 6 months of data | nr/NR (14.8) | NR, p=0.07
Gundlapalli, 2017 | Nonemergent, % of total visits | HPACT Enrolled, High Utilizers | 6 months before enrollment | nr/NR (20.6) | NR, p<0.001
Gundlapalli, 2017 | Nonemergent, % of total visits | HPACT Enrolled, High Utilizers | 6 months after enrollment | nr/NR (24.4) | NR, p<0.001
Gundlapalli, 2017 | Nonemergent, % of total visits | HPACT Site Nonenrolled, High utilizers | First 6 months of data | nr/NR (21.2) | NR, p=0.80
Gundlapalli, 2017 | Nonemergent, % of total visits | HPACT Site Nonenrolled, High utilizers | Second 6 months of data | nr/NR (21.6) | NR, p=0.80
Gundlapalli, 2017 | Nonemergent, % of total visits | Usual Care Site, High utilizers | First 6 months of data | nr/NR (26.8) | NR, p=0.48
Gundlapalli, 2017 | Nonemergent, % of total visits | Usual Care Site, High utilizers | Second 6 months of data | nr/NR (26.3) | NR, p=0.48
Gundlapalli, 2017 | Unclassified, % of total visits | HPACT Enrolled, High Utilizers | 6 months before enrollment | nr/NR (51.7) | NR, p=0.13
Gundlapalli, 2017 | Unclassified, % of total visits | HPACT Enrolled, High Utilizers | 6 months after enrollment | nr/NR (49.8) | NR, p=0.13
Gundlapalli, 2017 | Unclassified, % of total visits | HPACT Site Nonenrolled, High utilizers | First 6 months of data | nr/NR (59.6) | NR, p=0.46
Gundlapalli, 2017 | Unclassified, % of total visits | HPACT Site Nonenrolled, High utilizers | Second 6 months of data | nr/NR (58.3) | NR, p=0.46
Gundlapalli, 2017 | Unclassified, % of total visits | Usual Care Site, High utilizers | First 6 months of data | nr/NR (46.3) | NR, p=0.02
Gundlapalli, 2017 | Unclassified, % of total visits | Usual Care Site, High utilizers | Second 6 months of data | nr/NR (44.2) | NR, p=0.02
Jones, 2023, 35194740 | Emergency Department- Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Pre-enrollment slope (rate of utilization in 4 quarters prior to enrollment) | nr/NR | IRR (SE); 1.49 (0.14), p <0.001
Jones, 2023, 35194740 | Emergency Department- Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Level change (change in Q1 after enrollment vs Q prior to enrollment) | nr/NR | IRR (SE); 0.69 (0.18), p= 0.16
Jones, 2023, 35194740 | Emergency Department- Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Post-enrollment slope (rate in utilization in the 4 quarters after enrollment) | nr/NR | IRR (SE); 1.03 (0.04), p= 0.55
Jones, 2023, 35194740 | Emergency Department- Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Trend change (%) (% change in post-enrollment slope vs pre-enrollment slope) | nr/NR | −31%, p <0.001
O’Toole, 2010, 20966377 | Access emergency department | HOPC | First 6 months | 44^a^/79 (55.3) | HOPC, pre vs post, p <0.01; GIM, pre vs post, p= 0.53
O’Toole, 2010, 20966377 | Access emergency department | HOPC | Second 6 months | 29 ^a^/79 (36.8) | HOPC, pre vs post, p <0.01; GIM, pre vs post, p= 0.53
O’Toole, 2010, 20966377 | Access emergency department | GIM | First 6 months | 43 ^a^/98 (44.2) | HOPC vs GIM (Second 6 months); OR (95% CI)= 0.84 (0.46, 1.55)^a^; p= 0.57
O’Toole, 2010, 20966377 | Access emergency department | GIM | Second 6 months | 40 ^a^/98 (41.1) | HOPC vs GIM (Second 6 months); OR (95% CI)= 0.84 (0.46, 1.55)^a^; p= 0.57
O’Toole, 2010, 20966377 | Access emergency department, nonemergency care | HOPC | First 6 months | 18 ^a^/79 (22.4) | HOPC, pre vs post, p=0.02; GIM, pre vs post, p= 0.62
O’Toole, 2010, 20966377 | Access emergency department, nonemergency care | HOPC | Second 6 months | 10 ^a^/79 (13.2) | HOPC, pre vs post, p=0.02; GIM, pre vs post, p= 0.62
O’Toole, 2010, 20966377 | Access emergency department, nonemergency care | GIM | First 6 months | 24 ^a^/98 (24.2) | HOPC vs GIM (Second 6 months); OR (95% CI)= 0.50 (0.22, 1.13)^a^; p= 0.13
O’Toole, 2010, 20966377 | Access emergency department, nonemergency care | GIM | Second 6 months | 22 ^a^/98 (22.1) | HOPC vs GIM (Second 6 months); OR (95% CI)= 0.50 (0.22, 1.13)^a^; p= 0.13
O’Toole, 2010, 20966377 | Proportion of emergency department visits that were non-emergency | HOPC | First 6 months | 29/123 (23.6) | HOPC, pre vs post, p=0.39; GIM, pre vs post, p= 0.29
O’Toole, 2010, 20966377 | Proportion of emergency department visits that were non-emergency | HOPC | Second 6 months | 18/81 (18.5) | HOPC, pre vs post, p=0.39; GIM, pre vs post, p= 0.29
O’Toole, 2010, 20966377 | Proportion of emergency department visits that were non-emergency | GIM | First 6 months | 40/115 (34.8) | HOPC vs GIM (Second 6 months); OR (95% CI)= 0.46 (0.22, 0.93)^a^; P<0.01
O’Toole, 2010, 20966377 | Proportion of emergency department visits that were non-emergency | GIM | Second 6 months | 27/70 (38.6) | HOPC vs GIM (Second 6 months); OR (95% CI)= 0.46 (0.22, 0.93)^a^; P<0.01
O’Toole, 2010, 20966377 | Emergency department for a nonacute condition | HOPC | 2006–2007 | nr/79 (NR) | aOR (95% CI); 0.4 (0.2, 0.8)
O’Toole, 2010, 20966377 | Emergency department for a nonacute condition | GIM | 2004–2006 | nr/98 (NR) | aOR (95% CI); 0.4 (0.2, 0.8)
O’Toole, 2018 | Percent of participants accessing care-Emergency department (any) | HPACT | June 2012–January 2014 | 111/183 (61.0) | p=0.45; OR (95% CI)= 0.83 (0.48, 1.42)^a^
O’Toole, 2018 | Percent of participants accessing care-Emergency department (any) | PACT | June 2012–January 2014 | 54/83 (65.9) | p=0.45; OR (95% CI)= 0.83 (0.48, 1.42)^a^
O’Toole, 2018 | Percent of participants accessing care-Emergency department (mental health-related) | HPACT | June 2012–January 2014 | 62/183 (34.1) | p=0.04; OR (95% CI)= 0.58 (0.34, 0.98)^a^
O’Toole, 2018 | Percent of participants accessing care-Emergency department (mental health-related) | PACT | June 2012–January 2014 | 39/83 (47.6) | p=0.04; OR (95% CI)= 0.58 (0.34, 0.98)^a^
O’Toole, 2018 | Acute care event- All-cause emergency department visits and hospitalizations as well as emergency department visits and hospitalizations for ambulatory care–sensitive conditions | HPACT | June 2012–January 2014 | nr/NR | aOR (95% CI) = 0.41 (0.21, 0.80)
O’Toole, 2018 | Acute care event- All-cause emergency department visits and hospitalizations as well as emergency department visits and hospitalizations for ambulatory care–sensitive conditions | PACT | June 2012–January 2014 | nr/NR | aOR (95% CI) = 0.41 (0.21, 0.80)

Notes.

a Calculated by the research team.

Abbreviations. aOR=adjusted odds ratio; CI=confidence interval; GIM=general internal medicine; HOPC=homeless oriented primary care; HPACT=homeless patient aligned care teams; IRR=incidence rate ratios; N=number; NR=not reported; OR=odds ratio; PACT=patient aligned care teams; Q=quarter; SE=standard error.

## G3. Emergency Department (Non-Comparative)

Author, Year, PMID | Outcome Definition | Sample/Groups | Timepoint | n/N (%) | Effect size, p-value
O’Toole, 2013 | Services Utilization During First 6 Months of Primary Care Enrollment- Emergency Department Visits | Homeless PACT | 2008–2011 | 61^a^/127 (48)

Notes.

a Calculated by the research team.

Abbreviations. N=number; PACT=patient aligned care teams.

## G4. Hospitalizations

Author, Year, PMID | Outcome Definition | Sample/Groups | Timepoint | n/N (%) | Effect Size, p-value
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Inpatient stay | HPACT | 7–12 months before enrollment | 30/179 (17) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.43 (0.25, 0.76); 7–12 months after HPACT enrollment vs 0–6 months before = 0.45 (0.26, 0.80)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Inpatient stay | HPACT | 0–6 months before enrollment | 56/179 (31) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.43 (0.25, 0.76); 7–12 months after HPACT enrollment vs 0–6 months before = 0.45 (0.26, 0.80)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Inpatient stay | HPACT | 0–6 months after enrollment | 35/179 (20) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.43 (0.25, 0.76); 7–12 months after HPACT enrollment vs 0–6 months before = 0.45 (0.26, 0.80)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Inpatient stay | HPACT | 7–12 months after enrollment | 36/179 (20) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.43 (0.25, 0.76); 7–12 months after HPACT enrollment vs 0–6 months before = 0.45 (0.26, 0.80)
Jones, 2023, 35194740 | Hospitalizations- Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Pre-enrollment slope (rate of utilization in 4 quarters prior to enrollment) | nr/NR | IRR (SE); 1.54 (0.18), p <0.001
Jones, 2023, 35194740 | Hospitalizations- Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Level change (change in Q1 after enrollment vs Q prior to enrollment) | nr/NR | IRR (SE); 0.33 (0.11), p <0.001
Jones, 2023, 35194740 | Hospitalizations- Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Post-enrollment slope (rate in utilization in the 4 quarters after enrollment) | nr/NR | IRR (SE); 1.17 (0.11), p= 0.08
Jones, 2023, 35194740 | Hospitalizations- Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Trend change (%) (% change in post-enrollment slope vs pre-enrollment slope) | nr/NR | −34%, p= 0.04
O’Toole, 2010, 20966377 | Total number of hospitalizations | HOPC | 12 months | 72/NR | NR, p=0.02
O’Toole, 2010, 20966377 | Total number of hospitalizations | GIM | 12 months | 47/NR | NR, p=0.02
O’Toole, 2010, 20966377 | Proportion of hospitalizations not related to drug or alcohol use or mental health | HOPC | First 6 months | 10/35 (28.6) | HOPC, pre vs post, P<0.01; GIM, pre vs post, p= 0.6
O’Toole, 2010, 20966377 | Proportion of hospitalizations not related to drug or alcohol use or mental health | HOPC | Second 6 months | 4/37 (10.8) | HOPC, pre vs post, P<0.01; GIM, pre vs post, p= 0.6
O’Toole, 2010, 20966377 | Proportion of hospitalizations not related to drug or alcohol use or mental health | GIM | First 6 months | 14/29 (48.2) | HOPC vs GIM (Second 6 months); OR (95% CI)= 0.15 (0.04, 0.61)^a^; P<0.01
O’Toole, 2010, 20966377 | Proportion of hospitalizations not related to drug or alcohol use or mental health | GIM | Second 6 months | 8/18 (44.4) | HOPC vs GIM (Second 6 months); OR (95% CI)= 0.15 (0.04, 0.61)^a^; P<0.01
O’Toole, 2018 | Percent of participants accessing care-Hospitalizations | HPACT | June 2012–January 2014 | 42/183 (23.1) | p=0.04; OR (95% CI)= 0.55 (0.31, 0.98)^a^
O’Toole, 2018 | Percent of participants accessing care-Hospitalizations | PACT | June 2012–January 2014 | 29/83 (35.4) | p=0.04; OR (95% CI)= 0.55 (0.31, 0.98)^a^

Note.

a Calculated by the research team.

Abbreviations. aOR=adjusted odds ratio; CI=confidence interval; GIM=general internal medicine; HOPC=homeless oriented primary care; HPACT=homeless patient aligned care teams; IRR=Incidence rate ratios; N=number; NR=not reported; OR=odds ratio; PACT=patient aligned care teams; Q=quarter; SE=standard error.

## G5. Specialty Care

Author, Year, PMID | Outcome Definition | Sample/Groups | Timepoint | n/N (%) | Effect Sze, p-value
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Medical specialist visit | HPACT | 7–12 months before enrollment | 39/179 (22) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before= 1.38 (0.86, 2.23); 7–12 months after HPACT enrollment vs 0–6 months before = 0.81 (0.49, 1.31)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Medical specialist visit | HPACT | 0–6 months before enrollment | 66/179 (37) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before= 1.38 (0.86, 2.23); 7–12 months after HPACT enrollment vs 0–6 months before = 0.81 (0.49, 1.31)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Medical specialist visit | HPACT | 0–6 months after enrollment | 77/179 (43) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before= 1.38 (0.86, 2.23); 7–12 months after HPACT enrollment vs 0–6 months before = 0.81 (0.49, 1.31)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Medical specialist visit | HPACT | 7–12 months after enrollment | 59/179 (33) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before= 1.38 (0.86, 2.23); 7–12 months after HPACT enrollment vs 0–6 months before = 0.81 (0.49, 1.31)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Mental health specialist visit | HPACT | 7–12 months before enrollment | 41/179 (23) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.90 (0.53, 1.51); 7–12 months after HPACT enrollment vs 0–6 months before =0.35 (0.20, 0.60)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Mental health specialist visit | HPACT | 0–6 months before enrollment | 85/179 (47) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.90 (0.53, 1.51); 7–12 months after HPACT enrollment vs 0–6 months before =0.35 (0.20, 0.60)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Mental health specialist visit | HPACT | 0–6 months after enrollment | 82/179 (46) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.90 (0.53, 1.51); 7–12 months after HPACT enrollment vs 0–6 months before =0.35 (0.20, 0.60)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Mental health specialist visit | HPACT | 7–12 months after enrollment | 56/179 (31) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.90 (0.53, 1.51); 7–12 months after HPACT enrollment vs 0–6 months before =0.35 (0.20, 0.60)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Addiction specialist visit | HPACT | 7–12 months before enrollment | 14/179 (8) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.51 (0.24, 1.06); 7–12 months after HPACT enrollment vs 0–6 months before = 0.39 (0.18, 0.84)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Addiction specialist visit | HPACT | 0–6 months before enrollment | 25/179 (14) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.51 (0.24, 1.06); 7–12 months after HPACT enrollment vs 0–6 months before = 0.39 (0.18, 0.84)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Addiction specialist visit | HPACT | 0–6 months after enrollment | 15/179 (8) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.51 (0.24, 1.06); 7–12 months after HPACT enrollment vs 0–6 months before = 0.39 (0.18, 0.84)
Jones, 2018, 29412071 | Percentages of patients with any health care visit before and after HPACT- Addiction specialist visit | HPACT | 7–12 months after enrollment | 12/179 (7) | aOR (95% CI); 0–6 months after HPACT enrollment vs 0–6 months before = 0.51 (0.24, 1.06); 7–12 months after HPACT enrollment vs 0–6 months before = 0.39 (0.18, 0.84)
Jones, 2023, 35194740 | Mental health Clinic- Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Pre-enrollment slope (rate of utilization in 4 quarters prior to enrollment) | nr/NR | IRR (SE); 1.35 (0.06), p <0.001
Jones, 2023, 35194740 | Mental health Clinic- Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Level change (change in Q1 after enrollment vs Q prior to enrollment) | nr/NR | IRR (SE); 0.46 (0.06), p <0.001
Jones, 2023, 35194740 | Mental health Clinic- Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Post-enrollment slope (rate in utilization in the 4 quarters after enrollment) | nr/NR | IRR (SE); 0.94 (0.03), p <0.001
Jones, 2023, 35194740 | Mental health Clinic- Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Trend change (%) (% change in post-enrollment slope vs pre-enrollment slope) | nr/NR | −30%, p= 0.1
Jones, 2023, 35194740 | Specialty SUD Clinic - Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Pre-enrollment slope (rate of utilization in 4 quarters prior to enrollment) | nr/NR | IRR (SE); 1.31 (0.06), p <0.001
Jones, 2023, 35194740 | Specialty SUD Clinic - Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Level change (change in Q1 after enrollment vs Q prior to enrollment) | nr/NR | IRR (SE); 0.66 (0.09), p <0.001
Jones, 2023, 35194740 | Specialty SUD Clinic - Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Post-enrollment slope (rate in utilization in the 4 quarters after enrollment) | nr/NR | IRR (SE); 0.78 (0.03), p <0.001
Jones, 2023, 35194740 | Specialty SUD Clinic - Utilization Before and After Integrated Primary Care Enrollment | Integrated Primary Care | Trend change (%) (% change in post-enrollment slope vs pre-enrollment slope) | nr/NR | −40%, p <0.001
Jones, 2023, 36810631 | Rates of Depression Follow-up and Treatment | HPACT | Within 84 days | 234^a^/374 (62.6) | aOR (95% CI)= 1.61 (1.21–2.15), p<.001
Jones, 2023, 36810631 | Rates of Depression Follow-up and Treatment | PACT | Within 84 days | 1133^a^/2469 (45.9) | aOR (95% CI)= 1.61 (1.21–2.15), p<.001
Jones, 2023, 36810631 | Rates of Depression Follow-up and Treatment | HPACT | Within 180 days | 291^a^/374 (77.8) | aOR (95% CI)= 1.51 (1.15–1.99), p<.001
Jones, 2023, 36810631 | Rates of Depression Follow-up and Treatment | PACT | Within 180 days | 1618^a^/2469 (65.5) | aOR (95% CI)= 1.51 (1.15–1.99), p<.001
Jones, 2023, 36810631 | Receiving 60+ day supply of antidepressant prescriptions, 4+ mental health specialist visits, or 3+ psychotherapy visits | HPACT | Within 365 days following a positive depression screen | 334^a^/374 (89.3) | aOR (95% CI)= 1.58 (1.15–2.16), p<.01
Jones, 2023, 36810631 | Receiving 60+ day supply of antidepressant prescriptions, 4+ mental health specialist visits, or 3+ psychotherapy visits | PACT | Within 365 days following a positive depression screen | 2,017^a^/2469 (81.7) | aOR (95% CI)= 1.58 (1.15–2.16), p<.01
O’Toole, 2018 | Percent of participants accessing care-Psychiatry | HPACT | June 2012–January 2014 | 102/183 (56.0) | p= 0.26; OR (95% CI)= 0.75 (0.44, 1.28)^a^
O’Toole, 2018 | Percent of participants accessing care-Psychiatry | PACT | June 2012–January 2014 | 52/83 (63.4) | p= 0.26; OR (95% CI)= 0.75 (0.44, 1.28)^a^
O’Toole, 2018 | Percent of participants accessing care-Psychology | HPACT | June 2012–January 2014 | 59/183 (32.4) | p=0.30; OR (95% CI)= 0.76 (0.44, 1.30)^a^
O’Toole, 2018 | Percent of participants accessing care-Psychology | PACT | June 2012–January 2014 | 32/83 (39.0) | p=0.30; OR (95% CI)= 0.76 (0.44, 1.30)^a^
O’Toole, 2018 | Percent of participants accessing care- Group Therapy | HPACT | June 2012–January 2014 | 73/183 (40.1) | p=0.04; OR (95% CI)= 0.59 (0.35, 0.99)^a^
O’Toole, 2018 | Percent of participants accessing care- Group Therapy | PACT | June 2012–January 2014 | 44/83 (53.7) | p=0.04; OR (95% CI)= 0.59 (0.35, 0.99)^a^

Notes.

a Calculated by the research team.

Abbreviations. aOR=adjusted odds ratio; CI=confidence interval; GIM=general internal medicine; HOPC=homeless oriented primary care; HPACT=homeless patient aligned care teams; IRR=incidence rate ratios; N=number; NR=not reported; OR=odds ratio; PACT=patient aligned care teams; Q=quarter; SE=standard error.

## G6. Specialty Care (Non-Comparative)

Study | Outcome Definition | Sample/Groups | Timepoint | n/N (%) | Effect Size, p-value
O’Toole, 2013 | Services Utilization During First 6 Months of Primary Care Enrollment- Mental Health Care | Homeless PACT | 2008–2011 | 112^a^/127 (88.2) | -
O’Toole, 2013 | Services Utilization During First 6 Months of Primary Care Enrollment- Using substance abuse treatment services | Homeless PACT | 2008–2011 | 48^a^/127 (37.8) | -
O’Toole, 2013 | Services Utilization During First 6 Months of Primary Care Enrollment- Specialty Care | Homeless PACT | 2008–2011 | 110^a^/127 (86.6) | -
Chang 2020 | Receipt of any add-on intensive services-Telehealth services | Those receiving homeless specialized primary care | October 2015- September 2016 | 124/2775 (4.5) | -
Chang 2020 | Receipt of any add-on intensive services-Palliative care or hospice services | Those receiving homeless specialized primary care | October 2015- September 2016 | 47/2775 (1.7) | -
Chang 2020 | Receipt of any add-on intensive services-Intensive mental health case management services | Those receiving homeless specialized primary care | October 2015- September 2016 | 79/2775 (2.8) | -

Notes.

a Calculated by the research team.

Abbreviations. N=number; PACT=patient aligned care teams.

## G7. Patient Experience/Satisfaction

Study | Outcome Definition | Sample/Groups | Timepoint | n/N (%) | Effect size, p-value
Gabrielian, 2021 | Accessibility and coordination (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Unadjusted) | HPACT | March - October 2018 | 278/626 (45.3) | -
Gabrielian, 2021 | Accessibility and coordination (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Unadjusted) | Mainstream Primary Care | March - October 2018 | 94/343 (28.4) | -
Gabrielian, 2021 | Accessibility and coordination (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Adjusted) | HPACT | March - October 2018 | nr/NR (46.2) | aOR (95% CI) = 2.2 (1.6, 3.1), p<0.05
Gabrielian, 2021 | Accessibility and coordination (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Adjusted) | Mainstream Primary Care | March - October 2018 | nr/NR (28.0) | aOR (95% CI) = 2.2 (1.6, 3.1), p<0.05
Gabrielian, 2021 | Accessibility and coordination (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Unadjusted) | HPACT | March - October 2018 | 170/626 (27.7) | -
Gabrielian, 2021 | Accessibility and coordination (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Unadjusted) | Mainstream Primary Care | March - October 2018 | 124/343 (37.5) | -
Gabrielian, 2021 | Accessibility and coordination (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Adjusted) | HPACT | March - October 2018 | nr/NR (26.4) | aOR (95% CI) = 0.6 (0.4, 0.8), p<0.05
Gabrielian, 2021 | Accessibility and coordination (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Adjusted) | Mainstream Primary Care | March - October 2018 | nr/NR (38.4) | aOR (95% CI) = 0.6 (0.4, 0.8), p<0.05
Gabrielian, 2021 | Patient-clinician relationship (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Unadjusted) | HPACT | March - October 2018 | 279/626 (45.2) | -
Gabrielian, 2021 | Patient-clinician relationship (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Unadjusted) | Mainstream Primary Care | March - October 2018 | 114/343 (33.8) | -
Gabrielian, 2021 | Patient-clinician relationship (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Adjusted) | HPACT | March - October 2018 | nr/NR (46.8) | aOR (95% CI)= 1.9 (1.4, 2.6), p<0.05
Gabrielian, 2021 | Patient-clinician relationship (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Adjusted) | Mainstream Primary Care | March - October 2018 | nr/NR (31.7) | aOR (95% CI)= 1.9 (1.4, 2.6), p<0.05
Gabrielian, 2021 | Patient-clinician relationship (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Unadjusted) | HPACT | March - October 2018 | 178/626 (28.9) | -
Gabrielian, 2021 | Patient-clinician relationship (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Unadjusted) | Mainstream Primary Care | March - October 2018 | 131/343 (38.9) | -
Gabrielian, 2021 | Patient-clinician relationship(Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Adjusted) | HPACT | March - October 2018 | nr/NR (26.5) | aOR (95% CI) =0.5 (0.3, 0.6), p<0.05
Gabrielian, 2021 | Patient-clinician relationship(Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Adjusted) | Mainstream Primary Care | March - October 2018 | nr/NR (42.4) | aOR (95% CI) =0.5 (0.3, 0.6), p<0.05
Gabrielian, 2021 | Perceived cooperation among clinician (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Unadjusted) | HPACT | March - October 2018 | 211/626 (38.0) | -
Gabrielian, 2021 | Perceived cooperation among clinician (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Unadjusted) | Mainstream Primary Care | March - October 2018 | 96/343 (30.9) | -
Gabrielian, 2021 | Perceived cooperation among clinician (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Adjusted) | HPACT | March - October 2018 | nr/NR (40.1) | aOR (95% CI) = 1.9 (1.4, 2.6), p<0.05
Gabrielian, 2021 | Perceived cooperation among clinician (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Adjusted) | Mainstream Primary Care | March - October 2018 | nr/NR (28.6) | aOR (95% CI) = 1.9 (1.4, 2.6), p<0.05
Gabrielian, 2021 | Perceived cooperation among clinician (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Unadjusted) | HPACT | March - October 2018 | 155/626 (27.9) | -
Gabrielian, 2021 | Perceived cooperation among clinician (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Unadjusted) | Mainstream Primary Care | March - October 2018 | 116/343 (37.3) | -
Gabrielian, 2021 | Perceived cooperation among clinician (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Adjusted) | HPACT | March - October 2018 | nr/NR (25.6) | aOR (95% CI) =0.5 (0.3, 0.6), p<0.05
Gabrielian, 2021 | Perceived cooperation among clinician (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Adjusted) | Mainstream Primary Care | March - October 2018 | nr/NR (38.8) | aOR (95% CI) =0.5 (0.3, 0.6), p<0.05
Gabrielian, 2021 | Homeless-specific needs (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Unadjusted) | HPACT | March - October 2018 | 236/626 (39.9) | -
Gabrielian, 2021 | Homeless-specific needs (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Unadjusted) | Mainstream Primary Care | March - October 2018 | 77/343 (25.1) | -
Gabrielian, 2021 | Homeless-specific needs (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Adjusted) | HPACT | March - October 2018 | nr/NR (40.2) | aOR (95% CI) = 2.1 (1.5, 2.9), p<0.05
Gabrielian, 2021 | Homeless-specific needs (Primary Care Quality-Homeless [PCQ-H] questionnaire), Favorable (Adjusted) | Mainstream Primary Care | March - October 2018 | nr/NR (24.5) | aOR (95% CI) = 2.1 (1.5, 2.9), p<0.05
Gabrielian, 2021 | Homeless-specific needs (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Unadjusted) | HPACT | March - October 2018 | 253/626 (42.7) | -
Gabrielian, 2021 | Homeless-specific needs (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Unadjusted) | Mainstream Primary Care | March - October 2018 | 182/343 (59.3) | -
Gabrielian, 2021 | Homeless-specific needs (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Adjusted) | HPACT | March - October 2018 | nr/NR (41.9) | aOR (95% CI) =0.5 (0.4, 0.7), p<0.05
Gabrielian, 2021 | Homeless-specific needs (Primary Care Quality-Homeless [PCQ-H] questionnaire), Unfavorable (Adjusted) | Mainstream Primary Care | March - October 2018 | nr/NR (59.1) | aOR (95% CI) =0.5 (0.4, 0.7), p<0.05
Jones, 2018 29762272 | Access (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 9.3 vs 9.9
Jones, 2018 29762272 | Access (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 9.3 vs 9.9
Jones, 2018 29762272 | Access (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 45.5 vs 42.2
Jones, 2018 29762272 | Access (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 45.5 vs 42.2
Jones, 2018 29762272 | Communication (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 10.8 vs 14.1
Jones, 2018 29762272 | Communication (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 10.8 vs 14.1
Jones, 2018 29762272 | Communication (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 65.8 vs 58.9
Jones, 2018 29762272 | Communication (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 65.8 vs 58.9
Jones, 2018 29762272 | Office Staff Helpfulness/Courtesy (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 10.7 vs 12.3
Jones, 2018 29762272 | Office Staff Helpfulness/Courtesy (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 10.7 vs 12.3
Jones, 2018 29762272 | Office Staff Helpfulness/Courtesy (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 60.0 vs 58.8
Jones, 2018 29762272 | Office Staff Helpfulness/Courtesy (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 60.0 vs 58.8
Jones, 2018 29762272 | Overall Provider Rating (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 9.9 vs 12.5
Jones, 2018 29762272 | Overall Provider Rating (2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 9.9 vs 12.5
Jones, 2018 29762272 | Overall Provider Rating (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 53.7 vs48.0
Jones, 2018 29762272 | Overall Provider Rating (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 53.7 vs48.0
Jones, 2018 29762272 | Comprehensiveness (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 17.1 vs 21.6
Jones, 2018 29762272 | Comprehensiveness (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 17.1 vs 21.6
Jones, 2018 29762272 | Comprehensiveness (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 48.4 vs 44.0
Jones, 2018 29762272 | Comprehensiveness (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 48.4 vs 44.0
Jones, 2018 29762272 | Care Coordination (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 7.7 vs 10.4
Jones, 2018 29762272 | Care Coordination (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 7.7 vs 10.4
Jones, 2018 29762272 | Care Coordination (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 59.9 vs 55.6
Jones, 2018 29762272 | Care Coordination (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 59.9 vs 55.6
Jones, 2018 29762272 | Shared Decision-Making (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 9.8 vs15.2
Jones, 2018 29762272 | Shared Decision-Making (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 9.8 vs15.2
Jones, 2018 29762272 | Shared Decision-Making (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 42.3 vs 37.9
Jones, 2018 29762272 | Shared Decision-Making (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 42.3 vs 37.9
Jones, 2018 29762272 | Self-Management Support (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 25.1 vs 30.0
Jones, 2018 29762272 | Self-Management Support (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 25.1 vs 30.0
Jones, 2018 29762272 | Self-Management Support (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive experiences | HPACT Facilities | 2014–2015 | nr/2022 | HPACT vs Non-HPACT, Adjusted %= 52.6 vs 45.0
Jones, 2018 29762272 | Self-Management Support (2014–2015 Patient-Centered Medical Home-Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive experiences | Non-HPACT Facilities | 2014–2015 | nr/10148 | HPACT vs Non-HPACT, Adjusted %= 52.6 vs 45.0
Jones, 2019 | Access (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), (% [SE]) | HPACT | 2014–2015 | 140^a^/251 (55.7 [4.5]) | -
Jones, 2019 | Access (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), (% [SE]) | Standard PC with H-PACT Available | 2014–2015 | 534^a^/1,527 (35.0 [1.8]) | -
Jones, 2019 | Access (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), (% [SE]) | Standard PC (HPACT unavailable) | 2014–2015 | 3497^a^/10,079 (34.7 [0.8]) | -
Jones, 2019 | Access (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | HPACT | 2014–2015 | 95^a^/251 (37.9 [4.3]) | -
Jones, 2019 | Access (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 785^a^/1,527 (51.4 [1.9]) | -
Jones, 2019 | Access (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 5150^a^/10,079 (51.1 [0.8]) | -
Jones, 2019 | Access (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | HPACT | 2014–2015 | 16^a^/251 (6.4 [2.7]) | -
Jones, 2019 | Access (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 208^a^/1,527 (13.6 [1.5]) | -
Jones, 2019 | Access (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 1441^a^/10,079 (14.3 [0.6]) | -
Jones, 2019 | Access (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | HPACT | 2014–2015 | 129^a^/251 (51.5) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT = 17.4 (8.1,26.7), p<.001; Standard PC in facility with H-PACT versus facility without H-PACT = −0.9 (−4.6, 2.9), p= NS
Jones, 2019 | Access (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC with H-PACT Available | 2014–2015 | 521^a^/1,527 (34.1) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT = 17.4 (8.1,26.7), p<.001; Standard PC in facility with H-PACT versus facility without H-PACT = −0.9 (−4.6, 2.9), p= NS
Jones, 2019 | Access (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC (HPACT unavailable) | 2014–2015 | 3528^a^/10,079 (35.0) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT = 17.4 (8.1,26.7), p<.001; Standard PC in facility with H-PACT versus facility without H-PACT = −0.9 (−4.6, 2.9), p= NS
Jones, 2019 | Access (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience, Controlling for Site and Patient Covariate | HPACT | 2014–2015 | 141^a^/251 (56.2) | aRD (95% CI) :; 21.1 (11.2, 31.0), p<.001
Jones, 2019 | | Standard PC with H-PACT Available | 2014–2015 | 534^a^/1527 (35.0) | aRD (95% CI) :; 21.1 (11.2, 31.0), p<.001
Jones, 2019 | Communication (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | HPACT | 2014–2015 | 189^a^/251 (75.1 [3.9]) | -
Jones, 2019 | Communication (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 889^a^/1,527 (58.2 [1.8]) | -
Jones, 2019 | Communication (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 5241^a^/10,079 (52.0 [0.8]) | -
Jones, 2019 | Communication (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | HPACT | 2014–2015 | 48^a^/251 (19.2 [3.4]) | -
Jones, 2019 | Communication (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 391^a^/1,527 (25.6 [1.5]) | -
Jones, 2019 | Communication (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 2812^a^/10,079 (27.9 [0.7]) | -
Jones, 2019 | Communication (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | HPACT | 2014–2015 | 14^a^/251 (5.7 [2.4]) | -
Jones, 2019 | Communication (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 247^a^/1,527 (16.2 [1.5]) | -
Jones, 2019 | Communication (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 2026^a^/10,079 (20.1 [0.6]) | -
Jones, 2019 | Communication (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | HPACT | 2014–2015 | 178^a^/251 (71.0) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 13.9 (5.2, 22.6), p<.01; Standard PC in facility with H-PACT versus facility without H-PACT= 4.7 (0.9, 8.4), p<.05
Jones, 2019 | Communication (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC with H-PACT Available | 2014–2015 | 872^a^/1,527 (57.1) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 13.9 (5.2, 22.6), p<.01; Standard PC in facility with H-PACT versus facility without H-PACT= 4.7 (0.9, 8.4), p<.05
Jones, 2019 | Communication (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC (HPACT unavailable) | 2014–2015 | 5291^a^/10,079 (52.5) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 13.9 (5.2, 22.6), p<.01; Standard PC in facility with H-PACT versus facility without H-PACT= 4.7 (0.9, 8.4), p<.05
Jones, 2019 | Communication (2014–2015 Patient Centered Medical Home Survey of Health care Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience, Controlling for Site and Patient Covariate | HPACT | 2014–2015 | 180^a^/251 (71.8) | aRD (95% CI); 13.1 (4.5, 21.7), p<.01
Jones, 2019 | | Standard PC with H-PACT Available | 2014–2015 | 896^a^/1,527 (58.7) | aRD (95% CI); 13.1 (4.5, 21.7), p<.01
Jones, 2019 | Office staff helpfulness/courtesy (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | HPACT | 2014–2015 | 168^a^/251 (66.8 [4.2]) | -
Jones, 2019 | Office staff helpfulness/courtesy (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 776^a^/1,527 (50.8 [1.8]) | -
Jones, 2019 | Office staff helpfulness/courtesy (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 5423^a^/10,079 (53.8 [0.8]) | -
Jones, 2019 | Office staff helpfulness/courtesy (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | HPACT | 2014–2015 | 52^a^/251 (20.9 [3.6]) | -
Jones, 2019 | Office staff helpfulness/courtesy (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 505^a^/1,527 (33.1 [1.7]) | -
Jones, 2019 | Office staff helpfulness/courtesy (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 2993^a^/10,079 (29.7 [0.7]) | -
Jones, 2019 | Office staff helpfulness/courtesy (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | HPACT | 2014–2015 | 31^a^/251 (12.3 [3.1]) | -
Jones, 2019 | Office staff helpfulness/courtesy (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 246^a^/1,527 (16.1 [1.3]) | -
Jones, 2019 | Office staff helpfulness/courtesy (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 1663^a^/10,079 (16.5 [0.7]) | -
Jones, 2019 | Office staff helpfulness/courtesy (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | HPACT | 2014–2015 | 159^a^/251 (63.5) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 13.1 (4.1,22.2), p<.01; Standard PC in facility with H-PACT versus facility without H-PACT= −3.6 (−7.5, 0.3), p=NS
Jones, 2019 | Office staff helpfulness/courtesy (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC with H-PACT Available | 2014–2015 | 770^a^/1,527 (50.4) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 13.1 (4.1,22.2), p<.01; Standard PC in facility with H-PACT versus facility without H-PACT= −3.6 (−7.5, 0.3), p=NS
Jones, 2019 | Office staff helpfulness/courtesy (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC (HPACT unavailable) | 2014–2015 | 5443^a^/10,079 (54.0) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 13.1 (4.1,22.2), p<.01; Standard PC in facility with H-PACT versus facility without H-PACT= −3.6 (−7.5, 0.3), p=NS
Jones, 2019 | Office staff helpfulness/courtesy (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience, Controlling for Site and Patient Covariates | HPACT | 2014–2015 | 160^a^/251 (63.6) | aRD (95% CI):; 12.3 (3.5, 21.0), p<.01
Jones, 2019 | | Standard PC with H-PACT Available | 2014–2015 | 783^a^/1,527 (51.3) | aRD (95% CI):; 12.3 (3.5, 21.0), p<.01
Jones, 2019 | Provider rating (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | HPACT | 2014–2015 | 163^a^/251 (65.1 [4.2]) | -
Jones, 2019 | Provider rating (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 770^a^/1,527 (50.4 [1.8]) | -
Jones, 2019 | Provider rating (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 4364^a^/10,079 (43.3 [0.8]) | -
Jones, 2019 | Provider rating (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | HPACT | 2014–2015 | 75^a^/251 (29.8 [3.9]) | -
Jones, 2019 | Provider rating (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 542^a^/1,527 (35.5 [1.7]) | -
Jones, 2019 | Provider rating (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 3971^a^/10,079 (39.4 [0.8]) | -
Jones, 2019 | Provider rating (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | HPACT | 2014–2015 | 13^a^/251 (5.1 [2.4]) | -
Jones, 2019 | Provider rating (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 215^a^/1,527 (14.1 [1.4]) | -
Jones, 2019 | Provider rating (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 1744^a^/10,079 (17.3 [0.6]) | -
Jones, 2019 | Provider rating (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | HPACT | 2014–2015 | 148^a^/251 (58.9) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 11.0 (1.9, 20.1), p<.05; Standard PC in facility with H-PACT versus facility without H-PACT= 3.8 (−0.1, 7.6), p= NS
Jones, 2019 | Provider rating (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC with H-PACT Available | 2014–2015 | 730^a^/1,527 (47.8) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 11.0 (1.9, 20.1), p<.05; Standard PC in facility with H-PACT versus facility without H-PACT= 3.8 (−0.1, 7.6), p= NS
Jones, 2019 | Provider rating (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC (HPACT unavailable) | 2014–2015 | 445^a^/10,079 (44.1) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 11.0 (1.9, 20.1), p<.05; Standard PC in facility with H-PACT versus facility without H-PACT= 3.8 (−0.1, 7.6), p= NS
Jones, 2019 | Provider rating (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience, Controlling for Site and Patient Covariates | HPACT | 2014–2015 | 157^a^/251 (62.6) | aRD (95% CI):; 11.9 (2.4, 21.4), p<.05
Jones, 2019 | | Standard PC with H-PACT Available | 2014–2015 | 774^a^/1,527 (50.7) | aRD (95% CI):; 11.9 (2.4, 21.4), p<.05
Jones, 2019 | Comprehensiveness (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | HPACT | 2014–2015 | 165^a^/251 (65.6 [4.0]) | -
Jones, 2019 | Comprehensiveness (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 825^a^/1,527 (54.0 [1.8]) | -
Jones, 2019 | Comprehensiveness (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 5241^a^/10,079 (52.0 [0.8]) | -
Jones, 2019 | Comprehensiveness (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | HPACT | 2014–2015 | 61^a^/251 (24.4 [3.7]) | -
Jones, 2019 | Comprehensiveness (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 441^a^/1,527 (28.9 [1.7]) | -
Jones, 2019 | Comprehensiveness (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 2883^a^/10,079 (28.6 [0.7]) | -
Jones, 2019 | Comprehensiveness (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | HPACT | 2014–2015 | 25^a^/251 (10.0 [2.2]) | -
Jones, 2019 | Comprehensiveness (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 260^a^/1,527 (17.0 [1.3]) | -
Jones, 2019 | Comprehensiveness (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 1965^a^/10,079 (19.5 [0.6]) | -
Jones, 2019 | Comprehensiveness (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | HPACT | 2014–2015 | 157^a^/251 (62.6) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 9.3 (0.8, 17.9), p<.05; Standard PC in facility with H-PACT versus facility without H-PACT= 1.0 (−3.0, 5.0), p= NS
Jones, 2019 | Comprehensiveness (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC with H-PACT Available | 2014–2015 | 814^a^/1,527 (53.3) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 9.3 (0.8, 17.9), p<.05; Standard PC in facility with H-PACT versus facility without H-PACT= 1.0 (−3.0, 5.0), p= NS
Jones, 2019 | Comprehensiveness (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC (HPACT unavailable) | 2014–2015 | 5271^a^/10,079 (52.3) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 9.3 (0.8, 17.9), p<.05; Standard PC in facility with H-PACT versus facility without H-PACT= 1.0 (−3.0, 5.0), p= NS
Jones, 2019 | Comprehensiveness (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience, Controlling for Site and Patient Covariates | HPACT | 2014–2015 | 156^a^/251 (62.0) | aRD (95% CI):; 7.5 (−1.6, 16.6), p= NS
Jones, 2019 | | Standard PC with H-PACT Available | 2014–2015 | 832^a^/1,527 (54.5) | aRD (95% CI):; 7.5 (−1.6, 16.6), p= NS
Jones, 2019 | Coordination (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | HPACT | 2014–2015 | 170^a^/251 (67.9 [5.3]) | -
Jones, 2019 | Coordination (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 869^a^/1,527 (56.9 [2.1]) | -
Jones, 2019 | Coordination (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 5261^a^/10,079 (52.2 [0.9]) | -
Jones, 2019 | Coordination (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | HPACT | 2014–2015 | 71^a^/251 (28.3 [4.9]) | -
Jones, 2019 | Coordination (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 519^a^/1,527 (34.0 [2.0]) | -
Jones, 2019 | Coordination (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 3528^a^/10,079 (35.0 [0.9]) | -
Jones, 2019 | Coordination (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | HPACT | 2014–2015 | 9^a^/251 (3.7 [3.2]) | -
Jones, 2019 | Coordination (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 139^a^/1,527 (9.1 [1.4]) | -
Jones, 2019 | Coordination (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 1300^a^/10,079 (12.9 [0.7]) | -
Jones, 2019 | Coordination (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | HPACT | 2014–2015 | 160^a^/251 (63.7) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 8.9 (−1.0, 21.0), p= NS; Standard PC in facility with H-PACT versus facility without H-PACT= 2.0 (−1.8, 7.1), p= NS
Jones, 2019 | Coordination (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC with H-PACT Available | 2014–2015 | 837^a^/1,527 (54.8) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 8.9 (−1.0, 21.0), p= NS; Standard PC in facility with H-PACT versus facility without H-PACT= 2.0 (−1.8, 7.1), p= NS
Jones, 2019 | Coordination (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC (HPACT unavailable) | 2014–2015 | 5322^a^/10,079 (52.8) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 8.9 (−1.0, 21.0), p= NS; Standard PC in facility with H-PACT versus facility without H-PACT= 2.0 (−1.8, 7.1), p= NS
Jones, 2019 | Coordination (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience, Controlling for Site and Patient Covariates | HPACT | 2014–2015 | 165^a^/251 (65.8) | aRD (95% CI):; 8.6 (−2.9, 20.1), p= NS
Jones, 2019 | | Standard PC with H-PACT Available | 2014–2015 | 873^a^/1,527 (57.2) | aRD (95% CI):; 8.6 (−2.9, 20.1), p= NS
Jones, 2019 | Self-management support (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | HPACT | 2014–2015 | 163^a^/251 (64.8 [4.2]) | -
Jones, 2019 | Self-management support (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 806^a^/1,527 (52.8 [1.8]) | -
Jones, 2019 | Self-management support (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 4667^a^/10,079 (46.3 [0.8]) | -
Jones, 2019 | Self-management support (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | HPACT | 2014–2015 | 55^a^/251 (22.1 [3.7]) | -
Jones, 2019 | Self-management support (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 324^a^/1,527 (21.2 [1.4]) | -
Jones, 2019 | Self-management support (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 2339^a^/10,079 (23.8 [0.7]) | -
Jones, 2019 | Self-management support (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | HPACT | 2014–2015 | 33^a^/251 (13.0 [3.0]) | -
Jones, 2019 | Self-management support (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 389^a^/1,527 (25.5 [1.6]) | -
Jones, 2019 | Self-management support (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 3014^a^/10,079 (29.9 [0.7]) | -
Jones, 2019 | Self-management support (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | HPACT | 2014–2015 | 149^a^/251 (59.5) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 8.0 (−1.3, 17.4), p= NS; Standard PC in facility with H-PACT versus facility without H-PACT= 4.6 (0.7, 8.5), p<.05
Jones, 2019 | Self-management support (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC with H-PACT Available | 2014–2015 | 785^a^/1,527 (51.4) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 8.0 (−1.3, 17.4), p= NS; Standard PC in facility with H-PACT versus facility without H-PACT= 4.6 (0.7, 8.5), p<.05
Jones, 2019 | Self-management support (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC (HPACT unavailable) | 2014–2015 | 4717^a^/10,079 (46.8) | aRD (95% CI):; H-PACT versus standard PC in facility with H-PACT= 8.0 (−1.3, 17.4), p= NS; Standard PC in facility with H-PACT versus facility without H-PACT= 4.6 (0.7, 8.5), p<.05
Jones, 2019 | Self-management support (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience, Controlling for Site and Patient Covariates | HPACT | 2014–2015 | 151^a^/251 (60.3) | aRD (95% CI):; 6.9 (−2.7, 16.6), p= NS
Jones, 2019 | | Standard PC with H-PACT Available | 2014–2015 | 815^a^/1,527 (53.4) | aRD (95% CI):; 6.9 (−2.7, 16.6), p= NS
Jones, 2019 | Shared decision-making (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | HPACT | 2014–2015 | 135^a^/251 (53.6 [5.2]) | -
Jones, 2019 | Shared decision-making (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 634^a^/1,527 (41.5 [2.1]) | -
Jones, 2019 | Shared decision-making (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Positive (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 3719^a^/10,079 (36.9 [0.9]) | -
Jones, 2019 | Shared decision-making (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | HPACT | 2014–2015 | 99^a^/251 (39.6 [5.1]) | -
Jones, 2019 | Shared decision-making (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 719^a^/1,527 (47.1 [2.1]) | -
Jones, 2019 | Shared decision-making (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Moderate (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 4505^a^/10,079 (44.7 [1.0]) | -
Jones, 2019 | Shared decision-making (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | HPACT | 2014–2015 | 17^a^/251 (6.8 [3.2]) | -
Jones, 2019 | Shared decision-making (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC with H-PACT Available | 2014–2015 | 176^a^/1,527 (11.5 [1.3]) | -
Jones, 2019 | Shared decision-making (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Negative (Unadjusted), % (SE) | Standard PC (HPACT unavailable) | 2014–2015 | 1855^a^/10,079 (18.4 [0.8]) | -
Jones, 2019 | Shared decision-making (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | HPACT | 2014–2015 | 120^a^/251 (48.0) | aRD (95% CI); H-PACT versus standard PC in facility with H-PACT= 8.4 (−2.3, 6.6), p= NS; Standard PC in facility with H-PACT versus facility without H-PACT= 2.1 (−2.9, 19.7), p= NS
Jones, 2019 | Shared decision-making (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC with H-PACT Available | 2014–2015 | 605^a^/1,527 (39.6) | aRD (95% CI); H-PACT versus standard PC in facility with H-PACT= 8.4 (−2.3, 6.6), p= NS; Standard PC in facility with H-PACT versus facility without H-PACT= 2.1 (−2.9, 19.7), p= NS
Jones, 2019 | Shared decision-making (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience | Standard PC (HPACT unavailable) | 2014–2015 | 3780^a^/10,079 (37.5) | aRD (95% CI); H-PACT versus standard PC in facility with H-PACT= 8.4 (−2.3, 6.6), p= NS; Standard PC in facility with H-PACT versus facility without H-PACT= 2.1 (−2.9, 19.7), p= NS
Jones, 2019 | Shared decision-making (2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients [PCMH-SHEP]), Adjusted probability of reporting a positive experience, Controlling for Site and Patient Covariates | HPACT | 2014–2015 | 130^a^/251 (51.8) | aRD (95% CI):; 10.2 (−2.0, 22.3), p= NS
Jones, 2019 | | Standard PC with H-PACT Available | 2014–2015 | 637^a^/1,527 (41.7) | aRD (95% CI):; 10.2 (−2.0, 22.3), p= NS
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Relationship (Unadjusted), N(%) | HPACT | 2015–2017 | 894/3323^a^ (26.9) | p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Relationship (Unadjusted), N(%) | Mainstream PACT | 2015–2017 | 767/2303^a^ (33.3) | p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Relationship (Weighted and Adjusted), Predicted Percentage (95% CI) | HPACT | 2015–2017 | nr/NR | 26.2% (22.6%–29.7%) vs 38.0% (33.7%–42.3%), p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Relationship (Weighted and Adjusted), Predicted Percentage (95% CI) | Mainstream PACT | 2015–2017 | nr/NR | 26.2% (22.6%–29.7%) vs 38.0% (33.7%–42.3%), p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Cooperation (Unadjusted), N(%) | HPACT | 2015–2017 | 828/2947^a^ (28.1) | p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Cooperation (Unadjusted), N(%) | Mainstream PACT | 2015–2017 | 747/2041^a^ (36.6) | p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Cooperation (Weighted and Adjusted), Predicted Percentage (95% CI) | HPACT | 2015–2017 | nr/NR | 27.9% (24.1%–31.6%) vs 39.3% (34.9%–43.7%), p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Cooperation (Weighted and Adjusted), Predicted Percentage (95% CI) | Mainstream PACT | 2015–2017 | nr/NR | 27.9% (24.1%–31.6%) vs 39.3% (34.9%–43.7%), p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Access/Coordination (Unadjusted), N(%) | HPACT | 2015–2017 | 881/3300^a^ (26.7) | p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Access/Coordination (Unadjusted), N(%) | Mainstream PACT | 2015–2017 | 802/2284^a^ (35.1) | p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Access/Coordination (Weighted and Adjusted), Predicted Percentage (95% CI) | HPACT | 2015–2017 | nr/NR | 25.0% (21.4%–28.6%) vs 36.7% (32.3%–41.0%), p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Access/Coordination (Weighted and Adjusted), Predicted Percentage (95% CI) | Mainstream PACT | 2015–2017 | nr/NR | 25.0% (21.4%–28.6%) vs 36.7% (32.3%–41.0%), p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Homeless-specific needs (Unadjusted), N(%) | HPACT | 2015–2017 | 1362/3123^a^ (43.6) | p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Homeless-specific needs (Unadjusted), N(%) | Mainstream PACT | 2015–2017 | 1046/1,940^a^ (53.9) | p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Homeless-specific needs (Weighted and Adjusted), Predicted Percentage (95% CI) | HPACT | 2015–2017 | nr/NR | 48.3% (43.7%–52.9%) vs 60.9% (56.5%–65.4%), p<.001
Kertesz, 2021 | Unfavorable Experience, Primary Care Quality-Homeless (PCQ-H) Scores-Homeless-specific needs (Weighted and Adjusted), Predicted Percentage (95% CI) | Mainstream PACT | 2015–2017 | nr/NR | 48.3% (43.7%–52.9%) vs 60.9% (56.5%–65.4%), p<.001

Notes.

a Calculated by the research team.

Abbreviations. aOR=adjusted odds ratio; aRD=adjusted risk difference; CI=confidence interval; GIM=general internal medicine; HOPC=homeless oriented primary care; HPACT=homeless patient aligned care teams; N=number; NR=not reported; OR=odds ratio; PACT=patient aligned care teams.

## G8. Patient Experience/Satisfaction (Non-Comparative)

Study | Outcome Definition | Sample/Groups | Timepoint | n/N (%) | Effect size, p-value
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Access, Negative (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (18.88) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Access, Positive (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (20.60) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Access, Negative (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (15.98) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Access, Positive (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (22.72) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Communication, Negative (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (15.17) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Communication, Positive (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (53.43) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Communication, Negative (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (13.00) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Communication, Positive (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (56.81) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Office staff helpfulness/courtesy, Negative (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (11.10) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Office staff helpfulness/courtesy, Positive (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (53.48) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Office staff helpfulness/courtesy, Negative (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (10.10) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Office staff helpfulness/courtesy, Positive (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (55.00) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Overall provider rating, Negative (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (12.51) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Overall provider rating, Positive (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (42.47) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Overall provider rating, Negative (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (10.42) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Overall provider rating, Positive (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (45.56) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Comprehensiveness, Negative (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (19.03) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Comprehensiveness, Positive (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (53.20) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Comprehensiveness, Negative (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (18.80) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Comprehensiveness, Positive (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (53.11) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Care coordination, Negative (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (13.08) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Care coordination, Positive (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (51.69) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Care coordination, Negative (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (12.59) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Care coordination, Positive (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (53.32) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Medication decision making, Negative (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (13.32) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Medication decision making, Positive (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (39.18) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Medication decision making, Negative (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (12.06) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Medication decision making, Positive (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (41.27) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Self-management support, Negative (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (30.78) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Self-management support, Positive (Unadjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (44.98) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Self-management support, Negative (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (31.44) | -
Jones, 2017 | Patient- Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP)- Self-management support, Positive (Adjusted), % | PACT (homeless only) | October 2012- September 2013 | nr/NR (45.71) | -

Abbreviations. NR=not reported; PACT=patient aligned care teams.

## G9. Housing and Community Integration

Study | Outcome Definition | Sample/Groups | Timepoint | n/N (%) | Effect Size, p-value
Chinchilla | Community Adjustment based on primary care status (N=418) | Primary Care Access, Yes | 1 year after housing | nr/NR | aOR (95% CI)= 1.01 (0.98, 1.04), p= 0.47
Chinchilla | Community Adjustment based on primary care status (N=418) | Primary Care Access, No | 1 year after housing | nr/NR | aOR (95% CI)= 1.01 (0.98, 1.04), p= 0.47
Chinchilla | Housing Stability based on primary care status (N=426) | Primary Care Access, Yes | 1 year after housing | nr/NR | aOR (95% CI)= 1.00 (0.95, 1.05), p= 0.87
Chinchilla | Housing Stability based on primary care status (N=426) | Primary Care Access, No | 1 year after housing | nr/NR | aOR (95% CI)= 1.00 (0.95, 1.05), p= 0.87
Chinchilla | Employment based on primary care status (N=144) | Primary Care Access, Yes | 1 year after housing | nr/NR | aOR (95% CI)= 0.96 (0.88, 1.06), p= 0.44
Chinchilla | Employment based on primary care status (N=144) | Primary Care Access, No | 1 year after housing | nr/NR | aOR (95% CI)= 0.96 (0.88, 1.06), p= 0.44
Johnson, 2017 | Housing status change during the study- Remained in or moved to unstable housing | Accessed primary care within 1 month of study enrollment | 6 months | 9/81 (11) | OR (95% CI)= 0.38 (0.16, 0.95), p= 0.038^a^
Johnson, 2017 | Housing status change during the study- Remained in or moved to unstable housing | Did not access primary care within 1 month of study enrollment | 6 months | 15/61 (24.6) | OR (95% CI)= 0.38 (0.16, 0.95), p= 0.038^a^
Johnson, 2017 | Housing status change during the study- Began in unstable housing & moved to stable housing | Accessed primary care within 1 month of study enrollment | 6 months | 25/81 (30.9) | OR (95% CI)= 2.03 (0.91, 4.54), p= 0.085^a^
Johnson, 2017 | Housing status change during the study- Began in unstable housing & moved to stable housing | Did not access primary care within 1 month of study enrollment | 6 months | 11/61 (18) | OR (95% CI)= 2.03 (0.91, 4.54), p= 0.085^a^
Johnson, 2017 | Housing status change during the study- Remained in stable housing | Accessed primary care within 1 month of study enrollment | 6 months | 47/81 (58) | OR (95% CI)= 1.03 (0.52, 2.01), p= 0.938^a^
Johnson, 2017 | Housing status change during the study- Remained in stable housing | Did not access primary care within 1 month of study enrollment | 6 months | 35/61 (57.4) | OR (95% CI)= 1.03 (0.52, 2.01), p= 0.938^a^

Notes.

a Calculated by the research team.

Abbreviations. aOR=adjusted odds ratio; CI=confidence interval; N=number; NR=not reported; OR=odds ratio.

## G10. Housing and Community Integration (Non-Comparative)

Study | Outcome Definition | Sample/Groups | Timepoint | n/N (%) | Effect Size, p-value
Chang 2020 | Receipt of any add-on intensive services- Housing services | Those receiving homeless specialized primary care | October 2015-September 2016 | 1484/2775 (53.5) | -

Abbreviations. N=number.

## G11. Disease-Specific Outcomes

Study | Outcome Definition | Sample/Groups | Timepoint | n/N (%) | Effect Size, p-value
O’Toole 2010 | Patients at target goal- Blood Pressure under 140/90 mm Hg | HOPC | 6 months | 26^a^/33 (78.8) | p= 0.45; OR (95% CI)= 1.24 (0.41, 3.72)^a^
O’Toole 2010 | Patients at target goal- Blood Pressure under 140/90 mm Hg | GIM | 6 months | 30^a^/40 (75.0) | p= 0.45; OR (95% CI)= 1.24 (0.41, 3.72)^a^
O’Toole 2010 | Patients at target goal- Diabetes Care, HbA1c under 7.0 | HOPC | 6 months | 4^a^/7 (57.1) | p= 0.76; OR (95% CI)= 1.14 (0.18, 7.28)^a^
O’Toole 2010 | Patients at target goal- Diabetes Care, HbA1c under 7.0 | GIM | 6 months | 7^a^/13 (53.8) | p= 0.76; OR (95% CI)= 1.14 (0.18, 7.28)^a^
O’Toole 2010 | Patients at target goal- Lipid Management, LDL under 100 mg/dL for patients with comorbid diabetes and coronary artery disease and under 130 mg/dL for all others | HOPC | 6 months | 17^a^/26 (65.4) | p<0.01; OR (95% CI)= 2.27 (0.83, 6.18)^a^
O’Toole 2010 | Patients at target goal- Lipid Management, LDL under 100 mg/dL for patients with comorbid diabetes and coronary artery disease and under 130 mg/dL for all others | GIM | 6 months | 20^a^/44 (45.5) | p<0.01; OR (95% CI)= 2.27 (0.83, 6.18)^a^
Riggs, 2020, 32181829 | Overdose (any) in the last 3 years | HPACT | 2018 | nr/NR | aOR= 1.09 (0.92, 1.28)
Riggs, 2020, 32181829 | Overdose (any) in the last 3 years | Mainstream Primary Care | 2018 | nr/NR | aOR= 1.09 (0.92, 1.28)
Riggs, 2020, 32181829 | Overdose (drug-related) in the last 3 years | HPACT | 2018 | nr/NR | aOR= 1.12 (0.91, 1.38)
Riggs, 2020, 32181829 | Overdose (drug-related) in the last 3 years | Mainstream Primary Care | 2018 | nr/NR | aOR= 1.12 (0.91, 1.38)
Riggs, 2020, 32181829 | Overdose (alcohol-related) in the last 3 years | HPACT | 2018 | nr/NR | aOR= 1.21 (0.96, 1.53)
Riggs, 2020, 32181829 | Overdose (alcohol-related) in the last 3 years | Mainstream Primary Care | 2018 | nr/NR | aOR= 1.21 (0.96, 1.53)

Notes.

a Calculated by the research team.

Abbreviations. aOR=adjusted odds ratio; CI=confidence interval; GIM=general internal medicine; HOPC=homeless oriented primary care; HPACT=homeless patient aligned care teams; N=number; NR=not reported; OR=odds ratio.