# APPENDIX F COMPARISONS AND HOMELESS IDENTIFICATION

Author Year PMID, Study Design | Data Source | Primary Care | Comparisons | Homelessness Identification
Chang, 2020, 32597993, Single Group | Electronic medical record data as of 2015 | Homeless specialized primary care | None^a^ | Those receiving homeless specialized primary care (not specified)
Chinchilla, 2019, 31297070, NRCS | Homeless Operations Management and Evaluation System (HOMES) data from 10/1/14 to 9/30/15 | Primary care (Unspecified) | Primary care access, Yes vs No | Not specified (appeared to be based HUD-VASH enrollment)
Gabrielian, 2021, 33543675, NRCS | Data were part of the Primary Care Homeless Services Tailoring study | HPACT, Mainstream PACT | HPACT vs mainstream | Evidence of homelessness between May 2015 and November 2017 (ICD-9/ICD-10 diagnoses of homelessness or VA-specific indicators of receipt of homeless services)^b^
Gundlapalli, 2017, 28806373, NRCS | Medical records from January 2012 and June 2013 | HPACT, Non-enrolled at HPACT site, Usual Care at non-HPACT site | Before vs after enrollment (HPACT); first 6 months vs second 6 months (other care); HPACT vs. Those at HPACT sites not enrolled in HPACT vs. Those in usual care sites without HPACT | identified using a combination of administrative codes indicating homelessness (ICD-9-CM code V60.0, lack of housing)^b,c,d^
Johnson, 2017, 28481601, NRCS | Post hoc analysis of a prospective, community-based randomized controlled trial of homeless veterans not receiving any ongoing primary or continuity care | Primary care (Unspecified) | Accessed primary care within 1 month of study enrollment vs not | Homeless veterans eligible for VA care (as confirmed by study protocol)^e,c,d^
Jones, 2017, 28481602, Single Group | 2013 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP) | PACT (homeless not specified) | None^a^ | Past-year ICD-9 codes in VHA administrative records one inpatient or outpatient visit where lack of housing (V60.0), unstable housing (V60.1), or other housing circumstances (V60.89, V60.9) were documented. ^b^
Jones, 2018, 29412071, Single Group | Electronic medical records from May 2012 to December 2013. | HPACT | Before vs. After HPACT enrollment | Not specified (though all participants enrolled in HPACT)
Jones, 2018, 29762272, NRCS | 2014–2015 Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP) | HPACT, Non-HPACT facilities | Receiving primary care at HPACT vs Non-HPACT Facilities | One inpatient or outpatient visit where lack of housing, unstable housing, or other housing circumstances were documented (ICD-9 codes V60.0, V60.1, V60.89, V60.9), or they received VHA homeless services in the year before the PCMH-SHEP ^b^
Jones, 2019, 30789541, NRCS | 2014–2015 Patient Centered Medical Home Survey of Healthcare Experiences of Patients (PCMH-SHEP) | HPACT, Standard primary care with H-PACT Available, PACT | HPACT vs. Standard PC with H-PACT Available vs. PACT | One inpatient or outpatient visit where lack of housing, unstable housing, or other housing circumstances were documented (ICD-9 codes V60.0, V60.1, V60.89, V60.9), or they received VHA homeless services in the year prior to the survey. ^b^
Jones, 2023, 35194740, Single Group | Electronic medical records March 1, 2018, and September 30, 2019 | Integrated Primary Care (IPC) | Before vs. After IPC enrollment | Homelessness was determined from international classification of disease (ICD) codes related to unstable housing and VA homeless service records. ^b^
Jones, 2023, 36810631, NRCS | VA administrative and patient health records from 2016 to 2019. | HPACT, PACT | HPACT vs PACT | Homelessness was designated from international classification of disease (ICD) codes and/or use of VA homeless services in the study year (details not specified)
Kertesz, 2013, 24148052, NRCS | Face-to-face survey from January 2011 through March 2012 | Homeless tailored primary care, Mainstream care | Tailored vs. Mainstream | Presumptive past or current homelessness was based on an International Classification of Diseases-9-CM code of V60.0 diagnosis.
Kertesz, 2021, 33827104, NRCS | National patient survey of 26 HPACT sites, dates of survey not specified. | HPACT, Mainstream PACT | HPACT vs. Mainstream PACT | Diagnosis of homelessness (V60.0, V60.1, V60.89 from ICD-9, and Z59.0, Z59.1, Z59.8, Z59.9 from ICD-10) or receipt of VA homeless services (VA administrative stop codes 504, 507, 508, 511, 522, 528–530, 555–556, 590, or 37 between May 2015-November 2017. ^b^
O’Toole, 2010, 20966377, NRCS | Medical records from 2006–2007 (or 2004–2006 for comparison group) | Homeless Oriented Primary Care (HOPC), General Internal Medicine Clinic care (GIM) (Historic control) | HOPC vs. GIM | For Homeless Orientated Primary Care group: Sheltering criteria of the Stewart B. McKinney Homeless Assistance Act.^d^ Sheltering categories: no shelter; emergency shelter in a “dusk-to-dawn” shelter; transitional and supportive housing; and doubling up.; For comparison group: According to the V.60 codes of the International Classification of Diseases, Ninth Revision (ICD-9)
O’Toole, 2013, 24148042 Single Group | Medical and administrative records from 2008 to 2011 | HPACT | None^a^ | For HPACT: Current homelessness, including unsheltered, emergency sheltered, in transitional housing, or doubled-up with family or a friend
O’Toole, 2016, 27032987 Single Group | Medical and administrative records to 2014 | HPACT | Before vs. After HPACT enrollment | Not specified (though all participants enrolled in HPACT)
O’Toole, 2018, 29451116, NRCS | Medical and administrative records and prospective survey from 2012 to 2014 | HPACT, PACT | HPACT vs PACT | Homelessness was defined according to criteria of the McKinney-Vento Act^d^ following a sheltering typology that includes unsheltered, staying in an emergency shelter, or staying in transitional housing. We also included veterans in unstable (nonpermanent) doubled-up arrangements with family or friends.
Riggs, 2020, 32181829 | Medical and administrative records and prospective survey | HPACT, Mainstream Primary Care | HPACT vs Mainstream Primary Care | Homelessness defined at least 1 ICD-9 or ICD-10 diagnosis of homelessness or VA-specific administrative indicators of receipt of VA homeless services in the preceding 30 months.^b^
Trivedi, 2018, 30151996 Single Group | Registry of all Veterans enrolled in HPACT as of January 1,2013 | HPACT | None^a^ | Not specified (though all participants enrolled in HPACT)

Notes.

a Only includes those from the homeless group

b Peterson R, Gundlapalli AV, Metraux S, Identifying homelessness among veterans using VA administrative data: opportunities to expand detection criteria. PloS One. 2015;10(7):e0132664 26172386

c US Department of Veterans Affairs Office of Inspector General VA Office of Inspector General. Homeless Incidence and Risk Factors for Becoming Homeless in Veterans. Washington, DC: VA Office of Inspector General; 2012. Available at: https://www.va.gov/oig/pubs/VAOIG-11-03428-173.pdf

d Defined by the Stewart B. McKinney-Vento Homeless Assistance Act

e O’Toole TP, Johnson EE, Borgia ML, Rose J. Tailoring Outreach Efforts to Increase Primary Care Use Among Homeless Veterans: Results of a Randomized Controlled Trial. J Gen Intern Med. 2015;30(7):886–898. doi:10.1007/s11606-015-3193-x.25673574

Abbreviations. HPACT=homeless patient aligned care teams; HUD-VASH=Housing and Urban Development-Veterans Affairs Supportive Housing; ICD=international classification of disease; NRCS=non-randomized comparative study; PACT=patient aligned care teams.