# APPENDIX E BASELINE CHARACTERISTICS

Author Year PMID, Study Design | Number | Race/Ethnicity, % | Age (Years); Mean (SD) | Male, % | Comorbidities, % | Served in Combat | Priority Status
Chang, 2020, 32597993^a^ | 2775 | White: NR; Hispanic: NR; Black: NR; Other: NR | NR | NR | Mental health: NR; Substance use: NR; Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR | NR | NR
Chinchilla, 2019, 31297070 | 560 | White: 205 (38.2); Hispanic: 91 (16.6); Black: 307 (57.2); Other: NR | 52.9 (12.9) | 524 (93.6) | Mental health: 85 (15.2); Substance use: 35 (6.3); Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR | NR | NR
Gabrielian, 2021, 33543675 | 969 | Non-Hispanic white: 365 (37.7); Hispanic, any race: 119 (12.3); Non-Hispanic black: 322 (33.2); Other: 163 (16.8) | 18–54: 291 (30.0); 55–64: 516 (53.2); ≥65: 162 (16.7) | 820 (84.6) | Mental health; Schizophrenia spectrum disorders: 364 (37.6); Bipolar spectrum disorders: 543 (56.0); Other psychotic disorders: 308 (31.8); Substance use; Alcohol problem: 298 (30.8); Drug problem: 192 (19.8); Other; Dementia: NR; Diabetes: 237 (24.6); Hypertension: 496 (51.4); Hyperlipidemia: NR | NR | NR
Gundlapalli, 2017, 28806373^b^ | 51886 | White: 21020 (40.5); Hispanic: NR; Black: 26754 (51.6); Other: 4090 (7.8) | 53.0 (11.2) | 47327 (91.2) | Mental health: NR; Substance use: NR; Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR | 3081 (5.9) | NR
Johnson, 2017, 28481601 | 142 | White: 88 (62.0); Hispanic: NR; Black: NR; Other: NR | 48.4 (11.1) | 134 (94.4) | Mental health; Depression 79 (55.6); Anxiety 66 (46.5); PTSD 44 (31.0); Substance use; Alcohol 96 (67.6); Marijuana 47 (33.1); Cocaine 19 (13.4); Other; Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR | NR | NR
Jones, 2017, 28481602^a^,^c^ | 4605 | White: (47.15); Hispanic: (8.37); Black: (38.17); Other: (6.31) | 18–44= 23.09; 45–54= 33.60; 55–64= 34.83; 65+= 8.47 | (87.3) | Mental health; Depressive disorders (62.71); Post-traumatic stress disorder (30.68); Other anxiety disorders (25.08); Bipolar disorder (17.38); Psychotic disorders (11.87); Substance use; Alcohol use disorder (36.73); Drug use disorder (36.51); Other; Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR | NR | NR
Jones, 2018, 29412071 | 179 | White: 100 (56.0); Hispanic: 7 (4.0); Black: 72 (40.0); Other: NR | NR | 167 (93.0) | Mental health: 74 (41.0); Substance use treatment; Tobacco: 73 (41.0); Alcohol: 46 (26.0); Opioid: 29 (16.0); Cocaine: 16 (9.0); Cannabis: 13 (7.0); Polysubstance: 5 (3.0); Sedative/Hypnotic: 3 (2.0); Other; Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR | NR | NR
Jones, 2018, 29762272^a,b^ | 12170 | White: 5600 (46.0); Hispanic: 1011 (8.3); Black: 4761 (39.1); Other: 806 (6.6) | N (%):; 18–4: 2636 (21.7); 45–54: 3121 (25.7); 55–64: 4412 (36.3); 65+: 1997 (16.3) | 10749 (88.3) | Mental health; Mood Disorder: 5906 (48.5); Posttraumatic Stress Disorder: 3054 (25.1); Other Anxiety Disorders: 2287 (18.8); Psychotic Disorder: 1043 (8.5); Substance use; Alcohol Use Disorder: 3275 (26.9); Drug Use Disorder: 3106 (25.5); Other; Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR | NR | NR
Jones, 2019, 30789541^b^,^c^ | 11857 | White: 5483 (46.2); Hispanic: NR; Black: 4611 (38.8); Other: 1758 (14.8) | 18–44: 2636 (22.2); 45–54: 3020 (24.4); 55–64: 4279 (36.1); 65+: 1968 (16.4) | 10466 (88.3) | Mental health; Mood disorder: 5746 (48.2); Post-traumatic stress disorder: 2984 (25.0); Other anxiety disorders: 2235 (18.5); Psychotic disorder: 1010 (8.3); Substance use; Alcohol use disorder: 3163 (26.7); Drug use disorder: 2992 (25.2); Other; Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR | NR | NR
Jones, 2023, 35194740^a^ | 123 | White: 96 (78.7); Hispanic: 8 (6.6); Black: 12 (9.8); Other: 6 (4.9) | 25–44= 42 (34.2); 45–64= 57 (46.3); 65+= 24 (19.5) | 114 (92.7) | Mental health; Depression: 81 (66.9); PTSD: 57 (46.3); Anxiety 50 (40.7); Serious Mental Illness 20 (16.3); Other 32 (26); Any of the above 119 (96.8); Substance use; Alcohol Use Disorder: 53 (43.1); Opioid Use Disorder: 40 (32.5); Stimulant Use Disorder: 50 (40.7); Cannabis Use Disorder: 31 (35.2); Other Drug Use Disorder: 16 (13); Any of the above: 90 (74.8); Other; Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR | NR | 50–100% service connected: 44(35.8); <50% service connected: 28 (22.8); no service connection: 51(41.5)
Jones, 2023, 36810631 | 2843 | White: 1189 (41.8); Hispanic: 537 (18.9); Black: 743 (26.1); Other: 159 (17.9) | 49.1 (15.2) | 2509 (88.3) | Mental health; Anxiety disorder 1207 (42.5%); Post-traumatic stress disorder 1371 (48.2%); Bipolar, schizophrenia, or other psychotic disorders 253 (8.9%); Substance use; Drug Use: 454 (16.0); Alcohol Use: 643 (22.6); Other; Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR | NR | NR
Kertesz, 2013, 24148052^b,d^ | 406 | White: 107 (26.4); Hispanic: 9 (2.2); Black: 271 (66.7); Other: 27 (6.7%) | 53.5 (7.6) | 379 (93.4) | Mental health: NR; Substance use: NR; Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR | NR | NR
Kertesz, 2021, 33827104 | 5766 | White: 2367 (41.1); Hispanic: 602 (10.7); Black: 2252 (39.1); Other: 1147 (19.9) | 58.7 (10.9) | 5158 (90.7) | Mental health; Presence of severe psychological distress, last 2 weeks: 1724 (32.6); Receipt of psychiatric medication in the last 30 days: 1961(34.7); Substance use; Drug Problem: 782 (13.8); Alcohol problem: 1624 (28.7); Personal overdose experience in last 3 years: 379 (6.7); Other; Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR
O’Toole, 2010, 20966377^b^ | 177 | White: 143 (80.8); Hispanic:; Black:; Other: | 52.4 (4.3) | 169 (95.4) | Mental health; Depression: 98 (55.4); Anxiety: 59 (33.3); Bipolar: 34 (19.2); Schizophrenia: 13 (7.3); Substance use; Alcohol: 114 (64.4); Cocaine: 51 (28.8); Heroin: 14 (7.9); Marijuana: 23 (12.9); Other; Dementia: NR; Diabetes: 21 (11.8); Hypertension: 78 (44.1); Hyperlipidemia: 75 (42.4) | NR | NR
O’Toole, 2013, 24148042^a^, ^b^ | 127 | White: 97 (76.4); Hispanic: NR; Black: NR; Other: NR | 51.2 (NR) | 120 (94.5) | Mental health: 75 (59.1); Substance use: 32 (25.4)^e^; Dementia: NR; Diabetes: 12 (9.4); Hypertension: 36 (28.3); Hyperlipidemia: NR | NR | NR
O’Toole, 2016, 27032987^f^ | 14088 | White: NR; Hispanic: NR; Black: NR; Other: NR | 53.4 (NR) | 13524 (95.9) | Mental health: NR; Substance use: NR; Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR | NR | NR
O’Toole, 2018, 29451116 | 266 | White: 120 (45.1); Hispanic: NR; Black: NR; Other: NR | 52.1 (9.2) | 251(94.4) | Mental health ^h^; Any mental health condition: 207 (78.1); Depression: 180 (69.2); Anxiety: 165 (63.2); PTSD: 125 (50.8); Bipolar: 47 (19.2); Substance use ^h^; Any drinking past six months: 162 (61.1); Cocaine use in past six months: 60 (22.6); Heroin or nonprescribed opiate use in past six months: 24 (9.0); Other; Dementia: NR; Diabetes: NR; Hypertension: 87 (33.1); Hyperlipidemia: NR | NR | NR
Riggs, 2020, 32181829^b^ | 5694 | White: 2345 (40.7); Black: 2225 (38.1); Hispanic: 593 (10.4) | 56.4 (18.3) | 5100 (91.6) | Mental health; Receiving medication for mental health: 1947 (34.2); Substance use; Alcohol problem: 1617 (28.4); Drug problem: 775 (13.6); Other; Dementia: NR; Diabetes: NR; Hypertension: NR; Hyperlipidemia: NR | NR | NR
Trivedi, 2018, 30151996^b,g^ | 1211 | White: 618 (51); Hispanic: NR; Black: 569 (47); Other: 24(2) | 59.5 (9.7) | 1175 (97) | Mental health; Psychosis/Schizophrenia: 193 (16.0%); Depression: 109 (9.0%); Substance use; Substance Abuse Disorder: 169 (14.0%); Alcohol Disorder: 205 (17.0%); Other; Dementia: NR; Diabetes: 96 (8.0); Hypertension: 230 (19.0); Hyperlipidemia: NR | NR | Group 1: 217 (18.0); Group 2: 48 (4.0); Group 3: 121 (10.0); Group 4: 24 (2.0); Group 5: 775 (64.0); Group 6,7,8: 24 (2.0)

Notes.

a Only includes those experiencing homelessness

b Includes estimates calculated by research team based on data provided in the study

c Estimates use survey weights

d Does not include tailored non-VA care group

e Active substance abuse

f The demographic data reported in this study were for the August 2014 enrollment of patients, which corresponds with the ambulatory care use outcomes of this study. Demographic details of patients included in the pre-enrollment and post-enrollment acute care use data were not reported. All numbers calculated by the research team from percents provided in the study

g Only include high reliance group

h Some numbers or percents do not add up to 100%/266 due to missing data.

Abbreviations. NR=not reported; SD=standard deviation.