# APPENDIX D DESIGN DETAILS

Author Year PMID | Setting, Funding | Study Design,^a^ Sample Source | Enrollment Dates | Inclusion Criteria | Exclusion Criteria | Supportive Program(s) Enrolled | Primary Care Program(s)
Chang, 2020, 32597993 | Community, VA funded research | Single Group,^b^ National | 2015 | Included all VHA patients assigned to primary care (general or specialized) as of September 30, 2015 | Patients who had died during this period for the purpose of assigning a CAN (Care Assessment Needs) score. | Not specified | Primary Care (specialized homelessness)
Chinchilla, 2019, 31297070 | Community, VA funded research and non-industry funding | NRCS, Medical Center | 2014 to 2015 | Participants enrolled in HUD-VASH who achieved housing within 1 year of program enrollment | Participants were excluded if they were enrolled in HUD-VASH program for more than 1 year; Participants data was excluded if they had duplicate or conflicting entries, and they did not have any report data on the primary outcomes of interest. | HUD-VASH | Primary Care (not specified)
Gabrielian, 2021, 33543675 | Community, VA funded research | NRCS, National | 2018 | VA patients were eligible if they: (a) received ≥2 primary care visits at a study site; (b) had evidence of homelessness between May 2015 and November 2017 in VA’s national electronic medical record and c) were assigned to a single primary care team. Survey respondents had to have at least 1 ICD-9/ICD-10 code for schizophrenia spectrum disorders, bipolar spectrum disorders, or other psychotic disorders in VA’s national EMR between May 2015 and November 2017. Data were taken from a previously conducted survey (Riggs, 2020). | Participants were excluded if they had no available contact information or were deceased prior to the start of the survey | Not specified^c^ | HPACT, mainstream primary care
Gundlapalli, 2017, 28806373 | Community, VA funded research | NRCS, National | 2012 to 2013 | Veterans were required to have had at least 2 visits with their VHA medical center in the 6 months before enrollment in H-PACT and at least 1 visit in the 6 months after enrollment;; Veterans assigned a V60.0 ICD-9-CM code at least twice between January 1, 2012 and December 31, 2012 and verified to not have had an assignment with a PACT team at their site (for non-HPACT sites);; Veterans assigned a V60.0 ICD-9-CM code at least twice between January 1, 2012 and December 31, 2012 and never having any evidence of enrollment in H-PACT or any other primary care team assignment (PACT) during the observation period. | VHA sites that did not offer emergency department services were excluded to allow for comparability between comparator groups | Not specified^c,d^ | HPACT, Usual care
Johnson, 2017, 28481601 | Community, VA funded research | NRCS, National | to 2017 | Homeless veterans eligible for VA care (as confirmed by study protocol) who had not received any primary or longitudinal specialty care in the previous 6 months (by self-report and confirmed by review of VA records).; Inclusion criteria from parent RCT:^e^ The study population was currently homeless Veterans^f^ eligible to receive VA services who were cognitively intact as measured by the Short Blessed test. Veterans currently receiving primary/continuity care for a chronic medical condition from a VA-based or non-VA-based provider (defined by any visit to an ambulatory care clinic in the previous 6 months and/or having a self-identified ambulatory care-based source for usual care) were excluded. | Participants not planning to stay in the area for the 6 months study period, those whose housing status could not be ascertained, and those with significant cognitive impairment as measured by the Short Blessed Test.; Exclusions criteria from parent study:^f^ Veterans currently receiving primary/continuity care for a chronic medical condition from a VA-based or non-VA-based provider were excluded. | Not specified^f^ | Primary care (not specified)
Jones, 2017, 28481602 | Community, VA funded research | Single Group,^b^ National | 2013 | Data were taken from the Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP). Parent survey inclusion criteria: Veterans who received VHA outpatient services in the index month, had a primary care visit with an assigned PACT provider during the 10 months prior to index month, and did not participate in the prior year’s survey.; Inclusion for study: in year prior to the survey, they experienced One inpatient or two outpatient visits with and ICD-9 diagnosis for common MHSUDs. | Patients with missing data on variables of interest. | Not specified^c^ | PACT
Jones, 2018, 29412071 | Outpatient, VA funded research | Single Group,^g^ Medical Center | 2012 to 2013 | Patients who had an initial clinic visit to the Veterans Affairs Pittsburgh Healthcare System (VAHPS) HPACT | NR | Not specified | HPACT
Jones, 2018, 29762272 | Outpatient, VA funded research | NRCS, Other | 2014 to 2015 | Data were taken from the Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP). Parent survey inclusion criteria: Veterans outpatients who (1) had an outpatient visit with the lead provider of their primary care team in the past 10 months, and (2) did not participate in the prior year’s survey.; Inclusion for study: Eligible veterans who visited a primary care provider at one of 510 VHA medical centers or CBOCs | Patients missing data on study variables | Not specified^c^ | HPACT, Non-HPACT
Jones, 2019, 30789541 | Community, VA funded research | NRCS, National | 2014 to 2015 | Data were taken from the Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients (PCMH-SHEP). Parent survey inclusion criteria: Patients who received VHA outpatient services, had a primary care visit with the lead provider of their assigned primary care team lead in past 10 months, and did not participate in the prior year’s survey.; Inclusion for study: Had recent administrative evidence of homelessness.^c^ | Veterans with missing data on study variables, patients assigned to H-PACT for only part of the year prior to survey, patients with H-PACT enrollment data who primarily received care at VHA facilities without any H-PACT. | Not Provided^c^ | HPACT, standard primary care
Jones, 2023, 35194740 | Outpatient, VA funded research | Single Group,^g^ Medical Center | 2018 to 2021 | Veterans enrolled in the Vulnerable Veteran Innovative Patient-Aligned Care Team (VIP) Initiative at VA Salt Lake City Health Care System | NR | Not specified^c^ | Integrated primary care (IPC)
Jones, 2023, 36810631 | Outpatient, VA funded research | NRCS, VISN | 2016 to 2019 | Patients with positive depression screen and were formally diagnosed with a depressive disorder or prescribed an antidepressant in the 12 months following their positive screen. | Patients receiving depression treatment during the 6 months prior to screening. | Not specified | HPACT, other PACT
Kertesz, 2013, 24148052 | Outpatient, VA funded research | NRCS, Medical Center | 2011 to March 2012 | Presumptive past or current homelessness and receipt of primary care at the site of care 2 or more times in the past 2 years. | NR | Not specified | VA homeless-tailored primary care program, non-tailored primary care
Kertesz, 2021, 33827104 | Community, VA funded research | NRCS, National | 2015 to 2017 | Evidence of homelessness and had 2 or more primary care visits in 24 months at the same site, assigned to a single mainstream PACT or H-PACT | Excluded homeless-experienced veterans (HEV) if their mainstream PACT care was located at an outlying clinic, remote from the Veterans Affairs Medical Centers that housed the HPACT | Not specified^c^ | Mainstream PACT, H-PACT
O’Toole, 2010, 20966377 | Outpatient, VA funded research | NRCS, Medical Center | 2006 to 2008 | Homeless patients who voluntarily enrolled in the Homeless-Oriented Primary Care Clinic at the Providence VA Medical Center or seasonally matched controls from the general internal medicine clinics identified from historic patient registry data | Excluded potential control participants if there was positive documentation that the patient was living in an apartment or house that the patient owned or paid rent for; Or if the patient moved out of the are or was institutionalized during a significant period of the 12-month study period | Not specified^f^ | Homeless-Oriented Primary Care Clinic, General internal medicine clinics
O’Toole, 2013, 24148042 | Outpatient, VA funded research | Single Group,^b^ Medical Center | 2008 to 2011 | Newly enrolled HPACT patients who had at least 2 visits with their primary care team within the first 6 months of enrollment. HPACT requirements were: Current homelessness, including unsheltered, emergency sheltered, in transitional housing, or doubled-up with family or a friend, and having difficulty accessing care in a traditional clinic setting. | Individuals were excluded if they moved out of the area, were institutionalized, or were incarcerated during the study. Individuals already established in primary care, either within the VA medical center or at another facility, who then became homeless and transferred their care to the homeless PACT clinic were also excluded. | Not specified | HPACT
O’Toole, 2016, 27032987 | Outpatient, VA funded research | Single Group,^g^ National | 2013 to2014 | Homeless veterans enrolled in HPACT as of August 1, 2014 | NR | HUD-VASH Grants and Per Diem (GPD) Veteran Justice Outreach (VJO) Health Care to Homeless Veterans, Veterans courts, and vocational assistance programs | HPACT
O’Toole, 2018, 29451116 | Outpatient, VA funded research | NRCS, Medical Center | 2012 to 2014 | Homeless (to include: the unsheltered and those in emergency shelters, transitional housing, or unstable housing with family or friends) veterans enrolled in either PACT or HPACT at the selected study sites | Veterans that have moved into Section 8 housing or HUD-VASH housing units; Veterans enrolled in intensive case management programs | Not specified^f^ | PACT, HPACT
Riggs, 2020, 32181829 | Community, VA funded research | NRCS, National | 2018 | Eligible veterans were those who had evidence of having experienced homelessness in the preceding 30 months, used the VA’s primary care services at 1 of 26 VA medical centers with HPACT available, including a single active panel assignment and 2 or more visits to a clinic with an administrative code indicating primary care at the same study site in the preceding 24 months. | Participants who had no contact information from VA or other records or had died prior to survey initiation. | Not specified^c^ | HPACT, Mainstream Primary Care
Trivedi, 2018, 30151996 | Community, VA funded research | Single Group,^h^ Other | 2013 | HPACT enrollees with 12 months of Medicare Fee-for-Service Coverage in 2013 | HPACT enrollees not enrolled in Medicare for 12 months in 2013; HPACT enrollees who had one or more months of Medicare Advantage enrollment | No Specified | HPACT

Notes.

a Design listed is based on it use in this review

b Includes only those experiencing homelessness

c Peterson R, Gundlapalli AV, Metraux S, Identifying homelessness among veterans using VA administrative data: opportunities to expand detection criteria. PloS One. 2015;10(7):e0132664 26172386

d US Department of Veterans Affairs Office of Inspector General VA Office of Inspector General. Homeless Incidence and Risk Factors for Becoming Homeless in Veterans. Washington, DC: VA Office of Inspector General; 2012. Available at: https://www.va.gov/oig/pubs/VAOIG-11-03428-173.pdf

e O’Toole TP, Johnson EE, Borgia ML, Rose J. Tailoring Outreach Efforts to Increase Primary Care Use Among Homeless Veterans: Results of a Randomized Controlled Trial. J Gen Intern Med. 2015;30(7):886–898. doi:10.1007/s11606-015-3193-x 25673574

f Defined by the Stewart B. McKinney-Vento Homeless Assistance Act

g Includes baseline and follow-up data

h High reliance group only.

Abbreviations. CBOs=community based organizations; HPACT=homeless patient aligned care teams; HUD-VASH=Housing and Urban Development-Veterans Affairs Supportive Housing; ICD=international classification of disease; MHSUDs=mental health and substance use disorders; NR=not reported; NRCS=non-randomized comparative study; PACT=patient aligned care teams; RCT=randomized controlled trial; VHA=Veterans Health Administration.