# APPENDIX C RISK OF BIAS ASSESSMENTS

Author, Year, PMID, Design | Random sequence generation (selection bias) | Allocation concealment | Blinding of participants and personnel | Blinding of outcome assessor | Incomplete outcome data (attrition bias) | Selective Reporting (reporting bias) | Intention-to-treat analysis | Clear reporting with no discrepancies | Were eligibility criteria clear? | Were interventions adequately described? | Were the outcomes fully defined? | NRCS & Single: Representativeness of the cohort(s) | NRCS: Comparator representativeness | NRCS: Adjustment for confounders | Other bias | Overall RoB
Chang, 2020, 3259799, SG | NA | NA | NA | Unclear | Low | NA | NA | Yes | Yes | Yes | Yes | Low | NA | NA | High^a^ | High^a^
Chinchilla,2019, 31297070, NRCS | NA | NA | NA | Low | Low | NA | NA | Yes | Yes | Yes | Yes | Low | Yes (low ROB) | Low^b^ | Low | Low
Gabrielian, 2021, 33543675, NRCS | NA | NA | NA | High^c^ | Low | NA | NA | Yes | Yes | Yes | Yes | Low | Yes (low ROB) | Low^b^ | Low | Moderate
Gundlapalli, 2017, 28806373, NRCS | NA | NA | NA | Low | Low | NA | NA | No^d^ | Yes | Yes | Yes | Low | No (high ROB)^e^ | Low^b^ | Low | High
Johnson, 2017, 28481601, NRCS | NA | NA | NA | Unclear | Low | Low | Low | Yes | Yes | Yes | Yes | Low | Yes (low ROB | High^f^ | Low | Moderate
Jones, 2023, 35194740, SG | NA | NA | NA | Low | Unclear | NA | NA | Yes | Yes | Yes | Yes | Low | NA | NA | Lows | Low
Jones, 2018, 29412071, SG | NA | NA | NA | Low | Low | NA | NA | Yes | Yes | Yes | Yes | Low | NA | NA | Low | Low
Jones, 2023, 36810631, NRCS | NA | NA | NA | Low | Low | NA | NA | Yes | Yes | Yes | Yes | Unclear | Yes (low ROB) | Low^b^ | Low | Low
Jones, 2017, 28481602, SG | NA | NA | NA | High ^c^ | Low | NA | NA | Yes | Yes | Yes | Yes | Low | NA | NA | High^a^ | High^a^
Jones, 2018, 29762272, NRCS | NA | NA | NA | High ^c^ | Low | NA | NA | Yes | Yes | Yes | Yes | Low | Yes (low ROB) | Low^b^ | Low | Moderate
Jones, 2019, 30789541, NRCS | NA | NA | NA | High ^c^ | Low | NA | NA | Yes | Yes | Yes | Yes | Low | Yes (low ROB) | Low^b^ | Low | Moderate
Kertesz, 2021, 33827104, NRCS | NA | NA | NA | High ^c^ | Low | NA | NA | Yes | Yes | Yes | Yes | Low | Yes (low ROB | Low^b^ | Low | Moderate
Kertesz, 2013, 24148052, NRCS | NA | NA | NA | Low | Low | NA | NA | Yes | Yes | Yes | Yes | Low | Yes (low ROB | High^f^ | Low | Moderate
O’Toole, 2010, 20966377, NRCS^g^ | NA | NA | NA | Low | Low | NA | NA | Yes | Yes | Yes | Yes | Low | No (High)^h^ | Low^b^ | Low | Moderate
O’Toole, 2018, 29451116, NRCS | NA | NA | NA | High ^c^ | Low | NA | NA | Yes | Yes | Yes | Yes | Unclear | Yes (low ROB) | Low^b^ | Low | Moderate
O’Toole, 2013, 24148042, SG | NA | NA | NA | Low | Low | NA | NA | Yes | Yes | Yes | Yes | Low | NA | NA | High^a^ | High^a^
O’Toole, 2016, 27032987, SG | NA | NA | NA | Low | Low | NA | NA | Yes | Yes | Yes | Yes | Unclear | NA | NA | Low | Low
Riggs, 2020, 32181829 NRCS | NA | NA | NA | Unclear | Unclear | NA | NA | Yes | Yes | Yes | Yes | Low | Unclear | Low^b^ | Low | Moderate
Trivedi, 2018, 30151996, SG | NA | NA | NA | Low | Unclear | NA | NA | Yes | Yes | Yes | Yes | Low | NA | NA | High^a^ | High^a^

Notes.

a Single group, no baseline-follow up comparison

b Regression adjustment

c Self-reported outcomes and participants not blind to assessment

d Reported results of comparisons were not clear

e Comparison group data taken from a separate facility

f Crude analysis (unadjusted comparison between groups)

g This study was evaluated as both a single group study and NRCS for different questions of interest

h Comparison group data was collected at a different time point, data did not surround any care engagement event, and there were baseline differences in mental health and substance use conditions, as well as health care utilization.

Abbreviations. NA=not applicable; NRCS=non-randomized comparative study; SG=single group study.