# APPENDIX B STUDIES EXCLUDED DURING FULL-TEXT SCREENING

Citation and Reason for Exclusion
Bhalla IP, Stefanovics EA, Rosenheck RA. Social determinants of mental health care systems: intensive community based care in the Veterans Health Administration. BMC Public Health. 2020;20(1):1311. Not comparison/outcome of interest.32859202
Blonigen D, Hyde J, McInnes DK, Integrating data analytics, peer support, and whole health coaching to improve the health outcomes of homeless veterans: study protocol for an effectiveness-implementation trial. Contemporary Clinical Trials. article (non-systematic), editorial, case report/case series, protocol, or other publication type not of interest.
Blue-Howells J, McGuire J, Nakashima J. Co-location of health care services for homeless veterans: a case study of innovation in program implementation. Social Work in Health Care. 2008;47(3):219–31. Review article (non-systematic), editorial, case report/case series, protocol, or other publication type not of interest.19042482
Chang ET, Zulman DM, Nelson KM, Use of general primary care, specialized primary care, and other veterans affairs services among high-risk veterans. JAMA Network Open. 2020;3(6):E208120. Duplicate.32597993
Chrystal JG, Glover DL, Young AS, Experience of primary care among homeless individuals with mental health conditions. PloS One. 2015;10(2):e0117395. Non-Veteran population.25659142
Chrystal JG, Glover DL, Young AS, Experience of primary care among homeless individuals with mental health conditions. PloS One. 2015;10(2):e0117395. Duplicate.25659142
Davis JA, Tsui I, Gelberg L, Gabrielian S, Lee ML, Chang ET. Risk factors for diabetic retinopathy among homeless veterans. Psychological Services. 2017;14(2):221–228. Not comparison/outcome of interest.28481608
Etchin AG, LaCoursiere-Zucchero T, McDannold SE, McInnes DK. Dual use of Department of Veterans Affairs and community healthcare: homeless veterans' experiences, perspectives, and perceptions. Journal of the American Association of Nurse Practitioners. 2021;33(11):991–998. Wrong study design.34747906
Gabrielian S, Hamilton AB, Alexandrino A, Hellemann G, Young AS. "They're homeless in a home": retaining homeless-experienced consumers in supported housing. Psychological Services. 2017;14(2):154–166. Wrong study design.28481600
Gabrielian S, Jones AL, Hoge AE, Enhancing primary care experiences for homeless patients with serious mental illness: results from a national survey. Journal of Primary Care & Community Health. 2021;12:2150132721993654. Duplicate.
Gabrielian S, Yuan AH, Andersen RM, Rubenstein LV, Gelberg L. VA health service utilization for homeless and low-income veterans: a spotlight on the VA Supportive Housing (VASH) program in greater Los Angeles. Medical Care. 2014;52(5):454–61. Not comparison/outcome of interest.24714583
Gelberg L, Edwards ST, Hooker ER, Integrating interprofessional trainees into a complex care program for veterans experiencing homelessness: effects on health services utilization. Journal of General Internal Medicine. 2021;36(12):3659–3664. Not intervention of interest.34595681
Jones AL, Gordon AJ, Gabrielian SE, Perceptions of care coordination among homeless veterans receiving medical care in the veterans health administration and community care settings results from a national survey. Medical Care. 2021;59(6):504–512. Wrong setting.33827108
Jones AL, Hausmann LRM, Kertesz S, Differences in experiences with care between homeless and nonhomeless patients in Veterans Affairs facilities with tailored and nontailored pimary care teams. Medical Care. 2018;56(7):610–618. Duplicate.29762272
Jones AL, Hausmann LRM, Kertesz SG, Providing positive primary care experiences for homeless veterans through tailored medical homes: the Veterans Health Administration's Homeless Patient Aligned Care Teams. Medical Care. 2019;57(4):270–278. Duplicate.30789541
Kertesz SG, deRussy AJ, Kim Y- I, Comparison of patient experience between primary care settings tailored for homeless clientele and mainstream care settings. Medical Care. 2021;59(6):495–503. Duplicate.33827104
Kertesz SG, Holt CL, Steward JL, Comparing homeless persons' care experiences in tailored versus nontailored primary care programs. American Journal of Public Health. 2013;103 Suppl 2:S331–9. Duplicate.24148052
McGuire J, Gelberg L, Blue-Howells J, Rosenheck RA. Access to primary care for homeless veterans with serious mental illness or substance abuse: a follow-up evaluation of co-located primary care and homeless social services. Administration and Policy in Mental Health. 2009;36(4):255–64. Not comparison/outcome of interest.19280333
McGuire J, Rosenheck R. The quality of preventive medical care for homeless veterans with mental illness. Journal for Healthcare Quality: Official Publication of the National Association for Healthcare Quality. 2005;27(6):26–32. Not comparison/outcome of interest.
Montgomery AE, Cusack M, Szymkowiak D, Fargo J, O'Toole T. Factors contributing to eviction from permanent supportive housing: lessons from HUD-VASH. Evaluation and Program Planning. 2017;61:55–63. Not comparison/outcome of interest.27940343
O'Toole TP, Buckel L, Bourgault C, Applying the chronic care model to homeless veterans: effect of a population approach to primary care on utilization and clinical outcomes. American Journal of Public Health. 2010;100(12):2493–9. Duplicate.20966377
O'Toole TP, Buckel L, Bourgault C, Applying the chronic care model to homeless veterans of a population approach to primary care on utilization and clinical outcomes. American Journal of Public Health. 2010;100(12):2493–2499. Duplicate.20966377
O'Toole TP, Johnson EE, Borgia ML, Rose J. Tailoring outreach efforts to increase primary care use among homeless veterans: results of a randomized controlled trial. Journal of General Internal Medicine. 2015;30(7):886–98. Not intervention of interest.25673574
O'Toole TP, Johnson EE, Redihan S, Borgia M, Rose J. Needing primary care but not getting it: the role of trust, stigma and organizational obstacles reported by homeless veterans. Journal of Health Care for the Poor and Underserved. 2015;26(3):1019–31. Not comparison/outcome of interest.26320930
Simmons MM, Gabrielian S, Byrne T, A Hybrid III stepped wedge cluster randomized trial testing an implementation strategy to facilitate the use of an evidence-based practice in VA Homeless Primary Care Treatment Programs. Implementation Science. 2017;12(1):46. Review article (non-systematic), editorial, case report/case series, protocol, or other publication type not of interest.28376839
Swankoski KE, Reddy A, Grembowski D, Chang ET, Wong ES. Intensive care management for high-risk veterans in a patient-centered medical home – do some veterans benefit more than others? Healthcare. 2023;11(2)100677. Not specific to individuals at risk of or experiencing homelessness.36764053
Temblique EKR, Foster K, Fujimoto J, Kopelson K, Borthwick KM, Capone-Newton P. A 1-Year review of a nationally led intervention to improve suicide prevention screening at a large homeless veterans clinic. Federal Practitioner. 2022;39(1):12–18. No intervention of interest.35185314
Tsai J, Havlik J, Howell BA, Johnson E, Rosenthal D. Primary care for veterans experiencing homelessness: a narrative review of the Homeless Patient Aligned Care Team (HPACT) Model. Journal of General Internal Medicine. 2023;38(3):765–783. Review article (non-systematic), editorial, case report/case series, protocol, or other publication type not of interest.36443628
Zulman DM, Chee CP, Ezeji-Okoye SC, Effect of an intensive outpatient program to augment primary care for high-need veterans affairs patients a randomized clinical trial. Article. JAMA Internal Medicine. 2017;177(2):166–175. Not specific to individuals at risk of or experiencing homelessness.28027338

Notes. Five excluded records were duplicates within this list.