# APPENDIX A SEARCH STRATEGIES

Search Date: 03/26/2024 | | Search Statement | Results
Ovid Medline | 1 | exp Primary Health Care/ or Physicians, Family/ or Physicians, Primary Care/ or General Practitioners/ or Family Practice/ or Community Health Services/ or Community Health Nursing/ or exp Community Health Centers/ or Family Nursing/ or Mobile Health Units/ or ((primary adj3 (care or healthcare)) or ((annual or health or wellness) adj3 (exam* or visit*)) or ((family or general) adj3 (doctor* or medicine or nurse* or physician* or practi*)) or (collaborative adj2 (care or model* or practi?e*)) or (community adj3 (health* or nurs*)) or (mobile adj3 (hospital* or health unit* or health van* or clinic*)) or ((coordinat* or co-locat* or colocat* or integrat*) adj3 (health service* or health care or healthcare)) or (patient-centered adj3 medical home*) or PCMH or (patient aligned adj (care or healthcare) adj team*) or PACT or PACTs).ti,ab,kf. | 662562
Ovid Medline | 2 | Veterans/ or Veterans Health/ or Veterans Health Services/ or veteran*.ti,ab,kf. | 49894
Ovid Medline | 3 | exp Ill-Housed Persons/ or exp Homeless Persons/ or (homeless* or ill-housed or “no fixed address” or roofless* or rough sleep* or squatter* or ((street or transient*) adj3 (adolescent* or adult* or dweller* or individual* or man or men or people* or person* or population* or teen* or woman or women or youth*)) or ((inequalit* or insecurit* or instabilit* or lack or nonpermanent or non-permanent or precarious or temporary or supportive or unstable* or vulnerab*) adj2 (home* or hous* or accommodation* or apartment* or shelter* or hostel* or dwelling*))).ti,ab,kf. | 26748
Ovid Medline | 4 | and/1–3 | 220
Ovid Medline | 5 | (Compensated Work Therapy or CWT or Domiciliary Care for Homeless Veterans or DCHV or “Grants and Per Diem” or GPD or Health Care for Reentry Veterans or HCRV or Health Care for Homeless Veterans or HCHV or Homeless Veteran Community Employment or HVCES or Homeless Veterans Dental Program or Stand Down* or “Substance Use Disorder Treatment Enhancement Initiative” or Supportive Services for Veteran Families or SSVF or Veterans Affairs Supportive Housing or VA Supportive Housing or HUD-VASH or Veteran Justice Outreach or VJO).ti,ab,kf. | 2429
Ovid Medline | 6 | 1 and 5 | 36
Ovid Medline | 7 | (HPACT or HPACTs or Homeless Patient Aligned Care Team*).ti,ab,kf. | 22
Ovid Medline | 8 | 4 or 6 or 7 | 247
Cochrane | 1 | MeSH descriptor: [Primary Health Care] explode all trees | 11756
Cochrane | 2 | MeSH descriptor: [Physicians, Family] this term only | 538
Cochrane | 3 | MeSH descriptor: [Physicians, Primary Care] this term only | 243
Cochrane | 4 | MeSH descriptor: [General Practitioners] this term only | 592
Cochrane | 5 | MeSH descriptor: [Family Practice] this term only | 2373
Cochrane | 6 | MeSH descriptor: [Community Health Services] this term only | 1371
Cochrane | 7 | MeSH descriptor: [Community Health Nursing] this term only | 387
Cochrane | 8 | MeSH descriptor: [Community Health Centers] explode all trees | 715
Cochrane | 9 | MeSH descriptor: [Family Nursing] this term only | 48
Cochrane | 10 | MeSH descriptor: [Mobile Health Units] this term only | 84
Cochrane | 11 | ((primary NEAR/3 (care or healthcare)) or ((annual or health or wellness) NEAR/3 (exam* or visit*)) or ((family or general) NEAR/3 (doctor* or medicine or nurse* or physician* or practi*)) or (collaborative NEAR/2 (care or model* or practi?e*)) or (community NEAR/3 (health* or nurs*)) or (mobile NEAR/3 (hospital* or health unit* or health van* or clinic*)) or ((coordinat* or co-locat* or colocat* or integrat*) NEAR/3 (health service* or health care or healthcare)) or (patient-centered NEAR/3 medical home*) or PCMH or (patient aligned NEAR/1 (care or healthcare) NEAR/1 team*) or PACT or PACTs):ti,ab,kw | 67505
Cochrane | 12 | {or #1-#11} | 71931
Cochrane | 13 | MeSH descriptor: [Veterans] this term only | 1665
Cochrane | 14 | MeSH descriptor: [Veterans Health] this term only | 72
Cochrane | 15 | MeSH descriptor: [Veterans Health Services] this term only | 9
Cochrane | 16 | veteran*:ti,ab,kw | 7541
Cochrane | 17 | {or #13-#16} | 7541
Cochrane | 18 | MeSH descriptor: [Ill-Housed Persons] explode all trees | 543
Cochrane | 19 | (homeless* or ill-housed or “no fixed address” or roofless* or rough sleep* or squatter* or ((street or transient*) NEAR/3 (adolescent* or adult* or dweller* or individual* or man or men or people* or person* or population* or teen* or woman or women or youth*)) or ((inequalit* or insecurit* or instabilit* or lack or nonpermanent or non-permanent or precarious or temporary or supportive or unstable* or vulnerab*) NEAR/2 (home* or hous* or accommodation* or apartment* or shelter* or hostel* or dwelling*))):ti,ab,kw | 1923
Cochrane | 20 | #18 or #19 | 1923
Cochrane | 21 | #12 and #17 and #20 | 40
Cochrane | 22 | (Compensated Work Therapy or CWT or Domiciliary Care for Homeless Veterans or DCHV or “Grants and Per Diem” or GPD or Health Care for Reentry Veterans or HCRV or Health Care for Homeless Veterans or HCHV or Homeless Veteran Community Employment or HVCES or Homeless Veterans Dental Program or Stand Down* or “Substance Use Disorder Treatment Enhancement Initiative” or Supportive Services for Veteran Families or SSVF or Veterans Affairs Supportive Housing or VA Supportive Housing or HUD-VASH or Veteran Justice Outreach or VJO):ti,ab,kw | 919
Cochrane | 23 | #12 and #22 | 117
Cochrane | 24 | (HPACT or HPACTs or Homeless Patient Aligned Care Team*):ti,ab,kw | 5
Cochrane | 25 | #21 or #23 or #24 | 97
CINAHL | 1 | ((MH “Primary Health Care”) or (MH “Physicians, Family”) or (MH “Family Practice”) or (MH “Community Health Services+”) or (MH “Community Health Nursing+”) or (MH “Community Health Centers+”) or (MH “Family Nurses”) or (MH “Family Nursing”) or (MH “Family Nurse Practitioners”) or (MH “Mobile Health Units”)) OR TI (((primary N3 (care or healthcare)) or ((annual or health or wellness) N3 (exam* or visit*)) or ((family or general) N3 (doctor* or medicine or nurse* or physician* or practi*)) or (collaborative N2 (care or model* or practi?e*)) or (community N3 (health* or nurs*)) or (mobile N3 (hospital* or health unit* or health van* or clinic*)) or ((coordinat* or co-locat* or colocat* or integrat*) N3 (health service* or health care or healthcare)) or (patient-centered N3 medical home*) or PCMH or (patient aligned N1 (care or healthcare) N1 team*) or PACT or PACTs)) OR AB (((primary N3 (care or healthcare)) or ((annual or health or wellness) N3 (exam* or visit*)) or ((family or general) N3 (doctor* or medicine or nurse* or physician* or practi*)) or (collaborative N2 (care or model* or practi?e*)) or (community N3 (health* or nurs*)) or (mobile N3 (hospital* or health unit* or health van* or clinic*)) or ((coordinat* or co-locat* or colocat* or integrat*) N3 (health service* or health care or healthcare)) or (patient-centered N3 medical home*) or PCMH or (patient aligned N1 (care or healthcare) N1 team*) or PACT or PACTs)) | 819396
CINAHL | 2 | (MH “Veterans+”) or (MH “Veterans Health Services”) or veteran* | 36592
CINAHL | 3 | (MH “Homeless Persons”) OR TI ((homeless* or ill-housed or “no fixed address” or roofless* or rough sleep* or squatter* or ((street or transient*) N3 (adolescent* or adult* or dweller* or individual* or man or men or people* or person* or population* or teen* or woman or women or youth*)) or ((inequalit* or insecurit* or instabilit* or lack or nonpermanent or non-permanent or precarious or temporary or supportive or unstable* or vulnerab*) N2 (home* or hous* or accommodation* or apartment* or shelter* or hostel* or dwelling*)))) OR AB ((homeless* or ill-housed or “no fixed address” or roofless* or rough sleep* or squatter* or ((street or transient*) N3 (adolescent* or adult* or dweller* or individual* or man or men or people* or person* or population* or teen* or woman or women or youth*)) or ((inequalit* or insecurit* or instabilit* or lack or nonpermanent or non-permanent or precarious or temporary or supportive or unstable* or vulnerab*) N2 (home* or hous* or accommodation* or apartment* or shelter* or hostel* or dwelling*)))) | 18001
CINAHL | 4 | S1 and S2 and S3 | 187
CINAHL | 5 | TI ((Compensated Work Therapy or CWT or Domiciliary Care for Homeless Veterans or DCHV or “Grants and Per Diem” or GPD or Health Care for Reentry Veterans or HCRV or Health Care for Homeless Veterans or HCHV or Homeless Veteran Community Employment or HVCES or Homeless Veterans Dental Program or Stand Down* or “Substance Use Disorder Treatment Enhancement Initiative” or Supportive Services for Veteran Families or SSVF or Veterans Affairs Supportive Housing or VA Supportive Housing or HUD-VASH or Veteran Justice Outreach or VJO)) OR AB ((Compensated Work Therapy or CWT or Domiciliary Care for Homeless Veterans or DCHV or “Grants and Per Diem” or GPD or Health Care for Reentry Veterans or HCRV or Health Care for Homeless Veterans or HCHV or Homeless Veteran Community Employment or HVCES or Homeless Veterans Dental Program or Stand Down* or “Substance Use Disorder Treatment Enhancement Initiative” or Supportive Services for Veteran Families or SSVF or Veterans Affairs Supportive Housing or VA Supportive Housing or HUD-VASH or Veteran Justice Outreach or VJO)) | 346
CINAHL | 6 | S1 and S5 | 41
CINAHL | 7 | (HPACT or HPACTs or Homeless Patient Aligned Care Team*) | 14
CINAHL | 8 | S4 or S6 or S7 | 217
PsycInfo | 1 | exp Primary Health Care/ or Physicians, Family/ or General Practitioners/ or Family Medicine/ or exp Community Mental Health Services/ or Community Mental Health Centers/ or ((primary adj3 (care or healthcare)) or ((annual or health or wellness) adj3 (exam* or visit*)) or ((family or general) adj3 (doctor* or medicine or nurse* or physician* or practi*)) or (collaborative adj2 (care or model* or practi?e*)) or (community adj3 (health* or nurs*)) or (mobile adj3 (hospital* or health unit* or health van* or clinic*)) or ((coordinat* or co-locat* or colocat* or integrat*) adj3 (health service* or health care or healthcare)) or (patient-centered adj3 medical home*) or PCMH or (patient aligned adj (care or healthcare) adj team*) or PACT or PACTs).ti,ab | 131367
PsycInfo | 2 | Military Veterans/ or veteran*.ti,ab | 28094
PsycInfo | 3 | exp Homeless/ or (homeless* or ill-housed or “no fixed address” or roofless* or rough sleep* or squatter* or ((street or transient*) adj3 (adolescent* or adult* or dweller* or individual* or man or men or people* or person* or population* or teen* or woman or women or youth*)) or ((inequalit* or insecurit* or instabilit* or lack or nonpermanent or non-permanent or precarious or temporary or supportive or unstable* or vulnerab*) adj2 (home* or hous* or accommodation* or apartment* or shelter* or hostel* or dwelling*))).ti,ab | 18002
PsycInfo | 4 | and/1–3 | 89
PsycInfo | 5 | (Compensated Work Therapy or CWT or Domiciliary Care for Homeless Veterans or DCHV or “Grants and Per Diem” or GPD or Health Care for Reentry Veterans or HCRV or Health Care for Homeless Veterans or HCHV or Homeless Veteran Community Employment or HVCES or Homeless Veterans Dental Program or Stand Down* or “Substance Use Disorder Treatment Enhancement Initiative” or Supportive Services for Veteran Families or SSVF or Veterans Affairs Supportive Housing or VA Supportive Housing or HUD-VASH or Veteran Justice Outreach or VJO).ti,ab | 293
PsycInfo | 6 | 1 and 5 | 8
PsycInfo | 7 | (HPACT or HPACTs or Homeless Patient Aligned Care Team*).ti,ab | 4
PsycInfo | 8 | 4 or 6 or 7 | 90
Scopus | 1 | TITLE-ABS-KEY((primary W/3 (care OR healthcare)) OR ((annual OR health OR wellness) W/3 (exam* OR visit*)) OR ((family OR general) W/3 (doctor* OR medicine OR nurse* OR physician* OR practi*)) OR (collaborative W/2 (care OR model* OR practi?e*)) OR (community W/3 (health* OR nurs*)) OR (mobile W/3 (hospital* OR “health unit” OR “health units” OR “health van” OR “health van” OR clinic*)) OR ((coordinat* OR co-locat* OR colocat* OR integrat*) W/3 (“health service” OR “health services” OR “health care” OR healthcare)) OR (patient-centered W/3 (“medical home” OR “medical homes”)) OR pcmh OR (patient-aligned W/1 (care OR healthcare) W/1 team*) OR PACT OR PACTs) | 896282
Scopus | 2 | TITLE-ABS-KEY(veteran*) | 69228
Scopus | 3 | TITLE-ABS-KEY(homeless* or ill-housed or “no fixed address” or roofless* or “rough sleep” or “rough sleeping” or squatter* or ((street or transient*) W/3 (adolescent* or adult* or dweller* or individual* or man or men or people* or person* or population* or teen* or woman or women or youth*)) or ((inequalit* or insecurit* or instabilit* or lack or nonpermanent or non-permanent or precarious or temporary or supportive or unstable* or vulnerab*) W/2 (home* or hous* or accommodation* or apartment* or shelter* or hostel* or dwelling*))) | 63849
Scopus | 4 | 1 and 2 and 3 | 263
Scopus | 5 | TITLE-ABS-KEY(“Compensated Work Therapy” or CWT or “Domiciliary Care for Homeless Veterans” or DCHV or “Grants and Per Diem” or GPD or “Health Care for Reentry Veterans” or HCRV or “Health Care for Homeless Veterans” or HCHV or “Homeless Veteran Community Employment” or HVCES or “Homeless Veterans Dental Program” or “Stand Down” or “Stand Downs” or “Substance Use Disorder Treatment Enhancement Initiative” or “Supportive Services for Veteran Families” or SSVF or “Veterans Affairs Supportive Housing” or “VA Supportive Housing” or HUD-VASH or “Veteran Justice Outreach” or VJO) | 11118
Scopus | 6 | 1 and 5 | 50
Scopus | 7 | TITLE-ABS-KEY(HPACT or HPACTs or “Homeless Patient Aligned Care”) | 25
Scopus | 8 | 4 or 6 or 7 | 309
ClinicalTrials.gov | 1 | Condition/Disease: Homelessness and Other Terms: VA
ClinicalTrials.gov | 2 | Condition/Disease: Homelessness and Other Terms: veterans
ClinicalTrials.gov | 3 | Condition/Disease: Homelessness and Other Terms: PACT
ClinicalTrials.gov | 4 | Condition/Disease: Homelessness and Other Terms: HPACT | 52
| | Total | 1,012
| | Total after deduplication | 654