# ABBREVIATIONS TABLE

Abbreviation: Definition
aOR: Adjusted odds ratio
aRD: Adjusted risk difference
CWT: Compensated Work Therapy
DCHV: Domiciliary Care for Homeless Veterans
GERIPACT: Geriatric PACT
GPD: Grant and Per Diem
GRADE: Grading of Recommendations Assessment, Development and Evaluation
HCHV: Health Care for Homeless Veterans
HCRV: Health Care for Re-entry Veterans
HPACT: Homeless Patient Aligned Care Team
HUD-VASH: US Department of Housing and Urban Development-VA Supportive Housing
HVCES: Homeless Veteran Community Employment Services
ICD: International classification of disease
KQ: Key question
MD: Mean difference
MeSH: Medical subject headings
MOST: Multiphase optimization strategy
NR: Not reported
NRCS: Nonrandomized comparative studies
OR: Odds ratio
PACT: Patient Aligned Care Team
PCMH-SHEP: Patient-Centered Medical Home-Survey of Healthcare Experiences of Patients
PCQ-H: Primary Care Quality-Homeless survey
RCT: Randomized controlled trial
RD: Risk difference
SD: Standard deviation
SRDR+: Systematic Review Data Repository
SSVF: Supportive Services for Veteran Families
TEP: Technical expert panel
VA: Department of Veteran Affairs
VHA: Veterans Health Administration
VJO: Veteran Justice Outreach