# REFERENCES

1 Savarese G, Lund LH. Global Public Health Burden of Heart Failure. Card Fail Rev. Apr 2017;3(1):7–11. doi:10.15420/cfr.2016:25:2 28785469
2 Virani SS, Alonso A, Benjamin EJ, . Heart Disease and Stroke Statistics-2020 Update: A Report From the American Heart Association. Circulation. Mar 3 2020;141(9):e139–e596. doi:10.1161/cir.0000000000000757 31992061
3 Groeneveld PW, Medvedeva EL, Walker L, Segal AG, Menno DM, Epstein AJ. Association Between Spending and Survival of Chronic Heart Failure Across Veterans Affairs Medical Centers. JAMA Network Open. 2019;2(7):e197238–e197238. doi:10.1001/jamanetworkopen.2019.7238 31322689
4 Ziaeian B, Fonarow GC. The Prevention of Hospital Readmissions in Heart Failure. Prog Cardiovasc Dis. Jan–Feb 2016;58(4):379–85. doi:10.1016/j.pcad.2015.09.004 26432556
5 Dunlay SM, Redfield MM, Weston SA, . Hospitalizations after heart failure diagnosis a community perspective. J Am Coll Cardiol. Oct 27 2009;54(18):1695–702. doi:10.1016/j.jacc.2009.08.019 19850209
6 Roger VL. Epidemiology of Heart Failure: A Contemporary Perspective. Circ Res. May 14 2021;128(10):1421–1434. doi:10.1161/circresaha.121.318172 33983838
7 Joseph SM, Cedars AM, Ewald GA, Geltman EM, Mann DL. Acute decompensated heart failure: contemporary medical management. Tex Heart Inst J. 2009;36(6):510–20.20069075
8 Chang PP, Chambless LE, Shahar E, . Incidence and survival of hospitalized acute decompensated heart failure in four US communities (from the Atherosclerosis Risk in Communities Study). Am J Cardiol. Feb 1 2014;113(3):504–10. doi:10.1016/j.amjcard.2013.10.032 24342763
9 Njoroge JN, Teerlink JR. Pathophysiology and Therapeutic Approaches to Acute Decompensated Heart Failure. Circ Res. May 14 2021;128(10):1468–1486. doi:10.1161/circresaha.121.318186 33983837
10 Gupta D, Georgiopoulou VV, Kalogeropoulos AP, . Dietary sodium intake in heart failure. Circulation. Jul 24 2012;126(4):479–85. doi:10.1161/circulationaha.111.062430 22825409
11 McDonagh TA, Metra M, Adamo M, . 2021 ESC Guidelines for the diagnosis and treatment of acute and chronic heart failure. Eur Heart J. Sep 21 2021;42(36):3599–3726. doi:10.1093/eurheartj/ehab368 34447992
12 2022 AHA/ACC/HFSA Guideline for the Management of Heart Failure. J Card Fail. May 2022;28(5):e1–e167. doi:10.1016/j.cardfail.2022.02.010
13 Patel Y, Joseph J. Sodium Intake and Heart Failure. Int J Mol Sci. Dec 13 2020;21(24)doi:10.3390/ijms21249474
14 Alvelos M, Ferreira A, Bettencourt P, . The effect of dietary sodium restriction on neurohumoral activity and renal dopaminergic response in patients with heart failure. Eur J Heart Fail. Aug 2004;6(5):593–9. doi:10.1016/j.ejheart.2003.11.020 15302007
15 Graudal NA, Hubeck-Graudal T, Jürgens G. Effects of low-sodium diet vs. high-sodium diet on blood pressure, renin, aldosterone, catecholamines, cholesterol, and triglyceride (Cochrane Review). Am J Hypertens. Jan 2012;25(1):1–15. doi:10.1038/ajh.2011.210 22068710
16 Griffin M, Soufer A, Goljo E, . Real World Use of Hypertonic Saline in Refractory Acute Decompensated Heart Failure: A U.S. Center’s Experience. JACC Heart Fail. Mar 2020;8(3):199–208. doi:10.1016/j.jchf.2019.10.012 32035891
17 Gandhi S, Mosleh W, Myers RB. Hypertonic saline with furosemide for the treatment of acute congestive heart failure: a systematic review and meta-analysis. Int J Cardiol. May 1 2014;173(2):139–45. doi:10.1016/j.ijcard.2014.03.020 24679680
18 Covic A, Copur S, Tapoi L, . Efficiency of Hypertonic Saline in the Management of Decompensated Heart Failure: A Systematic Review and Meta-Analysis of Clinical Studies. Am J Cardiovasc Drugs. May 2021;21(3):331–347. doi:10.1007/s40256-020-00453-7 33210263
19 Liu C, Peng Z, Gao X, . Simultaneous Use of Hypertonic Saline and IV Furosemide for Fluid Overload: A Systematic Review and Meta-Analysis. Crit Care Med. Nov 1 2021;49(11):e1163–e1175. doi:10.1097/ccm.0000000000005174 34166286
20 Colin-Ramirez E, Sepehrvand N, Rathwell S, . Sodium Restriction in Patients With Heart Failure: A Systematic Review and Meta-Analysis of Randomized Clinical Trials. Circ Heart Fail. Jan 2023;16(1):e009879. doi:10.1161/circheartfailure.122.009879 36373551
21 Mahtani KR, Heneghan C, Onakpoya I, . Reduced Salt Intake for Heart Failure: A Systematic Review. JAMA Intern Med. Dec 1 2018;178(12):1693–1700. doi:10.1001/jamainternmed.2018.4673 30398532
22 Wallace BC, Small K, Brodley CE, Lau J, Trikalinos TA. Deploying an interactive machine learning system in an evidence-based practice center: abstrackr. presented at: Proceedings of the 2nd ACM SIGHIT International Health Informatics Symposium; 2012; Miami, Florida, USA. 10.1145/2110363.2110464
23 Sterne JA, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. Bmj. Oct 12 2016;355:i4919. doi:10.1136/bmj.i4919 27733354
24 Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. Bmj. Aug 28 2019;366:l4898. doi:10.1136/bmj.l4898 31462531
25 Hozo SP, Djulbegovic B, Hozo I. Estimating the mean and variance from the median, range, and the size of a sample. BMC Med Res Methodol. Apr 20 2005;5:13. doi:10.1186/1471-2288-5-13 15840177
26 Wan X, Wang W, Liu J, Tong T. Estimating the sample mean and standard deviation from the sample size, median, range and/or interquartile range. BMC Med Res Methodol. Dec 19 2014;14:135. doi:10.1186/1471-2288-14-135 25524443
27 Guyatt GH, Oxman AD, Vist GE, . GRADE: an emerging consensus on rating quality of evidence and strength of recommendations. Bmj. Apr 26 2008;336(7650):924–6. doi:10.1136/bmj.39489.470347.AD 18436948
28 Velloso LG, Alonso RR, Ciscato CM, Barretto AC, Bellotti G, Pileggi F. [Diet with usual quantity of salt in hospital treatment of congestive heart insufficiency]. Arq Bras Cardiol. Dec 1991;57(6):465–8. Dieta com quantidades habituais de sal no tratamento hospitalar da insuficiência cardíaca congestiva.1824218
29 Aliti GB, Rabelo ER, Clausell N, Rohde LE, Biolo A, Beck-da-Silva L. Aggressive fluid and sodium restriction in acute decompensated heart failure: a randomized clinical trial. JAMA Intern Med. Jun 24 2013;173(12):1058–64. doi:10.1001/jamainternmed.2013.552 23689381
30 Inuzuka Y, Kisimori, Takefumi, Inoue, Takesi Seki, Juny, Takeda, Sinsaku, Okada, Masaharu, Kosuga, Kunihiko, Ikeguchi, Shigeru. P21-3 - Sodium Restriction Is Associated With Low Caloric Intake in Patients Hospitalized With Acute Decompensated Heart Failure. Journal of Cardiac Failure. 2016;
31 Machado d’Almeida KS, Rabelo-Silva ER, Souza GC, . Aggressive fluid and sodium restriction in decompensated heart failure with preserved ejection fraction: Results from a randomized clinical trial. Nutrition. Oct 2018;54:111–117. doi:10.1016/j.nut.2018.02.007 29793053
32 Fabricio CG, Tanaka DM, Souza Gentil JR, . A normal sodium diet preserves serum sodium levels during treatment of acute decompensated heart failure: A prospective, blind and randomized trial. Clin Nutr ESPEN. Aug 2019;32:145–152. doi:10.1016/j.clnesp.2019.03.009 31221280
33 Paterna S, Di Pasquale P, Parrinello G, . Effects of high-dose furosemide and small-volume hypertonic saline solution infusion in comparison with a high dose of furosemide as a bolus, in refractory congestive heart failure. Eur J Heart Fail. Sep 2000;2(3):305–13. doi:10.1016/s1388-9842(00)00094-5 10938493
34 Licata G, Di Pasquale P, Parrinello G, . Effects of high-dose furosemide and small-volume hypertonic saline solution infusion in comparison with a high dose of furosemide as bolus in refractory congestive heart failure: long-term effects. Am Heart J. Mar 2003;145(3):459–66. doi:10.1067/mhj.2003.166 12660669
35 Paterna S, Di Pasquale P, Parrinello G, . Changes in brain natriuretic peptide levels and bioelectrical impedance measurements after treatment with high-dose furosemide and hypertonic saline solution versus high-dose furosemide alone in refractory congestive heart failure: a double-blind study. J Am Coll Cardiol. Jun 21 2005;45(12):1997–2003. doi:10.1016/j.jacc.2005.01.059 15963399
36 Tuttolomondo A, Pinto A, Di Raimondo D, . Changes in natriuretic peptide and cytokine plasma levels in patients with heart failure, after treatment with high dose of furosemide plus hypertonic saline solution (HSS) and after a saline loading. Nutr Metab Cardiovasc Dis. May 2011;21(5):372–9. doi:10.1016/j.numecd.2009.10.014 20346637
37 Paterna S, Fasullo S, Parrinello G, . Short-term effects of hypertonic saline solution in acute heart failure and long-term effects of a moderate sodium restriction in patients with compensated heart failure with New York Heart Association class III (Class C) (SMAC-HF Study). Am J Med Sci. Jul 2011;342(1):27–37. doi:10.1097/MAJ.0b013e31820f10ad 21701268
38 Parrinello G, Paterna S, Di Pasquale P, . Changes in estimating echocardiography pulmonary capillary wedge pressure after hypersaline plus furosemide versus furosemide alone in decompensated heart failure. J Card Fail. Apr 2011;17(4):331–9. doi:10.1016/j.cardfail.2010.11.003 21440872
39 Parrinello G, Di Pasquale P, Torres D, . Troponin I release after intravenous treatment with high furosemide doses plus hypertonic saline solution in decompensated heart failure trial (Tra-HSS-Fur). Am Heart J. Sep 2012;164(3):351–7. doi:10.1016/j.ahj.2012.05.025 22980301
40 Issa VS, Andrade L, Ayub-Ferreira SM, . Hypertonic saline solution for prevention of renal dysfunction in patients with decompensated heart failure. Int J Cardiol. Jul 15 2013;167(1):34–40. doi:10.1016/j.ijcard.2011.11.087 22243938
41 Okuhara Y, Hirotani S, Naito Y, . Intravenous salt supplementation with low-dose furosemide for treatment of acute decompensated heart failure. J Card Fail. May 2014;20(5):295–301. doi:10.1016/j.cardfail.2014.01.012 24462960
42 Yayla Ç, Akyel A, Canpolat U, . Comparison of three diuretic treatment strategies for patients with acute decompensated heart failure. Herz. Dec 2015;40(8):1115–20. doi:10.1007/s00059-015-4327-y 26135463
43 Wan Y, Li L, Niu H, . Impact of Compound Hypertonic Saline Solution on Decompensated Heart Failure. Int Heart J. Aug 3 2017;58(4):601–607. doi:10.1536/ihj.16-313 28701670
44 GR Gerald Roul JVH. Hypertonic saline solution in the management of severe decompensated heart failure in the elderly. European journal of heart failure. 2017;
45 Tuttolomondo A, Maida C, Casuccio A, . Effects of intravenous furosemide plus small-volume hypertonic saline solutions on markers of heart failure. ESC Heart Fail. Oct 2021;8(5):4174–4186. doi:10.1002/ehf2.13511 34288546
46 Mahjoob MP, Barzi F, Nassiri A, . Adjunct Hypertonic Saline in Patients with Diffuse Edema Due to Heart Failure: A Randomized Double-Blinded Clinical Trial. Iran J Pharm Res. Summer 2021;20(3):216–222. doi:10.22037/ijpr.2020.113853.14526
47 Montgomery RA, Mauch J, Sankar P, . Oral Sodium to Preserve Renal Efficiency in Acute Heart Failure: A Randomized, Placebo-Controlled, Double-Blind Study. J Card Fail. Jul 2023;29(7):986–996. doi:10.1016/j.cardfail.2023.03.018 37044281