# DISCUSSION

We identified 5 studies (4 RCTs and 1 NRCS) that compared a low sodium diet to higher sodium diet, and 15 studies (13 RCTs and 2 NRCSs) that compared HSS with furosemide or, in 1 instance, oral NaCl with furosemide, to furosemide alone. The most frequently evaluated outcomes for dietary sodium interventions were weight loss, diuretic dose during hospitalization, and all-cause mortality. For sodium supplementation studies, weight was the most frequently reported outcome followed by urine output, serum sodium, serum creatinine, and length of hospital stay. Only 1 study was conducted in the US and was not in the VA system. Key findings include the following:

## Dietary Sodium Interventions

### Intermediate Outcomes

- There is no evidence of a difference in serum creatinine (moderate confidence), BNP (low confidence) or BUN, urine output, serum Na, aldosterone, PRA, prescribed diuretics, or dose of diuretics between a low sodium and higher sodium diet (certainty of evidence not assessed).
- It is unknown if a low sodium diet affects NT-pro BNP (insufficient evidence).
- Fewer calories may be consumed by patients on a low sodium diet (low confidence).
- The studies did not evaluate eGFR or serum cystatin C.

### Clinical Outcomes

- There is no evidence of a difference in clinical congestion score between a low sodium diet compared to higher sodium diet (moderate confidence).
- Perceived thirst, but not other HF symptoms (shortness of breath or general well-being), may be greater for patients who receive a low sodium diet compared to higher sodium diet (certainty of evidence not assessed).
- It is unknown if a low sodium diet affects weight loss or mortality (insufficient evidence).
- Patients were adherent to the prescribed sodium diet (certainty of evidence not assessed).

### Health Service Utilization Outcomes

- There were no significant differences in 30-day readmission or length of stay between a low sodium diet compared to higher sodium diet (low confidence).

## Sodium Supplementation With Furosemide

### Intermediate Outcomes

- Sodium supplementation with furosemide may decrease serum creatinine (moderate confidence) and BNP (low confidence), but not NT-proBNP (low confidence).
- Sodium supplementation with furosemide may increase urine output, serum sodium, and eGFR, and may decrease BUN. There is no evidence of differences in cystatin C, serum aldosterone, or PRA (certainty of evidence not assessed).
- The studies did not evaluate caloric intake.

### Clinical Outcomes

- Sodium supplementation with furosemide may decrease weight (moderate confidence), reduce thirst symptoms (certainty of evidence not assessed), and improve NYHA functional class from admission to discharge (certainty of evidence not assessed).
- There may be no difference in shortness of breath or a composite measure of HF symptoms (certainty of evidence not assessed).
- It is unknown if sodium supplementation with furosemide affects mortality (insufficient evidence).
- The studies did not evaluate a clinical congestion score.

### Health Service Utilization Outcomes

- Sodium supplementation with furosemide may reduce length of hospital stay (moderate confidence).
- It is unknown whether sodium supplementation with furosemide reduces 30-day readmission or intensive care unit admission during hospitalization (insufficient evidence).

## SUMMARY

ADHF is 1 of the leading causes of hospitalization and rehospitalization in the US.^4^ For decades, patients hospitalized with ADHF have been prescribed a restricted sodium diet with diuretic therapy. One surprising finding from this review was that only 5 relatively small studies, with only 381 analyzed patients, evaluated the effect of restricting dietary sodium in an inpatient setting. The goal of restricting sodium in ADHF patients is to reduce fluid retention and congestion. Yet there were no significant differences in weight change, urine output, and clinical congestion score from baseline to last in-hospital measurement between patients who received restricted or higher sodium diets. Furthermore, for most prioritized intermediate, clinical, and health service utilization outcomes, there was no significant difference between patients who received a restricted or higher sodium diet. Importantly, restricting dietary sodium may be associated with harms. Fewer calories were consumed by patients who received a restricted diet (presumably because they did not like the taste of their food), and 2 studies reported increased thirst for patients who received a restricted sodium diet combined with fluid restriction.^29,31^ It is possible that this may partially explain why this strategy did not reduce hospital length of stay or other HF symptom metrics. Based on these data, the results suggest that a restricted sodium diet may not improve inpatient outcomes and may potentially result in poor experience with care. Unfortunately, these additional outcomes were not reported in all the included studies. Also, these findings are based on only small studies, mostly conducted in Brazil.

Unlike the restriction of dietary sodium, there is a larger evidence base evaluating the effect of combining furosemide with bolus sodium in the form of HSS or oral NaCl (15 studies and total analyzed N = 3,483). HSS is hypothesized to ameliorate diuretic resistance by shifting water from interstitial compartment, thus restoring effective intravascular volume and improving renal blood flow. In addition, HSS is expected to reduce hyperactivation of the renin-aldosterone-angiotensin pathway and help reduce the sodium-avid state of the kidneys.^18^ Consistent with this hypothesis, we found that HSS (or in 1 instance oral NaCl tablets) and furosemide compared to furosemide alone yielded a significant net improvement in kidney function (net reductions in serum creatinine and BUN and a net increase in eGFR), increased urine output, and reduced weight. Indirect evidence (across studies) suggests that improvements in kidney function and serum sodium become evident after about 4 to 6 days of treatment.

Despite evidence to suggest the efficacy of sodium supplementation as an adjuvant therapy for loop diuretics, providers may still have concerns that administering sodium to people with ADHF can lead to sodium overcorrection or pulmonary edema. Notably, though, the average sodium increase in these interventions was ~6 mEq/L, which is lower than the maximum of 8 mEq/L per 24 hour change in sodium that is deemed safe in acute correction. There were no reports of worsening pulmonary edema or hypoxia with administration of sodium supplementation in these studies, while shortness of breath symptoms and NYHA class improved across studies.

## STRENGTHS AND LIMITATIONS OF THE EVIDENCE BASE

The evidence base on restricting dietary sodium has several important limitations. First, only 5 small studies evaluated restricted dietary sodium interventions in an inpatient setting. Second, 2 of the 4 RCTs had major methodological limitations due to missing outcome data, not following an intent-to-treat analysis, or using hospital record number to randomize patients. Third, 2 studies did not clearly define how long patients were administered a restricted diet, which we assumed was for the duration of their hospitalization.^28,30^ Lastly, the few, small studies combined with heterogeneity in maximum sodium consumption (range 0.8 g/day to 2.4 g/day) makes it challenging to know whether outcomes may differ by the amount of prescribed sodium.

Most studies evaluating HSS (or oral sodium) and furosemide had low risk of bias (ie, no major methodological weaknesses). We synthesized data based on the last in-hospital measurement; however, there was meaningful variation across studies in the timing of outcome assessment. Some studies evaluated outcomes immediately after the intervention and others at discharge. At a minimum, future studies should report outcomes at admission, after the intervention, and at discharge. In addition, studies inconsistently reported whether they restricted dietary sodium. Lastly, variation across studies in the duration of intervention (24 hours to 12 days) and dose of furosemide (conventional or high dose) makes it challenging to identify the best sodium supplementation with diuretic strategy.

Although of importance to stakeholders, studies were inconsistent in whether they reported HF-related symptoms (and which symptoms), and none of the diet studies reported change in NYHA class. Of crucial importance to determine who might benefit most (or least) from the interventions, the studies did not report differences in effectiveness by patient characteristics (age, sex, or race/ethnicity), comorbid conditions, or community dietary sodium intake. Only 2 dietary studies reported baseline data on race/ethnicity^29,31^ (only reporting the proportion of White participants), and only the US-based sodium supplementation study (or oral sodium) reported data by race/ethnicity (only reporting the proportion of White and Black participants). The studies did not report outcomes by existing versus new-onset HF or preserved versus reduced ejection fraction. However, 3 studies found that HSS and furosemide resulted in meaningful improvements in NYHA functional class from admission to discharge. Finally, no study compared a dietary sodium restriction to HSS and furosemide.

## IMPLICATIONS FOR VA POLICY AND PRACTICE

HF is highly prevalent among the Veteran population and is an important cause of hospitalization, morbidity, and mortality in the VA.^3^ Providing the best care to Veterans hospitalized with decompensated heart failure is paramount to the VA’s mission. No study was conducted in the VA and only 1 study (oral sodium tables) was conducted in the US. All 4 dietary sodium RCTs were conducted in Brazil and most HSS studies were conducted in Europe. Two separate author groups each conducted 2 of the European studies,^36,38,39,45^ and a third author group conducted 3 of the European studies.^33,35,37^ Men were the majority in most studies (range 32%–81%; the VA population is 89% male) and no study reported effectiveness by sex. Despite these differences, the main overall findings likely translate to the VA population, as the underlying biology and pathophysiologic mechanisms are not likely different by country. It is also reasonable to hypothesize that the finding of a reduction in length of stay for sodium supplementation with diuretics may be reproduced in the VA, but it is likely that the magnitude of change in length of stay (a measure particularly sensitive to a health system’s characteristics) may be substantially different than found in mostly European studies. Veterans Integrated Services Networks with strong transitional care programs (eg, Hospital in Home and Cardiac Rehabilitation programs) are likely in the best position to leverage the observed reductions in length of stay for sodium supplementation. However, the single US study found no significant difference in hospital length of stay between oral sodium tablets with furosemide compared to furosemide alone.

As a high reliability organization, the VA should consider adapting and implementing the best evidence for Veterans with ADHF within its care delivery system. Our findings call for the careful review of the routine inpatient practice of severely restricting sodium intake for patients admitted with ADHF. While physiologic measures were largely unchanged with low sodium diets, the reduction in calories is a serious concern for the Veteran population who may be fluid overloaded (“overweight”) and malnourished. The use of HSS (or oral sodium supplementation) with loop diuretics to augment diuresis deserves consideration for inclusion in hospital protocols as a strategy for ADHF.

As VA Medical Centers and providers evaluate the merits of sodium supplementation, they will also need to consider broader implementation needs and barriers. Providers and systems may be reluctant to change practice. The pathophysiology of sodium in HF is generally discussed in medical curricula as something to be avoided. The counterintuitive nature of administering a high-sodium solution to patients in ADHF, concerns of over-correction or precipitation of pulmonary edema, and limited experience of providers will require education, partnership with cardiovascular and renal specialists, buy-in from leadership, and clear protocols. In addition, HSS will require greater utilization of clinical resources for patient monitoring with an appropriate safety protocol in place. Furthermore, clinical experience with the use of HSS for ADHF likely varies between facilities, and training of medical staff will be critical to promote the safe use of HSS in selected patients with ADHF.

Limited evidence of RCT data from North America suggests a unique opportunity for VA hospitals to evaluate effectiveness and implementation of this strategy in the US and to fill the gaps in evidence for VA providers and policy makers. Conducting studies in the US would be particularly informative to understand the effect of intervention on health system outcomes pertinent to the US (such as length of hospital stay), which are likely to differ substantially across different health systems and countries. In addition, interviews with Veterans, providers, and Medical Center leadership can identify barriers and facilitators to implementation of clinical interventions employing sodium supplementation with loop diuretic protocols. After systems adopt these protocols, effectiveness and safety measures can be evaluated by using the VA data.

## RESEARCH GAPS/FUTURE RESEARCH

Despite millions of people affected by HF worldwide, there is limited evidence on the effect of prescribed sodium interventions in an inpatient setting. Fewer than 400 people contributed data to the dietary sodium intake studies and fewer than 3,500 people contributed data to the sodium supplementation studies. There is a need for a well-designed, adequately powered RCT of pragmatic design to assess the effectiveness of HSS infusion (and possibly separately oral supplementation) for patients admitted with ADHF. There was variation in HSS administration (concentration ranged from 1.15% to 7.5%), tailoring dosage (tailoring or fixed), and duration of treatment. There are several broader research needs. Future studies should focus on examining differences in effectiveness by patient characteristics (age, sex, or race/ethnicity), HF phenotypes, chronicity of HF, and comorbid conditions. There is also a need to understand patient quality of life, experience, and satisfaction with care. As protocols are translated into practice, there will be a need to evaluate implementation efforts which can be incorporated into the pragmatic research design.

The evidence regarding restricted in-hospital dietary sodium is small. Future, well-conducted, larger studies would be needed to effectively evaluate the dietary sodium restriction. However, given the reluctance of patients to have their dietary sodium restricted (as evidenced by decreased caloric intake), the lack of evidence of a beneficial effect of restricted dietary sodium (to date), and the apparent effectiveness of sodium supplementation with furosemide treatment, it is unclear whether future studies of restricted in-hospital dietary sodium are warranted.

## STRENGTHS AND LIMITATIONS OF THE SYSTEMATIC REVIEW PROCESS

Our review represents the most up-to-date report evaluating the evidence the practice of dietary sodium restriction and the use of HSS (or oral sodium supplementation) with furosemide among hospitalized patients with ADHF. This evidence review has several limitations. There was variation in the dietary sodium intake and sodium supplementation administration strategies, and we were unable to compare effects by dosing or duration. Outcomes of 30-day mortality and 30-day readmission may be affected by care after discharge, but we were unable to evaluate corresponding outpatient care protocols. We were likewise unable to investigate potential sources of heterogeneity of treatment effects (explanations for differences across studies) because of small numbers of studies and lack of reporting on many characteristics of interest or of subgroup analyses. A strength of our review was the focus on hospitalized patients. Studies examining dietary interventions in outpatient settings are challenging to conduct because sodium consumption is documented via patient reported diaries. Documenting (and managing) sodium consumption in an inpatient setting is likely easier, and thus reported intakes are likely more accurate. While we did not define a priori sensitivity analyses, the post hoc sensitivity analyses based on removing substantive outliers provide important supportive evidence.

## CONCLUSIONS

Findings from this review call into the question the conventional practice of restricting dietary sodium for managing ADHF in an inpatient setting. Only a few studies examined the effect of restricting dietary sodium, and these studies had important methodological limitations. There was no evidence of differences in most intermediate, clinical, or health service use outcomes for patients prescribed a restricted sodium diet compared to a higher sodium diet, but patients consumed fewer calories on a low sodium diet compared to a higher sodium diet. Studies provide insufficient evidence for the effect of numerous outcomes, including mortality. Patients who received HSS (or in 1 instance, oral sodium supplementation) and furosemide, compared to furosemide alone, had clinical improvements in intermediate, clinical, and health service use outcomes, particularly related to effective diuresis and length of hospital stay, without evidence of deleterious kidney or HF effects. The effects of sodium supplementation and furosemide therapy may not become evident until at least 4 to 6 days of treatment. However, especially since little research has been conducted in the US, there is a need for well-designed and large RCTs to further assess the effectiveness of sodium supplementation and furosemide treatment for inpatients with ADHF. There is a particular need for future research to examine heterogeneity of treatment effects based on patient characteristics and to identify the optimal duration, dose, and protocol of sodium supplementation treatment. While more rigorous trials would be needed to determine whether restricted dietary sodium is effective in the inpatient setting, the apparent benefit of sodium supplementation and furosemide treatment may preclude the need for additional dietary studies.