# RESULTS

## LITERATURE FLOW AND OVERVIEW

Of 9,871 unique records screened, 78 studies were accepted for full-text review. Upon reviewing these, 20 studies^28–47^ were eligible (Figure1). The most common reasons for exclusion included records without additional outcomes of interest (N = 24), systematic reviews (N = 19), and not an intervention of interest (N = 9). We found no additional studies from the existing systematic reviews.

Figure 1 Literature Flowchart

Notes. *14 studies evaluated HSS and 1 study evaluated supplemental oral NaCl.

Abbreviations. D=design; HF=Heart failure; HSS=hypertonic saline solution; I=intervention; NaCl=sodium chloride; O=outcome; P=population; SR=systematic review.

Twenty studies were included and reported the effectiveness of dietary sodium intake^28,29,31,32^ ^30^ (N = 5), intravenous HSS with furosemide^33–46^ (N = 14), or oral NaCl supplementation^47^ (N = 1) for patients hospitalized with ADHF. Table 2 shows the summary characteristics of the eligible studies, Appendix D presents design details, and Appendix E presents baseline characteristics. There were 17 RCTs28,29,31-33,35,37-43,45-47 and 3 NRCSs.30,36,44 The 5 studies that evaluated the effectiveness of restricted dietary sodium intake intervention included 381 patients total (4 RCTs N = 191^28,29,31,32^ and 1 NRCS N = 190^30^). Fourteen studies that evaluated the effectiveness of HSS with furosemide included 3,483 patients (13 RCTs N = 3,166^33–35,37–43,45–47^ and 2 NRCSs N = 317^36,44^). One RCT evaluating HSS with furosemide conducted in Italy was large (N = 1,927).^37^ One RCT (N = 65) compared oral NaCl with furosemide to furosemide alone and was included in the synthesis of the HSS studies.^47^ Two studies^30,44^ were published as conference abstracts. The majority of the studies were conducted in Europe (N = 9),^33–39,44,45^ followed by South America (N = 5),^28,29,31,32,40^ Asia (N = 3),^30,41,43^ the Middle East (N = 2),^42,46^ and the US (N = 1).^47^ Appendix F.1 describes the dietary sodium restriction interventions and Appendix F.2 describes the sodium supplementation with furosemide interventions. Appendix G presents categorical outcomes and Appendix H presents continuous outcomes.

Table 2 Summary Characteristics of Eligible Studies

Characteristics | Restricted Dietary Sodium Intake (N = 5) | Supplemental Sodium Intake^a^ (N = 15)
Design
RCT (N = 16) | 4 | 13
NRCS (N = 3) | 1 | 2^b^
Risk of Bias
Low (N = 9) | 2 | 8
Moderate (N = 4) | 1 | 3
High (N = 6) | 2 | 4
Countries
Brazil (N = 5) | 4 | 1
China (N = 1) | -- | 1
France (N = 1) | -- | 1
Italy (N = 8) | -- | 8
Iran (N = 1) | -- | 1
Japan (N = 2) | 1 | 1
Turkey (N = 1) | -- | 1
United States (N = 1) | -- | 1
Interventions
Restricted prescribed sodium diet (N = 5) | 5 | --
Hypertonic saline solution with IV furosemide (N = 14) | -- | 14
Oral NaCl tablets with IV furosemide (N = 1) | -- | 1
Intermediate Measures
Aldosterone (N = 4) | 1 | 3
BNP (N = 9) | 2 | 7
Caloric intake^c^ (N = 2) | 2 | --
Diuretics dose during hospitalization (N = 4) | 3 | 1
Fluid intake (N = 1) | 1 | --
Kidney function (creatinine^d^) (N = 14) | 3 | 11
Kidney function (blood urea nitrogen) (N = 15) | 3 | 12
Kidney function (eGFR) (N = 6) | -- | 6
Kidney function (serum cystatin C) (N = 2) | -- | 2
NT-proBNP (N = 4) | 1 | 3
Plasma renin activity (N = 2) | 1 | 1
Renin (N = 1) | -- | 1
Serum sodium (N = 16) | 3 | 13
Clinical Outcomes
Clinical congestion score (N = 2) | 2 | --
Composite HF-related symptoms^e^ (N = 1) | -- | 1
HF-related symptom (change in NYHA functional class) (N =3) | -- | 3
HF-related symptom (general well-being) (N = 1) | 1 | --
HF-related symptom (shortness of breath^f^) (N = 3) | 1 | 2
HF-related symptom (thirst^g^) (N = 3) | 2 | 1
All-cause mortality^h^ (N = 8) | 4 | 4
Percent of patients received diuretics in hospital (N = 2) | 2 | NA
Time on IV diuretics^i^ (N = 2) | 2 | NA
Time to clinical stability (N = 1) | 1 | --
Urine output (N = 13) | 1 | 12
Weight change (N = 18) | 4 | 14
Adherence Outcomes
Adherence to prescribed interventions (N = 2) | 2 | NA
Health Service Utilization Outcomes
Length of hospital stay (N = 14) | 3 | 11
Readmission (HF-related or all-cause) (N = 5) | 3 | 2
Transfer to ICU (N = 1) | -- | 1

Notes.

a 14 studies evaluated HSS and 1 study evaluated supplemental oral NaCl;

b One retrospective and 1 prospective NRCS;

c One NRCS reported the incidence of low caloric intakes (caloric intakes less than 20 kcal/kg per day);

d One NRCS reported worsening of renal function, represented by an increase in serum creatinine ≥0.3 mg/dL;

e Composite includes dyspnea, lower edema, weakness, palpitation and fatigue;

f One RCT reported perceived dyspnea using visual analogue scale in dietary sodium interventions;

g Perceived thirst using visual analogue scale or Thirst Distress Scale for Heart Failure (TDS-HF);

h Reported in-hospital and at 30-day follow up;

i The time to transition from IV to oral diuretic therapy.

Abbreviations. BNP=brain (or B-type) natriuretic peptide; eGFR=Estimated Glomerular Filtration Rate; HF=heart failure; HSS=hypertonic saline solution; ICU=intensive care unit; IV=intravenous; N=number; NA=not applicable (not an outcome of interest for supplemental NaCl interventions), NRCS=non-randomized comparative studies; NT-proBNP=N-terminal pro-brain (or B-type) natriuretic peptide; RCT=randomized clinical trials.

## RESTRICTED DIETARY SODIUM INTAKE

Five studies (4 RCTs and 1 NRCS) conducted between 2008 and 2016 involving 381 analyzed participants (243 intervention, 138 control) compared a low sodium diet to higher sodium diet (unrestricted in 4 studies).^28–32^ All 5 studies had similar inclusion and exclusion criteria (Appendix D).

The 4 RCTs were all conducted in Brazil in a single-center hospital setting.^28,29,31,32^ Patients in the RCTs were, on average, from 54 to 72.3 years old (Appendix E).^28,29,31,32^ Most participants (in 3 of the 4 RCTs with data) were male (56.3–69%).^28,29,32^ Only 2 RCTs reported data on race/ethnicity, with White participants making up 81% and 84% of the study samples (no data on other patients).^29,31^ Three of the RCTs reported patient HF classification at baseline on the New York Heart Association (NYHA) scale, with 9.5% of patients being classified as NYHA Class II in 1 study,^31^ 47% and 50.9% as NYHA Class III in 2 studies,^29,31^ and 39.6% and 45% as NYHA Class IV in 2 studies.^29,31^ One RCT reported baseline NYHA classification for patients randomized to the low sodium group only, with 28.6% and 71.4% of participants classified as NYHA Classes III and IV, respectively.^28^ Three RCTs reported mean (SD) of left ventricular ejection fraction (LVEF) at baseline from 26.0% (8.7) to 60.9% (7.5),^29,31,32^ and 1 study reported mean (SD) of left ventricle end-diastolic diameter (LVEDD) 63.2% (12.2).^32^

The single NRCS (N = 190) was conducted in Japan, included participants with a median age of 79 years, did not report information on race/ethnicity, and 100% of participants were classified as NYHA II-IV at baseline.^30^

Although it was not possible to blind participants or personnel, all the RCTs studies had independent outcome assessors. One of the RCTs was, in fact, “quasi-randomized” in that it allocated patients based on medical record number. It was downgraded for high risk of bias randomization and allocation concealment (Appendix C).^28^ Another RCT was also judged to be at high risk of bias because of incomplete outcome data due to missing follow-up data.^32^ The NRCS was presented in a conference abstract,^30^ reported minimal methodological details, and was at moderate risk of bias.

Appendix F.1 describes the dietary sodium interventions. Prescribed sodium intake in the intervention groups ranged from a maximum of 0.8 g/day (in 3 studies) to 2.4 g/day (the NRCS). Sodium intake in higher sodium groups (ie, control) ranged from 2.8 g/day to 3-5 g/day. Two studies restricted fluid intake in both intervention and higher sodium diet groups (ranging from 800 mL/day and 1000 mL/day),^28,32^ and 2 studies did not indicate any fluid restriction in both intervention and higher sodium diet groups.^29,31^ In 2 studies, fluid intake did not differ between the intervention and control groups.^28,32^ Two studies described implementing a restricted diet until discharge or hospital day 7 (whichever came first),^29,31^ and in 1 study, patients received a restricted diet until hospital day 7 unless there was a clinical indication to end it early.^32^ Two of the studies did not report the duration of the intervention.^28,32^

## EFFECT OF RESTRICTED DIETARY SODIUM

In summary (Table 3), there was no statistically significant difference in serum creatinine (moderate confidence) or BNP (low confidence) between a low sodium and a higher sodium diet. Fewer calories were consumed by patients on a low sodium diet compared with a higher sodium diet (low confidence). There were no significant differences in clinical congestion score (moderate confidence), 30-day readmission, and length of stay between a low sodium diet and higher sodium diet (low confidence). Studies provided insufficient evidence (no conclusion) for effects on NT-pro BNP, weight loss, and mortality, due to imprecise estimates and very serious methodological limitations.

Other findings (certainty of evidence not assessed) included no statistically significant difference in blood urea nitrogen, urine output, prescribed diuretics or dose of diuretics, serum sodium, aldosterone, or PRA for patients on a low sodium diet compared to a higher sodium diet. There was an increase in thirst but no difference in shortness of breath and general well-being for patients on a low sodium diet compared to a higher sodium diet. There was no difference in days to compensation. Patients were adherent to the prescribed sodium diet. No study reported data on estimated glomerular filtration rate (eGFR) or serum cystatin C.

Table 3 Summary of Findings for Restricted Dietary Sodium Interventions

Outcome | Studies (Patients); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Overall Confidence | Summary of Findings
Creatinine | 3 (159); RCT^29,31,32^ | Serious^a^ | Direct | Precise | Consistent | None | Moderate | Pooled NMD = 0.08 mg/dL, 95% CI (−0.08, 0.23)
BNP | 2 (128); RCT^29,31^ | No limitations | Direct | Not precise^c^ | Consistent | Sparse data | Low | Net median difference = 525 and −13 pg/mL
NT-pro BNP | 1 (31); RCT^32^ | Very serious^a^ | Direct | Not precise^d^ | NA | Single Study | Insufficient | No conclusion
Caloric intake | 2 (243); RCT^30,31^ NCRS^30^ | Serious^b^ | Direct | Precise | Consistent | Sparse data | Low | Consume <20 kcal/kg/day; RR = 3.4, 95% CI [1.70, 6.86]); MD = −4.4 kcal/kg/day, 95% CI (−7.26, −1.53).; MD in percent estimate of daily requirement: −16, 95% CI (−6.6, −25.4)
Clinical congestion score | 2 (128); RCT^29,31^ | No limitations | Direct | Precise | Consistent | Sparse data | Moderate | NMD = −0.5, 95% CI (−1.76, 0.76) and 0.4, 95% CI (−1.6, 2.4)
Weight change | 4 (191); RCT^28,29,31,32^ | Serious^a,b^ | Indirect^e^ | Not precise^f^ | Serious^g^ | None | Insufficient | No conclusion
Mortality (All cause) | 4 (191); RCT^28,29,31,32^ | Serious^a,b^ | Indirect^e^ | Not precise^h^ | Consistent | Sparse data^i^ | Insufficient | No conclusion
Readmission | 3 (159); RCT^28,29,31,32^ | Serious^a^ | Direct | Precise | Serious^j^ | None | Low | Pooled RR = 1.07, 95% CI (0.68, 1.69)
Length of hospital stay | 3 (159); RCT^29,31,32^ | Serious^a^ | Direct | Not precise^k^ | Consistent | None | Low | Pooled NMD = 3.06 days, 95% CI (−0.61, 6.72)

Notes.

a One study was high risk of bias due to incomplete outcome data and no intent to treat analysis;

b One study was moderate risk of bias due to uncertainty about the completeness of the outcome data and selective reporting;

c One study had a wide IQR at baseline and follow-up for both groups;

d Wide IQR at baseline and follow-up measures for both groups;

e Data reported at different time points;

f At least 1 study had a large SD;

g Two of 4 studies reported a decrease in weight for higher diet and 2 reported a decrease for low sodium diet;

h At least 1 study had a wide confidence interval;

I Only 5 events per group (total events for all participants = 10) across all of the included studies;

j Two studies reported a lower risk for low sodium diet, and 1 study reported a higher risk for low sodium diet;

k At least 1 study had a wide confidence interval.

Abbreviations. BNP=brain (or B-type) natriuretic peptide; CI=confidence interval; MD=mean difference; NA=not applicable; NMD=net mean difference; NRCS=non-randomized controlled study; NT-proBNP=N-terminal pro-brain (or B-type) natriuretic peptide; RCT=randomized controlled trial; RR=relative risk.

### Intermediate Outcomes

#### Serum Creatinine

Three RCTs found no significant difference in serum creatinine from baseline to 7 days between the diet intervention arms (pooled NMD = 0.08 mg/dL, 95% CI [−0.07, 0.23]; Figure 2).^29,31,32^ The duration of intervention was 7 days in all studies. One RCT (Fabricio et al) yielded a highly imprecise estimate regarding difference in the likelihood that serum creatinine would increase by ≥0.3 mg/dL over 7 days between patients randomized to a low sodium diet of 1.2 g/day Na compared to a higher sodium diet of 2.8 g/day Na (RR = 0.94, 95% CI [0.43, 2.04]).^32^ (Note that we use the abbreviation for sodium, Na, when reporting a dose or serum level.)

Figure 2 Serum Creatinine: Low Sodium versus Higher Sodium Diet

Notes. Net reduction in serum creatinine is considered to be a favorable outcome.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; N=sample size; Na=sodium; NMD=net mean difference; RoB=risk of bias.

#### Blood Urea Nitrogen (BUN)

Three studies found no significant difference in BUN from baseline to 7 days (the duration of the intervention and follow-up) for patients who received a low sodium diet compared to higher sodium diet (pooled NMD = 6.5 mg/dL, 95% CI [−2.4, 15.4]; Figure 3),^29,31,32^ although all 3 studies found a small net increase in BUN among patients on low sodium diets compared with higher sodium diets.

Figure 3 Blood Urea Nitrogen (BUN): Low Sodium versus Higher Sodium Diet

Notes. Net reduction in BUN is considered to be a favorable outcome.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; N=sample size; Na=sodium; NMD=net mean difference; RoB=risk of bias.

#### Estimated Glomerular Filtration Rate (eGFR) and Serum Cystatin C

No study reported data on eGFR or serum cystatin C.

#### Natriuretic Proteins (BNP and NT-proBNP)

Two RCTs reported change in BNP from baseline to 7 days or discharge and 1 study reported change in NT-proBNP. One RCT found no significant difference in median BNP from baseline to 7 days between patients on a low sodium diet (0.8 g/day Na) compared to higher sodium diet (~3-5 g/day Na; net median difference = 525 pg/mL, p = 0.51).^29^ A second RCT found no significant difference in median BNP between intervention (0.8 g/day Na) and control arms (~4 g/day Na) from baseline to 7 days (net median difference = −13 pg/mL, p = 0.85).^31^ Finally, 1 RCT found no significant difference in change in serum NT-proBNP between a low (1.2 g/day Na) and higher sodium diet (2.8 g/day Na) groups from baseline to 7 days (net median difference = 139 pg/mL, NS).^32^

#### Weight Change

Four RCTs reported no significant difference in change in weight from baseline to 3 or 7 days.^28,29,31,32^ We did not meta-analyze these studies because of the inconsistent time points when weight was reported. One RCT found no significant difference in change in weight from baseline to the primary end point of 3 days (middle of intervention) between the low sodium diet (0.8 g/day Na) and higher sodium diet (~3-5 g/day Na; NMD = 0.3 kg, 95% CI [−1.9, 2.4]).^29^ The same study reported no significant difference in weight change from baseline to 7 days (means not reported, p = 0.12).^29^ A second RCT found no significant difference in mean change in weight from baseline to 3 days and baseline to 7 days (p > 0.99 and p = 0.49, respectively) between a low sodium diet (0.8 g/d Na) and higher sodium diet (~4 g/day Na).^31^ A third RCT found no significant difference in mean change in weight from baseline to 7 days between a low sodium diet (1.2 g/day Na) and higher sodium diet (2.8 g/day Na; NMD = −1.0 kg, 95% CI [−18.2, 16.2]).^32^ Finally, the fourth RCT found no significant difference in percent change in weight from baseline to time of compensation (the study did not clearly report mean days to compensation) between patients on a low sodium diet of 0.8 g/day compared to higher sodium diet of 4 g/day (MD = 2.2%, 95% CI [−3.5, 7.9]).^28^

#### Urine Output

One RCT found no significant difference in urine output between the low sodium diet (1.2 g/day Na) and higher sodium diet (2.8 g/day Na) groups from baseline to 7 days (MD = 1.4 L/24 hr, 95% CI [ −0.6, 3.4]).^32^

#### Serum Sodium

Three RCTs, overall, found no significant difference in serum sodium from baseline to day 7 (duration of intervention and follow-up) between the low and higher sodium arms (pooled NMD = −0.4 mEq/L, 95% CI [−2.2, 1.5]; Figure 4).^29,31,32^ One study found a statistically significant, but clinically small, net decrease (ie, worsening) in serum sodium in the patients given the low sodium diet.^32^ The authors hypothesize that the effect of natriuresis caused by the loop diuretics and the restricted sodium intake combined to lower serum sodium levels.

Figure 4 Serum Sodium: Low Sodium versus Higher Sodium Diet

Notes. Net increase in serum sodium is considered to be a favorable outcome.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; N=sample size; Na=sodium; NMD=net mean difference; RoB=risk of bias.

#### Prescribed Diuretics

Two RCTs reported no significant difference in the proportion of patients who received diuretics while hospitalized between the low sodium diet and higher sodium diet (RR = 0.97, 95% CI [0.89, 1.07] and 1.00, 95% CI [0.83, 1.20]).^29,32^

Three RCTs reported prescribed diuretic dose during the hospitalization.^28,31,32^ One RCT reported no significant difference in change in diuretic (furosemide) dose from baseline to 7 day between the low sodium diet of 0.8 g/day Na and higher sodium diet of ~4 g/day Na (NMD = 4.3 mg/day, 95% CI [−12.0, 20.6]).^31^ One RCT found no difference in cumulative loop diuretic dose during hospitalization between the low sodium (1.2 g/day Na) and higher sodium diet groups (2.8 g/day Na; MD = 103.5 mg/day, 95% CI [−14.2, 221.2]).^32^ One RCT found no difference in daily and cumulative diuretic (furosemide) dose during the compensation period between the low sodium diet 0.8 g/day Na and higher sodium diet of 4 g/day Na (MD = −0.2 mg/day, 95% CI [−0.6, 0.3] and −31.0 mg/day, 95% CI [−265.7, 203.7], respectively).^28^ Finally, 2 RCTs found no significant difference in the time to transition from an intravenous to an oral diuretic administration (median difference = 0 days and MD = 0.3 days, 95% CI [−0.86, 1.46]).^29,31^

#### Nutritional Intake

One NRCS found that the risk of consuming fewer calories (defined as <20 kcal/kg/day) was significantly greater for people who received a low sodium diet (2.4 g/day Na) compared to higher sodium diet (4 g/day Na; RR = 3.4, 95% CI [1.70, 6.86]).^30^ The NRCS and an RCT also reported calorie intake as a continuous measure. The NRCS found fewer calories (defined as the percent of estimated daily requirement) were consumed by patients prescribed a low sodium diet compared to those prescribed a higher sodium diet (MD = −16.0%, 95% CI [−6.6, −25.4]).^30^ Similarly, an RCT found fewer calories were consumed by patients on a restricted sodium diet (0.8 g/day Na) compared to those on a higher sodium diet (~4 g/day Na; MD = −4.4 kcal/day, 95% CI [−7.3, −1.5]).^31^ This RCT also found fewer liquids were consumed over 7 days in the low sodium diet group which also restricted fluids to 800 mL/day compared to those in the higher sodium diet group which did not restrict fluid intake (median difference = −312.7 mL/day, p <0.001).^31^

#### Other Intermediate Measures

One RCT found no significant difference in aldosterone from baseline to day 7 of admission or discharge between those on a low sodium diet (0.8 g/day Na) compared to higher sodium diet (~4 g/day Na; NMD = 11 pg/mL, p = 0.85).^31^ Similarly, 1 RCT reported no difference in PRA from baseline to day 7 or discharge in patients on a low sodium diet (0.8 g/day Na) compared to patients on a higher sodium diet (~4 g/day Na; NMD = −0.9 ng/mL/h, p = 0.42).^31^

### Clinical Outcomes

#### Clinical Congestion Score

Two RCTs reported clinical congestion scores between the low sodium and higher sodium diet groups from baseline to 3 or 7 days.^29,31^ One RCT found no significant difference in scores between the low sodium (0.8 g/day Na) and higher sodium (~3-5 g/day Na) groups from baseline to 3 and 7-days (NMD = −0.6, 95% CI [−2.1, 0.9] at 3 days and −0.5, 95% CI [−1.8, 0.8] at 7 days).^29^ A second RCT reported no significant difference in scores from baseline to day 7 of the intervention between the low sodium diet of 0.8 g/day Na and higher sodium diet of ~4 g/day Na (NMD = 0.4, 95% CI [−1.6, 2.4]).^31^

#### Heart Failure Related Symptoms

Two RCTs evaluated thirst via a 10-point visual analogue scale.^29,31^ In both studies, patients randomized to the low sodium diet compared to higher sodium diet reported greater feelings of thirst from baseline to 7-day follow-up.^29,31^ An RCT found a significant increase in thirst for patients in the low sodium diet (0.8 g/day Na) compared to higher sodium diet group (~3 to 5 g/day Na; NMD = 1.5, 95% CI [0.4, 2.7], p = 0.01).^29^ In this study, fluid intake was limited to a maximum of 800 mL/day in the intervention group, while liberal fluid intake of ≥2500 mL/day was allowed in the higher sodium group. Similarly, 1 RCT reported significantly greater perceived thirst during the study period for patients on a diet of 0.8 g/day Na and a restriction of 800 mL/day fluid compared to a diet of ~4 g/day Na and unlimited fluid intake (p = 0.03).^31^

One study found no significant difference in shortness of breath and general well-being, both measured by a 10-point visual analogue scale, for patients randomized to a low sodium diet (1.2 g/day Na) compared to higher sodium diet (2.8 g/day Na) from baseline to day 7 (NMD = 0.8, 95% CI [−0.3, 1.9] and 0.6, 95% CI [−0.9, 2.1], respectively).^32^

#### Mortality

Four studies reported all-cause mortality at different time points.^28,29,31,32^ Two RCTs reported no deaths in either group during the 7-day intervention period^29^ or during hospitalization.^30^ Two RCTs reported 30-day mortality outcomes. The event rates were low in both studies, yielding very imprecise estimates (RR = 0.93, 95% CI [0.15, 5.84]^32^ and RR = 0.77, 95% CI [0.12, 5.04]^31^). One RCT also reported a highly imprecise estimate of mortality not related to HF (RR = 1.29, 95% CI [0.09, 18.8], time frame unclear).^28^

#### Other Clinical Outcomes

One RCT found no significant difference in days to compensation between a low sodium (0.8g/day Na) and higher sodium diet (4 g/day Na; MD = 0.9, 95% CI [−0.3, 2.1]).^28^

### Health Service Utilization Outcomes

#### Readmission

Three RCTs reported no significant difference in 30-day readmission between patients on a low sodium diet compared to higher sodium diet (pooled RR = 1.07, 95% CI [0.68, 1.69]; Figure 5).^29,31,32^ One RCT reported 30-day readmission due to HF,^29^ while the other 2 RCTs^31,32^ reported all-cause 30-day readmission.

Figure 5 30-Day Readmission: Low Sodium versus Higher Sodium Diet

Notes. Lower rate of readmission is considered to be a favorable outcome.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; N=sample size; Na=sodium; RoB=risk of bias; RR=risk ratio.

#### Length of Hospital Stay

Three RCTs reported a nonsignificant longer length of stay for patients on a low sodium diet compared to the higher sodium diet (pooled MD = 3.1 days, 95% CI [−0.6, 6.7]; Figure 6).^29,31,32^ None of the studies, though, provided a hypothesis for why a low sodium diet would increase length of stay. There was a moderate degree of heterogeneity across studies, with differences ranging from 0.4 to 6.7 days.

Figure 6 Length of Hospital Stay: Low Sodium versus Higher Sodium Diet

Notes. Shorter hospital stay is considered to be a favorable outcome.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; N=sample size; Na=sodium; MD=mean difference; RoB=risk of bias.

#### Adherence

Two RCTs evaluated adherence to the hospital diet by measuring the amount of sodium consumed.^31,32^ The 2 RCTs found significantly less sodium was consumed over 7 days by patients who received a low sodium diet compared to higher sodium diet (median difference = −1.3 g/day Na, p < 0.001 and MD = −1.5 g/day, 95% CI [−1.7, −1.2]).^31,32^ A third RCT found no significant difference in the acceptance of the hospital diet defined as consuming 80% of the entire meal between the low (1.2 g/day Na) and higher sodium diet (2.8 g/day Na; mean 79.6% [14.3] vs 88.1% [12.3], p = 0.08).^32^

## SUPPLEMENTAL SODIUM INTERVENTIONS (WITH DIURETICS)

Fifteen studies33-47 including 13 RCTs33-35,37-39,41-43,45-47 and 2 NRCSs36,44 (conducted between 1996 and 2022) involving 3,483 participants (1,707 intervention, 1,776 control) evaluated the effectiveness of HSS with diuretics (N = 14) or oral NaCl with diuretics (N = 1) in patients hospitalized with ADHF. Appendix D shows the design details and Appendix E shows the baseline characteristics of the studies. Nine studies were conducted in Europe,^33–40,44,45^ 2 in Asia,^41,43^ 2 in the Middle East,^42,46^ 1 in the US,^47^ and 1 in South America.^40^ Most studies were conducted in single-center hospitals,^34,36–46^ but 2 studies did not report the hospital settings.^33,35^ The mean age of patients ranged from 47 to 76 years. The percentage of male population ranged from 38.3% to 81.3% and males were the minority in only 2 studies. Only 1 study, which was conducted in the US, reported data on race/ethnicity (86% White and 14% Black or African American). In 11 studies,^33–35,37–40,42,43,45^ mean (SD) of left ventricular ejection fraction (LVEF) at baseline ranged from 23.9% (6.3) to 56.4% (10.6), and 2 studies^36,41^ reported median (IQR) of LVEF at baseline [(34.5) (26.5, 41) and 37 (28.5, 42.5)]. Mean (SD) of LVEDD 71.6 mm (9.7) was reported in 1 study.^40^

In 1 RCT, an independent physician assigned patients to treatment groups, and 1 RCT had major discrepancies within the text and poor methodological reporting of outcome definitions (therefore both are high risk of bias).^35,43^ Three RCTs had moderate risk of bias due to concerns over the method of allocation concealment and blinding.^33,45,46^ Finally, 2 NRCSs had high risk of bias because they either conducted crude unadjusted analyses or did not report a method to address confouding.^36,44^

Appendix F.2 describes the sodium supplementation interventions including saline solution, sodium dose, diuretics, fluid intake, other intervention (eg, dietary sodium), and duration of interventions. In 7 studies, the concentration of HSS (between 1.4% and 4.6% NaCl ) was tailored based on the patients’ serum sodium levels.^33–37,39,45^ In 6 studies,^38,40–42,46^ HSS concentration was fixed (ranging from 1.94% to 7.5% NaCl). One study used compound HSS (NaCl 2.8%, KCl 0.2%, and MgSO_4_ 0.9%)^43^ and 1 study did not report concentration of HSS.^44^ One study (conducted in the US) used an oral NaCl formulation to replicate neurohormonal effects of HSS intervention and for easy administration to the study population.^47^ Dietary sodium intake was reported in 11 studies during the intervention period.^33–39,41,43,45,47^ Total sodium intake (calculated by the research team from all sources including diet) in the supplemental sodium arms ranged from 1.15 to 8.1 g/day, and in furosemide alone arms ranged from 0.7 g/d to 2.9 g/d. All but 1 study (a conference abstract) explicitly noted that HSS or oral sodium was combined with furosemide. In 9 studies sodium supplementation was combined with a conventional dose of furosemide (≤250 mg/d),^37–39,41–43,45–47^ in 3 studies HSS was combined with high doses of furosemide (500-1000 mg/d),^33–35^ and 1 study combined HSS with 125-1000 mg of furosemide.^36^

Ten studies compared supplemental sodium with furosemide to furosemide alone,^33–37,39,42,43,45,47^ 3 studies compared HSS with furosemide to furosemide with normal saline,^38,40,46^ 1 study compared HSS with furosemide to furosemide with glucose (5%),^41^ and 1 study did not report whether patients in the comparison arm received furosemide.^44^ Intervention durations varied across the studies (ranging from 1 day to 12 days), and 3 studies did not clearly define or report the duration of intervention period.^37,39,44^

In summary (Table 4), there were significant net decreases in creatinine, BNP, and weight from admission to last in-hospital measurement for patients administered supplemental sodium and furosemide compared to furosemide alone (low confidence for BNP and moderate confidence for others). Hospital length of stay was shorter for patients who received supplemental sodium (moderate confidence). There was no significant difference in NT-pro BNP (low confidence). Studies provide insufficient evidence (no conclusion) for mortality and 30-day readmission, and the studies did not report calorie intake or clinical congestion score.

For other outcomes (certainty of evidence not assessed), there was a significant net decrease in BUN; a significant net increase in eGFR, urine output, and serum sodium; and no significant difference in cystatin C, aldosterone, or PRA for patients administered supplemental sodium and furosemide compared to furosemide alone. Patients who received supplemental sodium with furosemide had a greater likelihood of improving on the NYHA functional class from admission to discharge. Two studies had conflicting findings related to dyspnea. Two RCTs found that fewer patients who were administered HSS and furosemide experienced dyspnea. One RCT, though, found no difference in a composite measure of clinical symptoms (dyspnea, lower limb edema, weakness, palpitations, and fatigue) at discharge between groups. One RCT found a reduction in thirst at the end of the 4 day intervention. Finally, 1 RCT found no difference in intensive care unit admissions.

Table 4 Summary of Findings for Supplemental Sodium Interventions

Outcome | Studies (Patients); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Overall Confidence | Summary of Findings
Creatinine | 11 (2,766); RCT^33–35,37–42,46,47^ | No limitations | Indirect^a^ | Precise | Consistent | None | Moderate | Pooled NMD = −0.38 mg/dL, 95% CI (−0.54, −0.22)
BNP | 7 (2,848); 6 RCT^35,37–40,43^ and 1 NRCS^36^ | Serious limitations^b,c,d^ | Indirect^a^ | Precise | Consistent | Sparse data | Low | Pooled NMD = −62.84 pg/mL, 95% CI (−103.61, −22.08)
NT-pro BNP | 3 (235); RCT^41,45,47^ | Serious limitations^e^ | Indirect^a^ | Imprecise^f^ | Consistent | Sparse data^g^ | Low | Pooled NMD = −1614.17 pg/mL, 95% CI (−3581.66, 353.31)
Caloric intake | 0 | NA | NA | NA | NA | NA | NA | No evidence
Clinical congestion score | 0 | NA | NA | NA | NA | NA | NA | No evidence
Weight change | 14 (3,333); 13 RCTs^33–35,37–43,45–47^ and 1 NCRS^44^ | No limitations | Indirect^a^ | Precise | Consistent^h^ | None | Moderate | Pooled NMD = −2.66 kg, 95% CI (−4.70, −0.62)
Mortality (all cause) | 4 (2,317); RCT^35,37,40,43^ | Serious limitations^b^ | Indirect^a^ | Imprecise | Inconsistent^i^ | Sparse data | Insufficient | No conclusion
Readmission | 2 (159); RCT^35,47^ | Serious limitations^b^ | Direct | Precise | Inconsistent^j^ | None | Insufficient | No conclusion
Length of hospital stay | 11 (3,243); 9 RCTs^33–35,37–39,42,44,47^ and 2 NRCS^36,44^ | Serious limitations^b,^ ^c,^ ^k^ | Direct | Precise | Consistent | Large effect^l^ | Moderate | Pooled NMD = −2.90 days, 95% CI (−4.02, −1.79

Notes.

a Studies reported outcomes at different time points;

b One RCT was high risk of bias due to randomization decided by an independent physician and no allocation concealment,

c One RCT was high risk of bias due to outcome not clearly being defined and uncertainty about blinding;

d One NRCS was high risk of bias because treatment and comparison groups were matched by age and sex and no adjusted comparisons;

e One RCT was moderate risk of bias due to no blinding of participants and personnel and unclear allocation concealment;

f One RCT reported significant net decrease in NT-proBNP and 2 RCTs reported non-significant decrease in outcome result;

g Two RCTs reported outcome in median (IQR) and 1 RCT reported outcome in mean (SD);

h One RCT reported a small weight gain (0.12 kq) in HSS group after 24-hr HSS intervention compared to furosemide alone while the remaining RCTs reported weight loss;

I Two RCTs reported no death during hospitalization, 1 RCT reported greater mortality risk in HSS group during hospitalization, and 1 RCT reported higher mortality risk in control group at 30-day follow-up;

j 1 RCT found reduction in 30-day readmission and another RCT found no difference in 30-day readmission outcome;

k 1 RCT was moderate risk of bias due to no blinding and incomplete outcome data;

l 1 NRCS being an outlier of longer length of stay in HSS group after the intervention.

Abbreviations. BNP=brain (or B-type) natriuretic peptide; CI=confidence interval; kg=kilogram; NA=not applicable; NMD=net mean difference; NRCS=non-randomized controlled trial; NT-proBNP=N-terminal pro-brain (or B-type) natriuretic peptide; RCT=randomized controlled trial; RR=relative risk.

### Intermediate Outcomes

#### Serum Creatinine

Eleven RCTs^33–35,37–42,46,47^ found a significant net decrease in serum creatinine from baseline to the last in-hospital measurement for patients randomized to HSS or oral NaCl with furosemide compared to furosemide alone (pooled NMD = −0.38 mg/dL, 95% CI [−0.54, −0.22]; Figure 7). Duration of intervention varied among studies (from 1 to 6 or more days, or until compensation), as did the timing of the last in-hospital measurement (24 hours to 6 days or discharge).

Meta-analysis revealed statistical heterogeneity in NMDs across studies. As shown in Figure 7, studies with shorter durations of intervention (1-3 days), which also had shorter duration of follow-up (1 to 4 days or compensation), found no difference in NMD for serum creatinine (pooled NMD = 0.03 mg/dL, 95% CI [−0.21, 0.27]), but after about 4 or 6 or more days of treatment and follow-up, serum creatinine levels were significantly lower in the sodium supplementation group (pooled NMD = −0.49 mg/dL, 95% CI [−0.60, −0.39]). The NMD was significantly greater in longer duration studies than shorter duration studies (p < 0.001).

Figure 7 Serum Creatinine: Supplemental Sodium (With Furosemide) versus Furosemide

Notes. Net reduction in serum creatinine is considered to be a favorable outcome.

* Time to compensation; ^†^ Compared oral NaCl with furosemide to furosemide alone.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; N=sample size; NMD=net mean difference; RoB=risk of bias.

#### Blood Urea Nitrogen (BUN)

Twelve RCTs found a significant net decrease in BUN from baseline to last reported in-hospital measurement (24 hours or 6 days or discharge) for patients randomized to supplemental sodium with furosemide compared to furosemide alone (pooled NMD = −19.2 mg/dL, 95% CI [−31.3, −7.2]; Figure 8).^33–35,37–43,46,47^ Mahjoob et al was the only study to report a large, statistically significant effect that favored furosemide alone (NMD = 50.2 mg/dL, 95% CI [3.5, 96.9]).^46^ In this study, patients were randomized to either HSS with furosemide or furosemide alone for 48 hours. The study did not offer an explanation for why BUN may have risen to such a degree. A post hoc sensitivity analysis excluding Mahjoob et al did not alter the conclusion (pooled NMD = −22.3 mg/dL, 95% CI [−33.2, −11.3]).

Meta-analysis revealed statistical heterogeneity in NMDs across studies. As shown in Figure 8, similar to serum creatinine, studies with shorter durations of intervention (1-3 days), which also had shorter duration of follow-up (1 to 4 days or compensation), found no difference in NMD for BUN levels (pooled NMD = 4.1 mg/dL, 95% CI [−3.6, 11.7]), but after about 4 or 6 or more days of treatment and follow-up, BUN levels were significantly lower in the sodium supplementation group (pooled NMD = −30.0 mg/dL, 95% CI [−39.6, −20.4]). Excluding the 1 outlier longer-term study with no effect (Wan et al) in a post hoc sensitivity analysis yielded an even greater, more precise NMD (pooled NMD = −21.2 mg/dL, 95% CI [−33.8, −8.5]). With or without Wan et al, the NMD was significantly greater in longer duration studies than shorter duration studies (p < 0.01).

Figure 8 Blood Urea Nitrogen (BUN): Supplemental Sodium (With Furosemide) versus Furosemide

Notes. Net reduction in serum BUN is considered to be a favorable outcome.

* Time to compensation. † Compared oral NaCl with furosemide to furosemide alone; ‡ Potential outlier among longer-duration studies; excluded in a post hoc sensitivity analysis of the subgroup.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; N=sample size; NMD=net mean difference; RoB=risk of bias.

#### Estimated Glomerular Filtration Rate (eGFR)

Six RCTs reported a significant net increase in eGFR from baseline to last in-hospital measurement (24 hours to 6 days or discharge) for patients randomized to HSS or oral NaCl with furosemide compared to furosemide alone (pooled NMD = 7.1 mL/min, 95% CI [1.2, 13.0]; Figure 9).^37–39,41,43,47^ Statistical heterogeneity was very large across studies, but no clear explanation was found. The single short duration study (1 day) did not differ from longer duration studies. Wan et al was the only study to report a small and significant net decrease in eGFR for patients who received HSS with furosemide compared to furosemide alone (NMD = −1.2 mL/min, 95% CI [ −2.1, −0.3). This study had major discrepancies between text and tables and unclear outcome definitions (high risk of bias). A post hoc sensitivity analysis excluding Wan et al yielded a larger and more precise effect relative to the main analysis (pooled NMD = 9.2 mL/min, 95% CI [3.7, 14.7]; I^2^ = 91%), although heterogeneity remained comparable to the main analysis.

Figure 9 Estimated Glomerular Filtration Rate (eGFR): Supplemental Sodium (With Furosemide) versus Furosemide

Notes. Net increase in eGFR is considered to be a favorable outcome.

* Compared oral NaCl with furosemide to furosemide alone; † Wan 2017 was excluded in post hoc sensitivity analysis.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; HSS=hypertonic saline solution (or oral sodium with furosemide); N=sample size; NMD=net mean difference; RoB=risk of bias.

#### Serum Cystatin C

Two RCTs found no significant difference in serum cystatin C between HSS and furosemide from baseline to last in-hospital measurement.^40,41^ One RCT found no significant difference in serum cystatin C between HSS with furosemide and furosemide alone from baseline to day 4, which was 24 hours after the intervention period (NMD = −0.15 mg/L, 95% CI [−0.50, 0.20]).^40^ Similarly, a second RCT found no significant difference in serum cystatin C between HSS with furosemide to furosemide with glucose (5%) from baseline to the end of 24-hour intervention (NMD = −0.10 mg/L, 95% CI [−0.65, 0.45]).^41^

#### Natriuretic Proteins (BNP and NT-proBNP)

Seven studies in total reported on BNP; however, only 4 reported BNP at baseline and follow-up,^35,39,40,43^ while 2 studies only reported BNP at follow-up^36,37^ and 1 study graphically reported BNP (means were not extracted).^38^ Across 6 studies reporting extractable data, there was a significant net decrease in BNP among patients who received HSS with furosemide compared to furosemide alone (pooled NMD = −62.8 pg/mL, 95% CI [−103.6, −22.1]; Figure 10).^35–37,39,40,43^ One RCT graphically reported a decrease in BNP from baseline to 6 days for patients who received HSS with furosemide compared to furosemide alone (p < 0.001). In a post hoc sensitivity analysis with the 4 studies reporting baseline and follow-up data, the net effect was greater and remained statistically significant (pooled NMD = −103.3 pg/mL, 95% CI [−151.8, −54.8]; I^2^ = 0%). The shorter duration studies were imprecise and thus did not clearly differ in findings from longer duration studies.

Figure 10 BNP: Supplemental Sodium (With Furosemide) versus Furosemide

Notes. Net reduction in BNP is considered to be a favorable outcome.

* Mean difference at follow-up time point (no baseline data reported). Excluded from post hoc sensitivity analysis.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; N=sample size; NMD=net mean difference; RoB=risk of bias.

Three RCTs found no significant difference in NT-proBNP from baseline to last in-hospital measurement (pooled NMD = −1614.2 pg/mL, 95% CI [−3581.7, 353.3]; Figure 11).^41,45,47^ The last in-hospital measurement varied between 1 to 6 days or discharge. One RCT found a significant net decrease in NT-pro BNP between HSS with furosemide compared to furosemide alone from baseline to the end of 6-day intervention period (NMD = −3078.0 pg/mL, 95% CI [−5043.4, −1112.6]).^45^ The remaining 2 RCTs found nonsignificant net decreases in NT-pro BNP between either HSS or oral NaCl and furosemide compared to furosemide alone.^41,47^

Figure 11 NT-proBNP: Supplemental Sodium (With Furosemide) versus Furosemide

Notes. Net reduction in NT-proBNP is considered to be a favorable outcome.

* Compared oral NaCl with furosemide to furosemide alone.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; HSS=hypertonic saline solution (or oral sodium with furosemide); N=sample size, NMD=net mean difference, RoB=risk of bias.

#### Weight

Fourteen studies (13 RCTs^33–35,37–43,45–47^ and 1 NRCS^44^) reported change in body weight from baseline to in-hospital follow up (3 to 6 days or discharge). Wan et al presented weight data that was inconsistent with adult patients (eg, 23.44 kg mean weight at baseline) and was excluded from meta-analyses.^43^ Roul et al reported median weight without data to allow an estimate of variance (net median difference = −7 kg), so we used the median SD from the other 11 RCTs in the meta-analysis. In pooled data from 13 studies,^33–35,37–42,45–47^ there was a significant net decrease in weight from baseline to last in-hospital measurement for patients who received supplemental sodium with furosemide compared to furosemide alone (pooled NMD = −2.7 kg, 95% CI [−4.7, −0.6]; Figure 12).

Meta-analysis revealed statistical heterogeneity in NMDs across studies. As shown in Figure 12, studies with shorter durations of intervention (1-3 days), which also had shorter duration of follow-up (1 to 4 days or compensation), found no difference in NMD for weight (pooled NMD = 0.4 kg, 95% CI [−1.8, 1.1]), but after about 4 or 6 or more days of treatment and follow-up, weight changes were significantly greater in the sodium supplementation group (pooled NMD = −3.2 kg, 95% CI [−5.9, −0.5]). The NMD was not significantly greater in longer duration studies than shorter duration studies (p = 0.10).

Montgomery et al compared oral NaCl with furosemide to furosemide alone and was the only study to report an increase in weight, but the effect size was small and nonsignificant. In a post hoc sensitivity analysis, we excluded Roul et al (for which we estimated the SD) and the pooled NMD was minimally changed (pooled NMD = −2.5 kg, 95% CI [−4.6, −0.5]). In another post hoc sensitivity analysis, we excluded Tuttolomondo 2021 et al, which reported a much larger reduction in weight than the other studies. The net effect remained statistically significant, but with a substantially smaller effect size (pooled NMD = −1.5 kg, 95% CI [−2.7, −0.3]; I^2^ = 56%).

Figure 12 Weight: Supplemental Sodium (With Furosemide) versus Furosemide

Notes. Net reduction in weight is considered to be a favorable outcome.

* Time to compensation; † Compared oral NaCl with furosemide to furosemide alone; ‡ Potential outlier. Excluded in a post hoc sensitivity analysis; § NMD and 95% CI estimated from reported median data. Excluded in a post hoc sensitivity analysis.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; HSS=hypertonic saline solution (or oral sodium with furosemide); N=sample size; NMD=net mean difference; RoB=risk of bias.

#### Urine Output

Twelve RCTs reported urine output at various periods of follow-up (24 hours to 4 days or 6 days or discharge).^33–35,37–41,43,45–47^ Most reported average daily (24 hour) urine output for the duration of follow-up. One study (Issa et al) reported only urine output (per kg per hour) on selected days and was excluded from meta-analyses.^40^ Meta-analysis of the 11 RCTs that reported average daily urine output (or equivalent data) found a clinically large, statistically significant greater urine output in the sodium supplementation with furosemide groups (pooled MD = 517.6 mL/24 hr, 95% CI [425.9, 609.3]; Figure 13). Although there was some heterogeneity in the estimate of the MD, the studies were consistent in finding favorable effects of sodium supplementation with furosemide, which were mostly clinically large and statistically significant. The study by Issa et al, which reported day-specific data for 3 days plus 24 hours post-intervention, in contrast found a nonsignificant, small effect (p = 0.07). If we assume that their reported data represent the full duration of follow-up for all patients, then the estimated MD was 43.6 mL/24 hr (95% CI [−3.6, 90.8]). Including this in the meta-analysis would reduce the pooled MD to 459.4 mL/24 hr (95% CI [327.0, 591.8]).

Figure 13 Urine Output: Supplemental Sodium (With Furosemide) versus Furosemide

Notes. Net increase in urine output is considered to be a favorable outcome. * Compared oral NaCl with furosemide to furosemide alone.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; N=sample size; NMD=net mean difference; RoB=risk of bias.

#### Caloric Intake

No study reported data on caloric or fluid intake.

#### Serum Sodium

Thirteen studies (12 RCTs^33–35,37–43,46,47^ and 1 NRCS^44^) evaluated serum sodium at baseline and at the end of intervention or discharge. Pooled data from 13 studies found a significant net increase in serum sodium from baseline to last in-hospital measurement (24 hours to 6 days or discharge) for patients who received sodium supplementation with furosemide compared to furosemide alone (pooled NMD = 6.0 mEq/L, 95% CI [3.6, 8.4]; Figure 14). Results remained consistent in a post hoc sensitivity analysis that excluded data from the NRCS that only reported serum sodium at follow-up (pooled NMD = 5.9 mEq/L, 95% CI [3.4, 8.5].^44^

Meta-analysis revealed large statistical heterogeneity in NMDs across studies (I^2^ = 94%). As shown in Figure 14, studies with shorter durations of intervention (1-4 days), which also had shorter duration of follow-up (1 to 4 days or compensation), mostly found no difference for serum sodium (pooled NMD = 1.3 mg/dL, 95% CI [−0.5, 3.0]), but after about 4-6 or more days of treatment and follow-up, NMD for serum sodium was larger (pooled NMD = 8.1 mg/dL, 95% CI [5.7, 10.6]). The NMD was significantly greater in longer duration studies than short duration studies (p < 0.01). While the statistical heterogeneity across the longer duration studies remained high, they all consistently found a relatively large, statistically significant improvement with sodium supplementation.

Figure 14 Serum Sodium: Supplemental Sodium (With Furosemide) versus Furosemide

Notes: Net increase in serum sodium is considered to be a favorable outcome.

* Time to compensation. † Compared oral NaCl with furosemide to furosemide alone. ‡ NMD and 95% CI estimated from reported median data. Excluded in a post hoc sensitivity analysis.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; N=sample size, NMD=net mean difference; RoB=risk of bias.

#### Serum Aldosterone

Three RCTs found no significant difference in serum aldosterone from baseline to end of intervention (1 day to discharge) for patients who received HSS or oral NaCl with furosemide compared to furosemide alone (pooled NMD = −1.7 pg/mL, 95% CI [−21.9, 18.5]; Figure 15).^40,41,47^ Montgomery et al reported a nonsignificant net increase in aldosterone, but the estimate was imprecise with a large confidence interval.

Figure 15 Serum Aldosterone: Supplemental Sodium (With Furosemide) versus Furosemide

Notes. Net decrease in serum aldosterone is considered to be a favorable outcome.

* Unit used for aldosterone was not reported; † Compared oral NaCl with furosemide to furosemide alone.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; HSS=hypertonic saline solution (or oral sodium with furosemide); N=sample size; NMD=net mean difference; RoB=risk of bias.

#### Plasma Renin Activity (PRA)

One RCT found no significant difference in PRA from baseline to at the end of 24-hr intervention in patients who received HSS with furosemide compared to furosemide alone (net median difference = −0.1 ng/mL/hr).^41^ One study reported no significant difference in renin levels from baseline to in-hospital follow-up (4 days) for patients who received HSS with furosemide intervention compared to furosemide alone (net median difference = 2.2, unit not reported).^40^

### Clinical Outcomes

#### Clinical Congestion Score

No study reported data on a clinical congestion score.

#### Heart Failure–Related Symptoms

Three RCTs reported the change in NYHA functional class from admission to discharge.^33,37,43^ In 2 studies (Paterna 2000 and Paterna 2011), all patients had a reduction in NYHA class prior to discharge (by 1 or 2 classes); in Wan et al, 88% had improvement. Pooling data from the 3 studies found that those randomized to HSS and furosemide were more likely to improve by 2 NYHA functional classes (eg, from class IV to II or from class III to I) than those on furosemide only (pooled RR = 1.64, 95% CI [1.18, 2.27]; Figure 16).^33,37,43^ In the study by Wan et al (where 12% of patients did not improve in NYHA class), the RR for improving by 1 or 2 classes was not statistically significant (RR = 1.42, 95% CI [0.68, 2.96]).

Figure 16 NYHA Functional Class, Change in Class: Supplemental Sodium (With Furosemide) versus Furosemide

Notes. The analyzed outcome is an improvement (in NYHA class). Thus, RR > 1 favors HSS (improved heart function is more likely with HSS).

* All patients improved by 1 or 2 NYHA classes in Paterna 2000 and Paterna 2011.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention; RoB=risk of bias; RR=relative risk.

#### Thirst

One RCT reported reduction in symptoms of thirst (TDS-HF score) from baseline to the end of 4-day intervention among patients randomized to oral NaCl with furosemide compared to furosemide alone. The score ranged from −1.2 to 0.11, with higher scores indicating greater thirst symptoms. No significant difference was found (NMD = −1.3 unit, 95% CI [−4.2, 1.5]).^47^

#### Shortness of Breath

Two RCTs reported data on shortness of breath.^41,45^ One RCT reported fewer patients experienced dyspnea and systematic venous congestion 24 hours after treatment among patients randomized to HSS with furosemide compared to furosemide with 5% glucose (RR = 1.73, 95% CI [1.10, 2.71]).^41^ A second RCT reported no significant difference in resting dyspnea and work effort dyspnea between the groups at the end of the intervention (RR = 0.46, 95% CI [0.1, 2.03] and RR = 0.52, 95% CI [0.278, 0.99], respectively).^45^

#### Composite Clinical Parameters

One RCT^43^ found no significant difference in a composite measure of clinical symptoms (dyspnea, lower limb edema, weakness, palpitations, and fatigue) at discharge for patients administered HSS with furosemide or furosemide alone (RR = 0.99, 95% CI [0.92, 1.07]).

#### Mortality (All-Cause)

Four RCTs reported all-cause mortality.^35,37,40,43^ Two RCTs reported no deaths in both groups during hospitalization.^37,43^ One RCT (Issa et al) reported an atypically large number of in-hospital deaths compared with other studies. They reported 10 (50%) in-hospital deaths among patients randomized to HSS with furosemide and 4 (33.3%) in-hospital deaths for patients randomized to furosemide alone (RR = 1.5, 95% CI [0.60, 3.74]).^40^ The fourth RCT reported 3 deaths during 30-day follow-up in patients treated with furosemide alone (0 vs 3 deaths, RD = −0.065, 95% CI [−0.145, 0.015].^35^

### Health Service Utilization Outcomes

#### Readmission

One RCT^35^ found a decrease in 30-day heart failure–related readmission for HSS with furosemide compared to furosemide alone (0 vs 12 events; RD = −0.26, 95% CI [−0.39, −0.13]). Another RCT found no significant difference in 30-day readmissions for oral NaCl with furosemide compared to furosemide alone (RR = 0.91, 95% CI [0.36, 2.31]).^47^

#### Length of Stay

Eleven studies (9 RCTs^33–35,37–39,42,43,47^ and 2 NRCSs^36,44^) reported hospital length of stay. One NRCS^44^ reported a longer median length of stay for patients who received HSS compared to no HSS (median difference = 11 days). This study did not report data to estimate a variance between groups and thus was excluded from meta-analysis. Of note, this study was an outlier both in direction and magnitude of difference in length of stay. The pooled estimate of the 10 remaining RCTs showed a shorter length of stay for sodium supplementation with furosemide compared to furosemide alone (pooled MD = −2.9 days, 95% CI [−4.0, −1.8]; Figure 17).^33–39,42,43^ Among these 9 RCTs, there were 2 outlier studies that found no difference (Tuttolomondo 2011 et al and Montgomery 2023 et al). Excluding these studies in a post hoc sensitivity analysis yielded a slightly greater effect, with greater precision (pooled MD = −3.5 days, 95% CI [−4.3, −2.7], I^2^ = 94%). Of note, Montgomery 2023 et al was the only study conducted in the US, and it found no significant difference between oral NaCl with furosemide compared to furosemide alone (MD = 0.3 days, 95% CI [−2.5, 3.2]).

Figure 17 Length of Hospital Stay: Supplemental Sodium (With Furosemide) versus Furosemide

Notes. Shorter length of stay is considered to be a favorable outcome.

* Compared oral NaCl with furosemide to furosemide alone.

Abbreviations. CI=confidence interval; d=day; DOI=duration of intervention N=sample size; MD=Mean difference; RoB=risk of bias.

#### Transfer to Intensive Care Unit (ICU)

One US-based RCT found no significant difference in intensive care unit admission during hospitalization for oral NaCl with furosemide compared to furosemide alone (RR = 0.56, 95% CI [0.15, 2.15]).^47^