# METHODS

## TOPIC DEVELOPMENT

We worked with representatives from VHA Hospital Medicine and our Technical Expert Panel (TEP) to refine the review scope and develop the key questions (KQ). We focus on studies that report on prescribed sodium intake to manage ADHF in an inpatient setting (eg, restricted dietary sodium intake or HHS). We excluded studies that did not prescribe sodium intake (eg, epidemiologic evaluation where daily sodium intake was evaluated as a continuous measure). We evaluated the effect that prescribed sodium intake had on intermediate measures (eg, neurohormonal activation and weight), clinical outcomes (eg, time to clinical stability and clinical congestion score), and health service use outcomes (eg, length of hospital stay and 30-day rehospitalization).

## KEY QUESTIONS

KQ1 Among adults hospitalized for decompensated heart failure, what is the comparative effectiveness of different prescribed sodium intake interventions?
KQ1a Does effectiveness differ as a function of patient characteristics, including by age, comorbid conditions (kidney function, hypertension, diabetes, stroke, body mass index), existing versus new onset heart failure, preserved versus reduced ejection fraction or pre-hospitalization dietary sodium intake, sex, and race/ethnicity?

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42023410146).

## DATA SOURCES AND SEARCHES

We searched Medline (via PubMed), Embase, ClinicalTrials.gov, CINAHL, and the Cochrane Database of Systematic Reviews from inception to February 13, 2023. We used Medical Subject Headings (MeSH) and free text terms for decompensated heart failure and related terms, prescribed sodium intake, and inpatient, together with filters for primary studies (see Appendix A for complete search strategies). We ensured that known relevant publications were captured by our searches. Additional citations were sought from hand-searching reference lists of relevant systematic reviews and consultation with content experts.

## STUDY SELECTION

Citations were uploaded into EndNote, where duplicates were removed. We screened citations in Abstrackr (http://abstrackr.cebm.brown.edu),^22^ which has machine learning algorithms to prioritize relevant citations. To ensure a common understanding of the eligibility criteria, we ran pilot rounds of 100 citations at a time, where all team members screened the same citations, until we achieved acceptable agreement. Subsequently, we screened citations in duplicate with conflicts adjudicated during team meetings or by a third senior researcher. Based on empirical evidence, we stopped screening when all remaining unscreened abstracts had a prediction value of <0.40 (on a 0–1 scale) and subsequently 400 abstracts in a row were rejected.^22^ Accepted abstracts underwent full-text review using an evidence mapping process independently by 1 researcher with confirmation of excluded articles by a second researcher. When necessary, the reviewers consulted a third senior researcher. A list of studies excluded at full-text review, with rejection reasons, is provided in Appendix B.

Eligibility criteria are listed in Table 1. In brief, eligible study participants were ≥18 years of age, hospitalized and treated for ADHF. Eligible studies evaluated the effect of prescribed sodium intake interventions, including restricted dietary sodium intake and supplemental sodium intake. We included any dietary sodium restriction, any concentration of intravenous supplemental NaCl (including HSS, half-normal saline, etc), and any prescribed supplemental oral NaCl intake. Studies were excluded if they were conducted in the emergency department (without an inpatient component) or outpatient setting, if they did not report patient-level interventions (eg, comparison of hospital policies that were not explicitly uniformly applied), or did not include a comparison group. We included RCT, nonrandomized comparative studies (NRCS), and other comparative observational studies, whether prospective or retrospective, and regardless of whether they were adjusted for potential confounders. We analyzed laboratory or intermediate measures, clinical outcomes, and health care utilization. We analyzed all outcomes except 30-day rehospitalization and 30-day mortality from the first in-hospital measurement to the end of the intervention or discharge.

Table 1 Inclusion and Exclusion Criteria

| Inclusion Criteria | Exclusion Criteria
Population | Adults ≥18 years of age hospitalized for treatment of decompensated HF, including for exacerbation of a chronic condition or new onset or previously undetected heart failure | - Advanced HF requiring mechanical support or heart transplant; - Patients in cardiogenic shock; - Patients undergoing surgery; - Patients on dialysis
Intervention | Prescribed sodium intake; - Restricted dietary sodium intake; - Increased oral sodium intake (eg, NaCl tablets); - Intravenous saline (hypertonic saline, normal saline, hypotonic [half normal] saline, other saline) | - Patients not prescribed sodium intake (eg, a hospital policy without explicit implementation in individuals); - Sodium intake evaluated as a continuous variable; - Subgroups of patients based on average sodium intake or hospital policy
Comparator | - More (including normal/typical) sodium intake (as a comparator of restricted dietary sodium intake); - Less oral sodium intake (as comparator of sodium tablets); - Other intravenous saline regimen (including none)
Outcomes | - Laboratory/Intermediate measures; ○ RAAS activation; ○ Neurohormonal activation; ○ Kidney function (eg, serum creatinine, eGFR); ○ BNP / NT-proBNP; ○ Urine output; ○ Weight loss; ○ Nutritional intake (calories and fluid); - Clinical outcomes; ○ Clinical congestion score; ○ Supplemental oxygen levels; ○ Duration or timing of IV diuretics; ○ Time to clinical stability (as defined by study); ○ Mortality (inpatient and 30 days); ○ Quality of life (generic or HF-specific); ○ HF-related symptoms (eg, thirst, shortness of breath); ○ Prescribed guideline recommended therapy after discharge (eg, ACE inhibitors); - Adherence to prescribed diet in the inpatient setting.; - Discharge location (eg, home, skilled nursing, cardiac rehab); - Health care utilization; ○ Length of hospital stay; ○ Hospital readmission related to HF within 30 days; ○ Cardiovascular related ED visit within 30 days; ○ Transfer to ICU (proxy for clinical deterioration); ○ Mechanical ventilation (proxy for clinical deterioration)
Timing | - In-hospital (preferentially end-of-treatment or hospital discharge) for all except 30-days post discharge for hospital readmission and mortality
Setting | - Inpatient | - Emergency department only; - Outpatient
Study Design | - RCT; - Nonrandomized comparative study, prospective or retrospective | - Single group (noncomparative) studies; - Association between sodium as a continuous measure (not a prescribed intervention) and outcomes
Other | - No language restriction; - No country restriction

Abbreviations. ACE inhibitors=angiotensin converting enzyme inhibitors; BNP=brain (or B-type) natriuretic peptide; ED=emergency department; eGFR=estimated glomerular filtration rate; HF=heart failure; ICU=intensive care unit; NT-proBNP=N-terminal pro-brain (or B-type) natriuretic peptide; NRCS=nonrandomized comparative study; RAAS=renin-angiotensin-aldosterone system; RCT=randomized controlled trial.

## DATA EXTRACTION AND ASSESSMENT

We created a data extraction form in the Systematic Review Data Repository-Plus (SRDR+) online system (https://srdrplus.ahrq.gov). We extracted the following data from eligible studies: study design, setting, baseline population characteristics, amount, and duration of sodium intake (intervention and comparator), and intermediate, clinical, and health service use outcomes. All data extraction was first completed by 1 reviewer and then checked by a second reviewer. Disagreements were resolved by consensus or discussion with a third reviewer.

Study risk of bias was independently assessed by 2 reviewers using questions derived from the Cochrane Risk of Bias and the ROBINS-I (Risk Of Bias In Non-randomized Studies – of Interventions) tools (Appendix C).^23,24^ For all study designs, we also evaluated whether the article was free of discrepancies, and reporting of patient eligibility criteria, protocols, setting, and outcome assessments were sufficiently clear. For RCTs, we evaluated the method of randomization, allocation concealment, and whether intention-to-treat analysis was used. For NRCSs, we evaluated whether patients in the treated and comparison groups were similar and what strategies were used to deal with potential confounders.

## SYNTHESIS AND CERTAINTY OF EVIDENCE

For both KQs, we compared results in study groups using relative risks (RR) for dichotomous outcomes. When a study had no events in 1 group, we calculated risk differences (RD). We compared continuous data using net mean differences (NMD; ie, difference-in-differences or between-intervention comparisons of within-intervention changes from baseline to follow-up) or mean differences (MD) between interventions for outcomes evaluated only post-intervention (eg, length of stay). When necessary, we estimated NMDs or MDs and their standard deviations from reported data, including from reported medians and ranges.^25,26^ Adjusted analyses were preferentially extracted over unadjusted (crude) comparisons. Where there were at least 3 studies reporting results from sufficiently similar analyses (based on population, interventions, comparators, and outcomes), we conducted meta-analyses using the restricted maximum-likelihood estimation (REML) random-effects models in the “meta” package for R version 4.3.0 (2023-04-21). Statistical heterogeneity was estimated using the I^2^ statistic, which estimates the percentage of heterogeneity ascribed to statistical heterogeneity (not ascribed to random chance).

We assessed the certainty of evidence following the GRADE (Grading of Recommendations Assessment, Development and Evaluation) approach.^27^ We compiled key study findings in evidence profiles, which provide the basis for determination of certainty of evidence and summarize conclusions for outcomes prioritized by the stakeholders: serum creatinine, BNP, NT-pro BNP, caloric intake, clinical congestion score, weight loss, 30-day all-cause mortality, 30-day readmission, and length of hospital stay. Within each priority outcome, we considered the study design, the number of studies (and participants), methodological limitations (ie, risk of bias), directness of the evidence, precision of the findings, consistency across studies, and other issues. Based on these, we determined certainty of evidence, which could be high, moderate, or low. Where we found few or no comparable studies, we report that there is insufficient evidence to draw conclusions. We did not determine certainty of evidence for non-prioritized outcomes.