# INTRODUCTION

## PURPOSE

The Evidence Synthesis Program (ESP) was asked by the Veterans Health Administration (VHA) Hospital Medicine for an evidence review on interventions affecting sodium intake (eg, dietary sodium restriction and supplemental sodium chloride [NaCl] given as either hypertonic saline solution [HSS] infusion or oral NaCl tablets) for adults ≥18 years of age hospitalized for acute decompensated heart failure (ADHF). For decades, standard non-pharmacologic inpatient care for people with ADHF has included restricting dietary sodium intake. However, evidence on the benefit of sodium restriction in the inpatient setting is mixed and there are concerns of harms, particularly related to antidiuretic effects and poor nutritional intake. In contrast, several studies suggest that the use of supplemental sodium in combination with an intravenous diuretic regimen may improve kidney function and reduce mortality in patients with ADHF. Veterans and providers could benefit from clear guidance on the use of sodium intake interventions to manage ADHF in an inpatient setting. VHA Hospital Medicine intends to use this ESP review to inform national clinical guidance on sodium restriction during acute care for patients with ADHF.

## BACKGROUND

Heart failure (HF) affects around 26 million people worldwide,^1^ 6.2 million people in the United States (US) alone, and 5% of Veterans.^2,3^ HF is also a leading cause of hospitalization and rehospitalization in the US.^4^ Despite progress in evidence-based pharmacotherapies and device interventions, most HF patients are hospitalized within 5 years of a diagnosis.^5,6^ Approximately 38% of hospitalizations of people with HF are for ADHF,^5^ which is characterized by sudden or gradual onset of signs and symptoms of HF with pulmonary and/or systemic congestion related to increased left- and right-heart filling pressures (eg, dyspnea, orthopnea, weight gain, and lower limb swelling). People experiencing ADHF require immediate hospitalization or unplanned office or emergency room visits to stabilize their symptoms.^7,8^

The goal of treatment for patients hospitalized with ADHF is to reverse acute hemodynamic abnormalities and improve symptoms.^9^ This is predominantly achieved by using diuretics (eg, loop diuretics) and vasodilators that decrease venous congestion and volume overload.^9^ In addition to pharmacological therapies, for decades the standard inpatient management of ADHF has included restricting dietary sodium.^10^ However, there is no consensus in clinical guidelines on the threshold of sodium intake per day. For example, the 2022 American Heart Association/American College of Cardiology/Heart Failure Society of America (AHA/ACC/HFSA) Guideline for the Management of Heart Failure recommends a daily sodium intake of <2.3 g/day, and the 2021 European Society of Cardiology (ESC) guidelines recommend sodium intake of <5 g/day.^11,12^

The motivation to restrict dietary sodium is based on the clinical observation that excess sodium contributes to fluid retention.^13^ However, sodium restriction can also have a negative effect by activating antidiuretic and anti-natriuretic systems, which leads to further development of congestion.^14^ There is also concern that patients find low-sodium food less flavorful, which could negatively affect nutrition intake and lead to poor adherence to a low-sodium diet. Low sodium intake may also reduce blood pressure that in turn increases heart rate and negates the effects of beta-blockers.^14^ Most data on restricted dietary sodium come from studies conducted in outpatient settings.^15^ Few studies have formally evaluated the effect of sodium restriction in inpatient settings.

Conversely, supplemental sodium (either HSS infusion or oral NaCl tablets) has been proposed as an adjuvant therapy to loop diuretics to improve diuretic efficacy in patients hospitalized with ADHF.^16^ This therapeutic approach is motivated by the observation that volume expansion by HSS as a resuscitation fluid leads to the mobilization of fluid to the intravascular compartment, which is followed by increased urine output.^18^ Randomized controlled trials (RCTs) conducted in inpatient and outpatient settings found that HSS with loop diuretics improved kidney function, urine output, weight loss, and electrolyte abnormalities, in addition to decreased plasma renin activity (PRA), inflammatory markers, and biomarkers including brain (or B-type) natriuretic peptide (BNP) levels.^17–19^ Despite the potential clinical benefits, inpatient providers may be hesitant to adopt HSS given conceptual concerns that increased sodium intake may exacerbate HF symptoms.^18^

To date, most systematic reviews on sodium intake interventions have included studies combining data from both inpatient and outpatient settings.^20,21^ We, therefore, conducted a systematic review on comparative effectiveness of various oral and/or intravenous prescribed sodium intake interventions in the treatment for ADHF patients during hospitalization.