# APPENDIX I PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 3 | Yes | Thank you.
3 | 4 | Yes | Thank you.
4 | 5 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
5 | 1 | No | Thank you.
6 | 3 | No | Thank you.
7 | 4 | No | Thank you.
8 | 5 | No | Thank you.
Are you aware of any published or unpublished studies that we may have overlooked?
9 | 1 | No | Thank you.
10 | 3 | No | Thank you.
11 | 4 | Yes - This study was published in 2023 and is an RCT of oral sodium during acute heart failure.; “Oral Sodium to Preserve Renal Efficiency in Acute Heart Failure: A Randomized, Placebo-Controlled, Double-Blind Study” PMID: 37044281 DOI: 10.1016/j.cardfail.2023.03.018 | The identified study was published after our search date. We have added the study to the report and updated the results and text accordingly.
12 | 5 | Yes - https://www.thelancet.com/journals/lancet/article/PIIS0140-6736(22)00369-5/fulltext | The suggested study was not conducted in hospitalized heart failure patients, and does not meet our review eligibility criteria.
Additional suggestions or comments can be provided below.
19 | 1 | Wow. This is just amazing. | Thank you.
20 | 3 | There not seem to have bias on the analysis of data itself.; But there seems to have a clear indication, between the lines, that the studies are “not good enough” because are made “somewhere else” outside US. | Thank you. Our intent was to note that health system related outcomes may not generalize across countries. We revised the text to clarify that studies in the US are needed to evaluate outcomes in the US context. “Limited evidence of RCT data from North America suggests a unique opportunity for VA hospitals to evaluate effectiveness and implementation of this strategy in the US and to fill the gaps in evidence for VA providers and policy makers. Conducting studies in the US would be particularly informative to understand the effect of intervention on health system outcomes pertinent to the US (such as length of hospital stay), which are likely to differ substantially across different health systems and countries.”
21 | 4 | The authors appropriately point out that the HSS/furosemide data largely comes from Europe and that the findings (particularly LOS) may not apply to VA. Would it be valuable to expand on this by noting that most of the European studies are from the same research group? | Thank you for this comment. We revised the Discussion to comment that 3 research groups were responsible for conducting the majority of the European studies.
22 | 4 | Ezekowitz et al RCT form Lancet was missed it appears which I hope is because the data cut was before 2022 otherwise would be a major oversight.; https://www.thelancet.com/journals/lancet/article/PIIS0140-6736(22)00369-5/fulltext; Otherwise reads well | Thank you for sharing this study. Upon review, we found that the suggested study was not conducted in hospitalized heart failure patients, and, thus, does not meet our review eligibility criteria.