# APPENDIX H CONTINUOUS OUTCOMES

Outcome | Study, Year, PMID | Arm | Total Sodium Intake/d^1^ | Fluid Intake/d | Time | Outcome Definition | N | Mean (SD)/Median (IQR) | MD (95% CI)^2^ | Reported P Value
Lab/Intermediate Measures
Weight | Diet (g/d Na)
Weight | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | Baseline | Weight (kg) | 38 | 78 (14.6) | - | 0.29
Weight | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | Baseline | Weight (kg) | 37 | 82.4 (21.5) | - | 0.29
Weight | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | 3 (d) | Weight change (kg) from baseline to day 3 (primary end point). | 38 | −4.42 (2.85) | NMD 0.25; (−1.9, 2.4)^3^ | P value (NMD); 0.82
Weight | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | 3 (d) | Weight change (kg) from baseline to day 3 (primary end point). | 37 | −4.67 (5.6) | NMD 0.25; (−1.9, 2.4)^3^ | P value (NMD); 0.82
Weight | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | 7 (d) | Weight change from baseline to day 7 | 38 | NR | - | P value (NMD); 0.12
Weight | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | 7 (d) | Weight change from baseline to day 7 | 37 | NR | - | P value (NMD); 0.12
Weight | d’Almeida, 2018, 2979305 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | Baseline | Weight (kg) | 30 | 80.5 (17.8) | - | 0.58
Weight | d’Almeida, 2018, 2979305 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | Baseline | Weight (kg) | 23 | 77.6 (16.1) | - | 0.58
Weight | d’Almeida, 2018, 2979305 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | 3 (d) | Weight (kg) change from baseline to day 3 (primary end point). | 30 | NR | NR | P value (NMD); >0.99
Weight | d’Almeida, 2018, 2979305 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | 3 (d) | Weight (kg) change from baseline to day 3 (primary end point). | 23 | NR | NR | P value (NMD); >0.99
Weight | d’Almeida, 2018, 2979305 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | 7 (d)^#^ | Weight (kg) change from baseline to day 7 | 30 | −1.6 (2.2) | NMD 0.2; (−0.36, 0.77)^3^ | P value (NMD); 0.49
Weight | d’Almeida, 2018, 2979305 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | 7 (d)^#^ | Weight (kg) change from baseline to day 7 | 23 | −1.8 (2.1) | NMD 0.2; (−0.36, 0.77)^3^ | P value (NMD); 0.49
Weight | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | Weight (kg) | 16 | 80.9 (32.7) | -
Weight | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | Weight (kg) | 15 | 68.5 (13) | -
Weight | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Weight (kg) at day 7 | 16 | 76.2 (31.8) | 11.4; (−5.7, 28.5); NMD −1; (−18.2, 16.2) | NR
Weight | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Weight (kg) at day 7 | 15 | 64.8 (14.0) | 11.4; (−5.7, 28.5); NMD −1; (−18.2, 16.2) | NR
Weight | Velloso, 1991, 1824218 | Low sodium diet | 0.8 g/d Na for NR days^4^ | 800 mL/d | Uncompensated and vs. compensated | Percentage change in weight | 14 | 12.2 (9.2) | 2.2; (−3.5, 7.9)^3^ | 0.45
Weight | Velloso, 1991, 1824218 | Unrestricted sodium diet | 4 g/d Na for NR days^4^ | 800 mL/d | Uncompensated and vs. compensated | Percentage change in weight | 18 | 10.0 (5.9) | 2.2; (−3.5, 7.9)^3^ | 0.45
Weight | HSS (% NaCl)
Weight | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 (d); Total Na 5.9 =~6 g/d^5^ | NR | Baseline | Weight (kg) | 20 | 83.8 (18.4) | - | P interaction; 0.62
Weight | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 (d); Total Na 0.7 g/d^5^ | NR | Baseline | Weight (kg) | 12 | 79.0 (28.0) | - | P interaction; 0.62
Weight | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 (d); Total Na 5.9 =~6 g/d^5^ | NR | 1 (d) | Weight (kg) | 20 | 82.8 (18.0) | 4.6; (−13.8, 23.0) | P interaction; 0.62
Weight | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 (d); Total Na 0.7 g/d^5^ | NR | 1 (d) | Weight (kg) | 12 | 78.2 (27.7) | 4.6; (−13.8, 23.0) | P interaction; 0.62
Weight | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 (d); Total Na 5.9 =~6 g/d^5^ | NR | 2 (d) | Weight (kg) | 20 | 82.0 (17.8) | 3.4; (−12.93, 19.73) | P interaction; 0.62
Weight | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 (d); Total Na 0.7 g/d^5^ | NR | 2 (d) | Weight (kg) | 12 | 78.6 (27.6) | 3.4; (−12.93, 19.73) | P interaction; 0.62
Weight | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 (d); Total Na 5.9 =~6 g/d^5^ | NR | 3 (d) | Weight (kg) | 20 | 81.3 (17.6) | 3.4; (−12.9, 19.2); NMD; (Baseline-3 d); −1.4; (−19.05, 16.25) | P interaction; 0.62
Weight | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 (d); Total Na 0.7 g/d^5^ | NR | 3 (d) | Weight (kg) | 12 | 77.9 (27.8) | 3.4; (−12.9, 19.2); NMD; (Baseline-3 d); −1.4; (−19.05, 16.25) | P interaction; 0.62
Weight | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 (d); Total Na 5.9 =~6 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Weight (kg) | 20 | 80.9 (18.3) | 4.5; (−12.0, 21.0); NMD; −0.3; (−17.97, 17.37) | P interaction; 0.62
Weight | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 (d); Total Na 0.7 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Weight (kg) | 12 | 76.4 (27.6) | 4.5; (−12.0, 21.0); NMD; −0.3; (−17.97, 17.37) | P interaction; 0.62
Weight | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Weight (kg) | 48 | 76.0 (16) | - | NR
Weight | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | Baseline | Weight (kg) | 46 | 75.8 (15) | - | NR
Weight | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | 6 (d) | Weight (kg) | 48 | 65.8 (15) | −1.3; (−7.2, 4.6); NMD; −1.5; (−7.58, 4.58) | NR
Weight | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | 6 (d) | Weight (kg) | 46 | 67.1 (14) | −1.3; (−7.2, 4.6); NMD; −1.5; (−7.58, 4.58) | NR
Weight | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline-6 d | Weight (kg) | 48 | −10.9 (4.1) | NMD; (Baseline-6 d); −2.8; (−4.15, −1.44) | <0.0001
Weight | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | Baseline-6 d | Weight (kg) | 46 | −8.1 (2.4) | NMD; (Baseline-6 d); −2.8; (−4.15, −1.44) | <0.0001
Weight | Wan, 2017, 28701670 | Furosemide with compound HSS | 100 mL c-HSS^8^ (2.8% NaCl) twice daily until clinical compensation^9^; Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Baseline | Weight (kg) | 132 | 23.4 (9)^10^ | - | NR
Weight | Wan, 2017, 28701670 | Furosemide without compound HSS | Normal sodium diet 2.76 g/d; until clinical compensation^9^; Total Na ~2.8 g/d | < 500 mL/d | Baseline | Weight (kg) | 132 | 24.2 (11)^10^ | - | NR
Weight | Wan, 2017, 28701670 | Furosemide with compound HSS | 100 mL c-HSS^8^ (2.8% NaCl) twice daily until clinical compensation^9^; Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Discharge | Weight (kg) | 132 | 21.7(70)^10^ | -
Weight | Wan, 2017, 28701670 | Without c-HSS Furosemide | Normal sodium diet 2.76 g/d; until clinical compensation^9^; Total Na ~2.8 g/d | < 500 mL/d | Discharge | Weight (kg) | 132 | 22.0 (01)^10^ | -
Weight | Mahjoob, 2021, 34903983 | Furosemide with HSS | 150 mL (5% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na 5.9=~6 g/d^5^ | NR | Baseline | Weight (kg) | 14 | 84.71 (21.11) | - | 0.7^11^
Weight | Mahjoob, 2021, 34903983 | Furosemide without HSS | 150 mL (0.9% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na ~1.1 g/d^5^ | NR | Baseline | Weight (kg) | 14 | 81.74 (19.82) | - | 0.7^11^
Weight | Mahjoob, 2021, 34903983 | Furosemide with HSS | 150 mL (5% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na 5.9=~6 g/d^5^ | NR | 3 (d) | Weight (kg) | 14 | 78.3 (20.26) | 0.2; (−14.4,14.8); NMD; −2.77; (−17.65, 12.11) | 0.98^12^
Weight | Mahjoob, 2021, 34903983 | Furosemide without HSS | 150 mL (0.9% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na ~1.1 g/d^5^ | NR | 3 (d) | Weight (kg) | 14 | 78.1 (19.04) | 0.2; (−14.4,14.8); NMD; −2.77; (−17.65, 12.11) | 0.98^12^
Weight | Mahjoob, 2021, 34903983 | Furosemide with HSS | 150 mL (5% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na 5.9=~6 g/d^5^ | NR | Baseline-3 (d) | Weight change from baseline to day 3 | 14 | −6.38 (2.17) | NMD; (Baseline-3 d); −2.79; (−4.5, −1.0)^3^ | 0.002^12^
Weight | Mahjoob, 2021, 34903983 | Furosemide without HSS | 150 mL (0.9% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na ~1.1 g/d^5^ | NR | Baseline-3 (d) | Weight change from baseline to day 3 | 14 | −3.59 (2.12) | NMD; (Baseline-3 d); −2.79; (−4.5, −1.0)^3^ | 0.002^12^
Weight | Licata, 2003, 12660669 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily for 6 to 12 (d); Normal sodium diet 2.76 g/d= ~2.8 g/d Na; Total Na 4.41-8.1 g/d | 1000 mL/d | Baseline | Weight (kg) | 53 | 74.5 (9) | - | NR
Weight | Licata, 2003, 12660669 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for; 6 to 12 (d); Total Na 1.8 g/d | 1000 mL/d | Baseline | Weight (kg) | 54 | 72.7 (9) | - | NR
Weight | Licata, 2003, 12660669 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily for 6 to 12 (d); Normal sodium diet 2.76 g/d= ~2.8 g/d Na; Total Na 4.41-8.1 g/d | 1000 mL/d | Discharge | Weight (kg) | 53 | 63.6 (8) | −0.7; (−3.9, 2.2); NMD; −2.5(−5.67, 0.67) | NR
Weight | Licata, 2003, 12660669 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for; 6 to 12 (d); Total Na 1.8 g/d | 1000 mL/d | Discharge | Weight (kg) | 54 | 64.3 (7) | −0.7; (−3.9, 2.2); NMD; −2.5(−5.67, 0.67) | NR
Weight | Licata, 2003, 12660669 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily for 6 to 12 days; Normal sodium diet 2.76 g/d= ~2.8 g/d Na; Total Na 4.41-8.1 g/d | 1000 mL/d | Baseline-Discharge | Weight change from baseline to discharge, kg. | 53 | −9.9 (4.15) | NMD; (Baseline-Discharge); −1.4; (−2.7, −0.08) | NS
Weight | Licata, 2003, 12660669 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for; 6 to 12 days; Total Na 1.8 g/d | 1000 mL/d | Baseline-Discharge | Weight change from baseline to discharge, kg. | 54 | −8.5 (2.6) | NMD; (Baseline-Discharge); −1.4; (−2.7, −0.08) | NS
Weight | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Weight (kg) | 30 | 73.8 (9.1) | - | NR
Weight | Paterna, 2000, 10938493 | Furosemide Without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | Baseline | Weight (kg) | 30 | 72.9 (9.3) | - | NR
Weight | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Weight (kg) | 30 | 63.8 (8.8) | −0.7; (−4.8, 3.4); NMD; −1.6; (−6.03, 2.83) | NR
Weight | Paterna, 2000, 10938493 | Furosemide without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | Discharge | Weight (kg) | 30 | 64.5 (7.5) | −0.7; (−4.8, 3.4); NMD; −1.6; (−6.03, 2.83) | NR
Weight | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline-Discharge | Weight change from baseline to discharge, kg. | 30 | −9.9 (4.14) | NMD; (Baseline-Discharge); −1.43; (−3.18, 0.32) | NS
Weight | Paterna, 2000, 10938493 | Furosemide Without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | Baseline-Discharge | Weight change from baseline to discharge, kg. | 30 | −8.47 (2.61) | NMD; (Baseline-Discharge); −1.43; (−3.18, 0.32) | NS
Weight | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Weight (kg) | 953 | 82.7 (13) | - | NR
Weight | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Baseline | Weight (kg) | 974 | 84.5 (15) | - | NR
Weight | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Weight (kg) | 953 | 73.2 (6) | −3.4; (−3.99, −2.80); NMD; (Baseline-Discharge); −1.6; (−2.69, −0.51) | <0.0001
Weight | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Discharge | Weight (kg) | 974 | 76.6 (7) | −3.4; (−3.99, −2.80); NMD; (Baseline-Discharge); −1.6; (−2.69, −0.51) | <0.0001
Weight | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Baseline | Weight (kg) | 122 | 75.8 (15) | - | 0.72
Weight | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Baseline | Weight (kg) | 126 | 76.5 (16) | - | 0.72
Weight | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Discharge | Weight (kg) | 122 | 64.4 (5) | −5.6; (−9.08, −2.12)^3^ | P value between-group:; Discharge; 0.0001
Weight | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Discharge | Weight (kg) | 126 | 70.7 (3) | −5.6; (−9.08, −2.12)^3^ | P value between-group:; Discharge; 0.0001
Weight | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Baseline-Discharge | Weight change from baseline to discharge | 122 | −11.4 (1.43)^16^ | NMD; −5.6; (−5.96, −5.23) | <0.001
Weight | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Baseline-Discharge | Weight change from baseline to discharge | 126 | −5.8 (1.45)^16^ | NMD; −5.6; (−5.96, −5.23) | <0.001
Weight | Yayla, 2015, 26135463 | Furosemide with HSS | 150 mL HSS (1.95% NaCl); once daily for 48 (h); Sodium Diet NR; Total Na 1.15 g/d^5^ | NR | Baseline-Discharge | Weight change from baseline to discharge | 14 | −5.7 (3.6) | NMD; (HSS vs bIV)^17^; (Baseline-Discharge); −1.6; (−3.96, 0.76) | 0.66
Weight | Yayla, 2015, 26135463 | Furosemide (continuous) cIV without HSS | Sodium Diet NR | NR | Baseline-Discharge | Weight change from baseline to discharge | 15 | −4.6 (5.2) | NMD; (HSS vs bIV)^17^; (Baseline-Discharge); −1.6; (−3.96, 0.76) | 0.66
Weight | Yayla, 2015, 26135463 | Furosemide (bolus) bIV | Sodium Diet NR | NR | Baseline-Discharge | Weight change from baseline to discharge | 14 | −4.1 (2.7) | NMD; (HSS vs bIV)^17^; (Baseline-Discharge); −1.6; (−3.96, 0.76) | 0.66
Weight | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d | 1000 mL/d | Baseline | Weight (kg) | 66 | 75.8 (15) | - | NS
Weight | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | Baseline | Weight (kg) | 67 | 76.0 (16) | - | NS
Weight | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d | 1000 mL/d | 6 (d) | Weight (kg) | 66 | 64.8 (5) | −3.2; (−6.1, −0.30); NMD; (Baseline-6 d); −3; (−7.66, 1.66) | P value between-group; at discharge; <0.033
Weight | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | 6 (d) | Weight (kg) | 67 | 68.0 (11) | −3.2; (−6.1, −0.30); NMD; (Baseline-6 d); −3; (−7.66, 1.66) | P value between-group; at discharge; <0.033
Weight | Tuttolomondo, 2021, 34288546 | Furosemide with HSS | 150 mL of HSS (1.4–4.6% NaCl) twice daily for 6 days; 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 3.3-7 g/d^18^ | NR | Baseline | Weight (kg) | 68 | 82.9 (14.5) | - | <0.0005
Weight | Tuttolomondo, 2021, 34288546 | Furosemide without HSS | 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 1.61 g/d^18^ | NR | Baseline | Weight (kg) | 68 | 73.3 (13.8) | - | <0.0005
Weight | Tuttolomondo, 2021, 34288546 | Furosemide with HSS | 150 mL of HSS (1.4–4.6% NaCl) twice daily for 6 days; 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 3.3-7 g/d^18^ | NR | 6 (d) | Weight (kg) | 68 | 67.50 (5.32) | −2.19; (−3.78, −0.59); NMD; (Baseline-6 d); −11.79; (−15.99, −7.59) | NR
Weight | Tuttolomondo, 2021, 34288546 | Furosemide without HSS | 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 1.61 g/d^18^ | NR | 6 (d) | Weight (kg) | 68 | 69.69 (4.08) | −2.19; (−3.78, −0.59); NMD; (Baseline-6 d); −11.79; (−15.99, −7.59) | NR
Weight | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | 24 h | Weight (kg) change from baseline to 24 h, median (IQR) | 22 | −1.1; (0.725, 1.475) | Net Median Difference; −0.71 | P value (Net Median Difference); 0.05
Weight | Okuhara, 2014, 24462960 | Furosemide with Glucose (5%) | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | 24 h | Weight (kg) change from baseline to 24 h, median (IQR) | 22 | −0.39; (−0.05, 1.20) | Net Median Difference; −0.71 | P value (Net Median Difference); 0.05
Weight | Roul, 2017 | HSS | HSS (NaCl% NR); Sodium diet NR^19^ | NR^19^ | After intervention | Weight (kg) | 11 | 73 (NR) | −7 | <0.008
Weight | Roul, 2017 | without HSS | NR^19^ | NR^19^ | After intervention | Weight (kg) | 156 | 80 (NR) | −7 | <0.008
Weight | Montgomery, 2023, 37044281 | Furosemide With Oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | 4 (d) | Weight change from enrollment to day 4, (kg) | 34 | −4.0 (4.3) | Cohen d^α^; 0.14 (−0.35, 0.63); NMD; 0.6; (−1.468, 2.668) | 0.57
Weight | Montgomery, 2023, 37044281 | Furosemide without Oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | 4 (d) | Weight change from enrollment to day 4, (kg) | 31 | −4.6 (4.2) | Cohen d^α^; 0.14 (−0.35, 0.63); NMD; 0.6; (−1.468, 2.668) | 0.57
Weight | Montgomery, 2023, 37044281 | Furosemide With Oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | Discharge | Weight change from enrollment to discharge, (kg) | 34 | −6.3 (6.4) | Cohen d^α^; 0.22; (−0.30, 0.74); NMD; 1.4; (−1.845, 4.645) | 0.41
Weight | Montgomery, 2023, 37044281 | Furosemide without Oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | Discharge | Weight change from enrollment to discharge, (kg) | 31 | −7.7 (6.9) | Cohen d^α^; 0.22; (−0.30, 0.74); NMD; 1.4; (−1.845, 4.645) | 0.41
Kidney Function | Kidney function (Creatinine, mg/dL)
Kidney Function | Diet (g/d Na)
Kidney Function | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | Baseline | Serum creatinine (mg/dL) | 38 | 1.3 (0.5) | - | 0.86
Kidney Function | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | Baseline | Serum creatinine (mg/dL) | 37 | 1.3 (0.6) | - | 0.86
Kidney Function | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | 7d | Serum creatinine (mg/dL) | 38 | 1.3 (0.5) | 0.1; (−0.08, 0.28); NMD; (Baseline-7 d); 0.1; (−0.22, 0.42)^3^ | P group * time (baseline − day 7) 0.44^20^; P group * time (baseline-discharge) 0.55^21^
Kidney Function | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | 7d | Serum creatinine (mg/dL) | 37 | 1.2 (0.3) | 0.1; (−0.08, 0.28); NMD; (Baseline-7 d); 0.1; (−0.22, 0.42)^3^ | P group * time (baseline − day 7) 0.44^20^; P group * time (baseline-discharge) 0.55^21^
Kidney Function | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | Serum creatinine (mg/dL) | 16 | 1.5 (0.5) | - | NR
Kidney Function | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | Serum creatinine (mg/dL) | 15 | 1.5 (0.5) | - | NR
Kidney Function | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Serum creatinine (mg/dL) | 16 | 1.7 (0.5) | 0 (−0.35, 0.35); NMD; (Baseline-7 d); 0 (−0.36, 0.36) | NR
Kidney Function | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Serum creatinine (mg/dL) | 15 | 1.7 (0.5) | 0 (−0.35, 0.35); NMD; (Baseline-7 d); 0 (−0.36, 0.36) | NR
Kidney Function | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | Baseline | Serum creatinine (mg/dL) | 30 | 1.0 (0.3) | - | NR
Kidney Function | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | Baseline | Serum creatinine (mg/dL) | 23 | 1.2 (0.4) | - | NR
Kidney Function | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | 7 (d)^#^ | Serum creatinine (mg/dL) | 30 | 1.2 (0.7) | −0.1; (−0.44, 0.24); NMD; (Baseline-7 d); 0.1; (−0.01, 0.30)^3^ | P group * time (baseline - ≤ 7 days) 0.32^21^
Kidney Function | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | 7 (d)^#^ | Serum creatinine (mg/dL) | 23 | 1.3 (0.5) | −0.1; (−0.44, 0.24); NMD; (Baseline-7 d); 0.1; (−0.01, 0.30)^3^ | P group * time (baseline - ≤ 7 days) 0.32^21^
Kidney Function | HSS (% NaCl)
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | Baseline | Serum creatinine (mg/dL) | 20 | 1.72 (0.47) | - | P group * time interaction 0.004
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | Baseline | Serum creatinine (mg/dL) | 12 | 1.58 (0.48) | - | P group * time interaction 0.004
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 1 (d) | Serum creatinine (mg/dL) | 20 | 1.71 (0.44) | - | P group * time interaction 0.004
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 1 (d) | Serum creatinine (mg/dL) | 12 | 1.81 (1.01) | - | P group * time interaction 0.004
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 2(d) | Serum creatinine (mg/dL) | 20 | 1.65 (0.44) | - | P group * time interaction 0.004
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 2(d) | Serum creatinine (mg/dL) | 12 | 1.96 (1.06) | - | P group * time interaction 0.004
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 3 (d) | Serum creatinine (mg/dL) | 20 | 1.66 (0.55) | −0.23; (−0.72, 0.26); NMD; (Baseline-3 d); −0.37; (−0.81, 0.07) | P group * time interaction 0.004
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 3 (d) | Serum creatinine (mg/dL) | 12 | 1.89 (0.77) | −0.23; (−0.72, 0.26); NMD; (Baseline-3 d); −0.37; (−0.81, 0.07) | P group * time interaction 0.004
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Serum creatinine (mg/dL) | 20 | 1.88 (0.68) | −0.02; (−0.54, 0.50); NMD; (Baseline-3 d) | P group * time interaction 0.004
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Serum creatinine (mg/dL) | 12 | 1.90 (0.76) | −0.02; (−0.54, 0.50); NMD; (Baseline-3 d) | P group * time interaction 0.004
Kidney Function | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Serum creatinine (mg/dl) | 48 | 1.51 (0.1) | - | NR
Kidney Function | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | Baseline | Serum creatinine (mg/dl) | 46 | 1.55 (0.05) | - | NR
Kidney Function | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | 6 (d) | Serum creatinine (mg/dl) | 48 | 1.45 (0.05) | −0.53; (−0.59, −0.47); NMD; (Baseline-6 d); −0.49; (−0.55, −0.43) | P value between- group:; At 6 days; <0.0001
Kidney Function | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | 6 (d) | Serum creatinine (mg/dl) | 46 | 1.98 (0.2) | −0.53; (−0.59, −0.47); NMD; (Baseline-6 d); −0.49; (−0.55, −0.43) | P value between- group:; At 6 days; <0.0001
Kidney Function | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Serum creatinine (mg/dl) | 48 | 1.55 (0.05) | −0.42; (−0.48, −0.36); NMD; (Baseline-Discharge); −0.42; (−0.48, −0.36) | <0.001
Kidney Function | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | Discharge | Serum creatinine (mg/dl) | 46 | 1.97 (0.2) | −0.42; (−0.48, −0.36); NMD; (Baseline-Discharge); −0.42; (−0.48, −0.36) | <0.001
Kidney Function | Mahjoob, 2021, 34903983 | Furosemide with HSS | 150 mL (5% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na 5.9=~6 g/d^5^ | NR | Baseline | Serum creatinine (mg/dL) | 14 | 1.68 (0.81) | - | 0.19^11^
Kidney Function | Mahjoob, 2021, 34903983 | Furosemide without HSS | 150 mL (0.9% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na ~1.1 g/d^5^ | NR | Baseline | Serum creatinine (mg/dL) | 14 | 2.36 (1.22) | - | 0.19^11^
Kidney Function | Mahjoob, 2021, 34903983 | Furosemide with HSS | 150 mL (5% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na 5.9=~6 g/d^5^ | NR | 3 (d) | Serum creatinine (mg/dL) | 14 | 1.74 (0.75) | −0.82; (−1.64, 0.21)^3^; NMD; (Baseline-3 d); −0.14; (−0.93, 0.65) | 0.12^11^
Kidney Function | Mahjoob, 2021, 34903983 | Furosemide without HSS | 150 mL (0.9% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na ~1.1 g/d^5^ | NR | 3 (d) | Serum creatinine (mg/dL) | 14 | 2.56 (1.38) | −0.82; (−1.64, 0.21)^3^; NMD; (Baseline-3 d); −0.14; (−0.93, 0.65) | 0.12^11^
Kidney Function | Licata, 2003, 12660669 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily for 6 to 12 ds; Normal sodium diet 2.76 g/d= ~2.8 g/d Na; Total Na= ~4.5-8.2 g/d | 1000 mL/d | Baseline | Serum creatinine (mg/dL) | 53 | 1.6 (0.05) | - | NR
Kidney Function | Licata, 2003, 12660669 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for; 6 to 12 days; Total Na 1.8 g/d | 1000 mL/d | Baseline | Serum creatinine (mg/dL) | 54 | 1.65 (0.05) | - | NR
Kidney Function | Licata, 2003, 12660669 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily for 6 to 12 ds; Normal sodium diet 2.76 g/d= ~2.8 g/d Na; Total Na= ~4.5-8.2 g/d | 1000 mL/d | Discharge | Serum creatinine (mg/dL) | 53 | 1.4 (0.05) | −0.55; (−0.58, −0.52); NMD; (Baseline-Discharge); −0.5; (−0.53, −0.47) | P value between groups:; (Discharge); <0.001
Kidney Function | Licata, 2003, 12660669 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for; 6 to 12 days; Total Na 1.8 g/d | 1000 mL/d | Discharge | Serum creatinine (mg/dL) | 54 | 1.95 (0.1) | −0.55; (−0.58, −0.52); NMD; (Baseline-Discharge); −0.5; (−0.53, −0.47) | P value between groups:; (Discharge); <0.001
Kidney Function | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Serum creatinine (mg/dL) | 30 | 1.6 (0.05) | - | NR
Kidney Function | Paterna, 2000, 10938493 | Furosemide without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | Baseline | Serum creatinine (mg/dL) | 30 | 1.65 (0.07) | - | NR
Kidney Function | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Serum creatinine (mg/dL) | 30 | 1.4 (0.07) | −0.54; (−0.58, −0.49); NMD; (Baseline-Discharge); −0.49; (−0.53, −0.45) | P value between-group; at discharge; <0.001
Kidney Function | Paterna, 2000, 10938493 | Furosemide without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | Discharge | Serum creatinine (mg/dL) | 30 | 1.94 (0.1) | −0.54; (−0.58, −0.49); NMD; (Baseline-Discharge); −0.49; (−0.53, −0.45) | P value between-group; at discharge; <0.001
Kidney Function | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Serum creatinine (mg/dL) | 953 | 1.65 (0.05) | - | NR
Kidney Function | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Baseline | Serum creatinine (mg/dL) | 974 | 1.61 (0.05) | - | NR
Kidney Function | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Serum creatinine (mg/dL) | 953 | 1.45 (0.05) | −0.46; (−0.47, −0.45); NMD; (Baseline-Discharge); −0.5; (−0.51, −0.49) | NR
Kidney Function | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Discharge | Serum creatinine (mg/dL) | 974 | 1.91 (0.1) | −0.46; (−0.47, −0.45); NMD; (Baseline-Discharge); −0.5; (−0.51, −0.49) | NR
Kidney Function | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Baseline | Serum creatinine (mg/dL) | 122 | 1.22 (0.4) | - | 0.53
Kidney Function | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Baseline | Serum creatinine (mg/dL) | 126 | 1.18 (0.6) | - | 0.53
Kidney Function | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Discharge | Serum creatinine (mg/dL) | 122 | 1.28 (0.48) | −0.32; (−0.48, −0.16); NMD; (Baseline-Discharge); −0.36; (−0.48, −0.24) | P value between-group; At Discharge; 0.0001
Kidney Function | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Discharge | Serum creatinine (mg/dL) | 126 | 1.6 (0.32) | −0.32; (−0.48, −0.16); NMD; (Baseline-Discharge); −0.36; (−0.48, −0.24) | P value between-group; At Discharge; 0.0001
Kidney Function | Yayla, 2015, 26135463 | Furosemide with HSS | 150 mL HSS (1.95% NaCl); once daily for 48 (h); Sodium Diet NR; Total Na 1.15 g/d^5^ | NR | Baseline | Serum creatinine (mg/dL) | 14 | 0.96 (0.29) | - | P values between-group; 0.27
Kidney Function | Yayla, 2015, 26135463 | Furosemide (continuous) cIV without HSS | Sodium Diet NR | NR | Baseline | Serum creatinine (mg/dL) | 15 | 1.10 (0.26) | - | P values between-group; 0.27
Kidney Function | Yayla, 2015, 26135463 | Furosemide (bolus) bIV without HSS | Sodium Diet NR | NR | Baseline | Serum creatinine (mg/dL) | 14 | 0.93 (0.32) | - | P values between-group; 0.27
Kidney Function | Yayla, 2015, 26135463 | Furosemide with HSS | 150 mL HSS (1.95% NaCl); once daily for 48 (h); Sodium Diet NR; Total Na 1.15 g/d^5^ | NR | 48 (h) | Serum creatinine (mg/dL) | 14 | 1.17 (0.32) | 0.2; (−0.12, 0.52)^3^; NMD; (HSS vs bIV)^17^; 0.17; (−0.05, 0.39) | P values between-group; 0.04; HSS vs bIV; 0.22
Kidney Function | Yayla, 2015, 26135463 | Furosemide (continuous) cIV without HSS | Sodium Diet NR | NR | 48 (h) | Serum creatinine (mg/dL) | 15 | 1.27 (0.31) | 0.2; (−0.12, 0.52)^3^; NMD; (HSS vs bIV)^17^; 0.17; (−0.05, 0.39) | P values between-group; 0.04; HSS vs bIV; 0.22
Kidney Function | Yayla, 2015, 26135463 | Furosemide (bolus) bIV without HSS | Sodium Diet NR | NR | 48 (h) | Serum creatinine (mg/dL) | 14 | 0.97 (0.27) | 0.2; (−0.12, 0.52)^3^; NMD; (HSS vs bIV)^17^; 0.17; (−0.05, 0.39) | P values between-group; 0.04; HSS vs bIV; 0.22
Kidney Function | Yayla, 2015, 26135463 | Furosemide with HSS | 150 mL HSS (1.95% NaCl); once daily for 48 (h); Sodium Diet NR; Total Na 1.15 g/d^5^ | NR | Baseline-compensated | Serum creatinine (mg/dL) | 14 | 1.27 (0.49) | NMD; (HSS vs bIV)^17^; (Baseline-compensation); 0.24; (−0.09, 0.57) | 0.09
Kidney Function | Yayla, 2015, 26135463 | Furosemide (continuous) cIV without HSS | Sodium Diet NR | NR | Baseline-compensated | Serum creatinine (mg/dL) | 15 | 1.46 (0.60) | NMD; (HSS vs bIV)^17^; (Baseline-compensation); 0.24; (−0.09, 0.57) | 0.09
Kidney Function | Yayla, 2015, 26135463 | Furosemide (bolus) bIV without HSS | Sodium Diet NR | NR | Baseline-compensated | Serum creatinine (mg/dL) | 14 | 1.03 (0.40) | NMD; (HSS vs bIV)^17^; (Baseline-compensation); 0.24; (−0.09, 0.57) | 0.09
Kidney Function | Yayla, 2015, 26135463 | Furosemide with HSS | 150 mL HSS (1.95% NaCl); once daily for 48 (h); Sodium Diet NR; Total Na 1.15 g/d^5^ | NR | Baseline-48 (h) | Change in serum creatinine from baseline to 48 hours. | 14 | 0.20 (0.21) | NMD; HSS vs bIV^17^; (Baseline-48 h); 0.16; (0.03, 0.30) | 0.08
Kidney Function | Yayla, 2015, 26135463 | Furosemide (continuous) cIV without HSS | Sodium Diet NR | NR | Baseline-48 (h) | Change in serum creatinine from baseline to 48 hours. | 15 | 0.16 (0.21) | NMD; HSS vs bIV^17^; (Baseline-48 h); 0.16; (0.03, 0.30) | 0.08
Kidney Function | Yayla, 2015, 26135463 | Furosemide (bolus) bIV without HSS | Sodium Diet NR | NR | Baseline-48 (h) | Change in serum creatinine from baseline to 48 hours. | 14 | 0.04 (0.15) | NMD; HSS vs bIV^17^; (Baseline-48 h); 0.16; (0.03, 0.30) | 0.08
Kidney Function | Yayla, 2015, 26135463 | Furosemide with HSS | 150 mL HSS (1.95% NaCl); once daily for 48 (h); Sodium Diet NR; Total Na 1.15 g/d^5^ | NR | Baseline-Compensation | Change in serum creatinine from baseline to compensation | 14 | 0.30 (0.42) | NMD; HSS vs bIV^17^; (Baseline-compensation); 0.2; (−0.06, 0.46) | 0.18
Kidney Function | Yayla, 2015, 26135463 | Furosemide (continuous) cIV without HSS | Sodium Diet NR | NR | Baseline-Compensation | Change in serum creatinine from baseline to compensation | 15 | 0.36 (0.42) | NMD; HSS vs bIV^17^; (Baseline-compensation); 0.2; (−0.06, 0.46) | 0.18
Kidney Function | Yayla, 2015, 26135463 | Furosemide (bolus) bIV without HSS | Sodium Diet NR | NR | Baseline-Compensation | Change in serum creatinine from baseline to compensation | 14 | 0.10 (0.28) | NMD; HSS vs bIV^17^; (Baseline-compensation); 0.2; (−0.06, 0.46) | 0.18
Kidney Function | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d | 1000 mL/d | Baseline | Serum creatinine (mg/dL) | 66 | 1.5 (0.3) | -- | NS
Kidney Function | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | Baseline | Serum creatinine (mg/dL) | 67 | 1.4 (0.5) | -- | NS
Kidney Function | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d | 1000 mL/d | 6 (d) | Serum creatinine (mg/dL) | 66 | 1.1 (0.3) | −0.7; (−0.80, −0.59); NMD; (Baseline-6 d); −0.8; (−0.93, −0.67) | <0.0001
Kidney Function | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | 6 (d) | Serum creatinine (mg/dL) | 67 | 1.8 (0.3) | −0.7; (−0.80, −0.59); NMD; (Baseline-6 d); −0.8; (−0.93, −0.67) | <0.0001
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | Baseline | Serum creatinine (mg/dL) | 22 | 1.56 (0.85) | - | NR
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with Glucose (5%) | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | Baseline | Serum creatinine (mg/dL) | 22 | 1.45 (0.77) | - | NR
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | 24 (h) | Serum creatinine (mg/dL) at 24 hours (end of intervention) | 22 | 1.55 (0.75) | 0.02; (−0.45, 0.49); NMD; (Baseline-24 h); −0.09; (−0.56, 0.38) | NR
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with Glucose (5%) | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | 24 (h) | Serum creatinine (mg/dL) at 24 hours (end of intervention) | 22 | 1.53 (0.81) | 0.02; (−0.45, 0.49); NMD; (Baseline-24 h); −0.09; (−0.56, 0.38) | NR
Kidney Function | Montgomery, 2023, 37044281 | Furosemide With Oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | 4 (d) | Serum creatinine change from enrollment to day 4, mg/dL (units determined from clinical trial.gov and baseline table) | 34 | 0.04 (0.39) | Cohen d^α^; −0.26; (−0.75, 0.23); NMD; −0.11; (−0.313, 0.093), | 0.30
Kidney Function | Montgomery, 2023, 37044281 | Furosemide without Oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | 4 (d) | Serum creatinine change from enrollment to day 4, mg/dL (units determined from clinical trial.gov and baseline table) | 31 | 0.15 (0.44) | Cohen d^α^; −0.26; (−0.75, 0.23); NMD; −0.11; (−0.313, 0.093), | 0.30
Kidney Function | Montgomery, 2023, 37044281 | Furosemide With Oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | Discharge | Serum creatinine change from enrollment to discharge, mg/dL | 34 | −0.04 (0.51) | Cohen d^α^; −0.41; (−0.91, 0.09); NMD; −0.22; (−0.479, 0.039), | 0.11
Kidney Function | Montgomery, 2023, 37044281 | Furosemide without Oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | Discharge | Serum creatinine change from enrollment to discharge, mg/dL | 31 | 0.18 (0.55) | Cohen d^α^; −0.41; (−0.91, 0.09); NMD; −0.22; (−0.479, 0.039), | 0.11
Kidney Function | Kidney Function (Urea, mg/dL)
Kidney Function | Diet (g/d Na)
Kidney Function | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | Baseline | Urea, median (IQR) | 38 | 56 (48, 87) | - | P value between-group; Baseline; 0.38; 7 (d); 0.06; group * time; 0.32
Kidney Function | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | Baseline | Urea, median (IQR) | 37 | 58 (41, 83) | - | P value between-group; Baseline; 0.38; 7 (d); 0.06; group * time; 0.32
Kidney Function | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | 7 (d) | Urea, median (IQR) | 38 | 59 (43, 88) | Median Difference; 10; Net Median Difference; (Baseline-7 d); 12 | P value between-group; Baseline; 0.38; 7 (d); 0.06; group * time; 0.32
Kidney Function | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | 7 (d) | Urea, median (IQR) | 37 | 49 (42, 71) | Median Difference; 10; Net Median Difference; (Baseline-7 d); 12 | P value between-group; Baseline; 0.38; 7 (d); 0.06; group * time; 0.32
Kidney Function | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | Baseline | Urea, mg/dL | 30 | 51(19) | - | NR
Kidney Function | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | Baseline | Urea, mg/dL | 23 | 54 (21) | - | NR
Kidney Function | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | ≤7 (d) | Urea, mg/dL, | 30 | 60 (33) | 5; (−10.8, 20.8); NMD; (Baseline-study end); 8; (−1.8, 17.8)^3^ | P group * time; (Baseline-study end); 0.11^21^
Kidney Function | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | ≤7 (d) | Urea, mg/dL, | 23 | 55 (21) | 5; (−10.8, 20.8); NMD; (Baseline-study end); 8; (−1.8, 17.8)^3^ | P group * time; (Baseline-study end); 0.11^21^
Kidney Function | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | Urea, mg/dL | 16 | 68.4 (40.2) | - | NR
Kidney Function | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | Urea, mg/dL | 15 | 66.6 (30.2) | - | NR
Kidney Function | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Urea, mg/dL | 16 | 76.9 (36.6) | 4; (−19.3, 27.3); NMD; (Baseline-7 d); 2.2; (−21.6, 26.0) | NR
Kidney Function | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Urea, mg/dL | 15 | 72.9 (27.2) | 4; (−19.3, 27.3); NMD; (Baseline-7 d); 2.2; (−21.6, 26.0) | NR
Kidney Function | HSS (% NaCl)
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | Baseline | Urea, mg/dL | 20 | 80.8 (35.6) | - | P group * time interaction; 0.66
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | Baseline | Urea, mg/dL | 12 | 83.7 (43.6) | - | P group * time interaction; 0.66
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 1 (d) | Urea, mg/dL | 20 | 78.6 (33.3) | - | P group * time interaction; 0.66
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 1 (d) | Urea, mg/dL | 12 | 82.7 (43.6) | - | P group * time interaction; 0.66
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 2 (d) | Urea, mg/dL | 20 | 77.6 (32.8) | - | P group * time interaction; 0.66
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 2 (d) | Urea, mg/dL | 12 | 85.9 (46.5) | - | P group * time interaction; 0.66
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 3 (d) | Urea, mg/dL | 20 | 77.0 (38.6) | −8.7; (−37.8, 20.5); NMD; (Baseline-3 d); −5.8; (−35.00, 23.40) | P group * time interaction; 0.66
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 3 (d) | Urea, mg/dL | 12 | 85.7 (42.0) | −8.7; (−37.8, 20.5); NMD; (Baseline-3 d); −5.8; (−35.00, 23.40) | P group * time interaction; 0.66
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Urea, mg/dL | 20 | 83.2 (45.2) | −3.3; (−34.4, 27.8); NMD | P group * time interaction; 0.66
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Urea, mg/dL | 12 | 86.5 (42.3) | −3.3; (−34.4, 27.8); NMD | P group * time interaction; 0.66
Kidney Function | Licata, 2003, 12660669 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily for 6 to 12 ds; Normal sodium diet 2.76 g/d= ~2.8 g/d Na; Total Na= ~4.5-8.2 g/d | 1000 mL/d | Baseline | Urea, mg/dL | 53 | 62 (4) | -
Kidney Function | Licata, 2003, 12660669 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for; 6 to 12 days; Total Na 1.8 g/d | 1000 mL/d | Baseline | Urea, mg/dL | 54 | 58.2 (3.5) | -
Kidney Function | Licata, 2003, 12660669 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily for 6 to 12 ds; Normal sodium diet 2.76 g/d= ~2.8 g/d Na; Total Na= ~4.5-8.2 g/d | 1000 mL/d | Discharge | Urea, mg/dL | 53 | 70 (9.5) | −27; (−31.3, −22.7); NMD; (Baseline-Discharge); −30.8; (−34.62, −26.98) | P value between- group:; At Discharge; <0.001
Kidney Function | Licata, 2003, 12660669 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for; 6 to 12 days; Total Na 1.8 g/d | 1000 mL/d | Discharge | Urea, mg/dL | 54 | 97 (13) | −27; (−31.3, −22.7); NMD; (Baseline-Discharge); −30.8; (−34.62, −26.98) | P value between- group:; At Discharge; <0.001
Kidney Function | Mahjoob, 2021, 34903983 | Furosemide with HSS | 150 mL (5% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na 5.9=~6 g/d^5^ | NR | Baseline | Urea, mg/dL | 14 | 76.21 (52.28) | - | 0.3^12^
Kidney Function | Mahjoob, 2021, 34903983 | Furosemide without HSS | 150 mL (0.9% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na ~1.1 g/d^5^ | NR | Baseline | Urea, mg/dL | 14 | 101.32 (72.04) | - | 0.3^12^
Kidney Function | Mahjoob, 2021, 34903983 | Furosemide with HSS | 150 mL (5% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na 5.9=~6 g/d^5^ | NR | 3 (d) | Urea, mg/dL | 14 | 138.86 (2.35) | 25.1; (−15.2, 65.4); NMD; (Baseline-3 d); 50.2; (3.54, 96.90) | P value between group at day 3; 0.31^11^
Kidney Function | Mahjoob, 2021, 34903983 | Furosemide without HSS | 150 mL (0.9% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na ~1.1 g/d^5^ | NR | 3 (d) | Urea, mg/dL | 14 | 113.75 (73.91) | 25.1; (−15.2, 65.4); NMD; (Baseline-3 d); 50.2; (3.54, 96.90) | P value between group at day 3; 0.31^11^
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) for 24 (h); Restricted sodium to 2.4 g/d Na; Total Na 5.7=~6 g/d | 500 mL/d | Baseline | Urea, mg/dL | 22 | 32.33 (21.26) | - | NR
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with Glucose (5%) | 500 mL/d 5% glucose; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | Baseline | Urea, mg/dL | 22 | 29.76 (15.37) | - | NR
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | 24 (h) | Urea, mg/dL | 22 | 30.86 (20.03) | 2.43; (−8.60, 13.5); NMD; (Baseline-24 h); −0.14; (−10.93, 10.65) | NR
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with Glucose (5%) | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | 24 (h) | Urea, mg/dL | 22 | 28.43 (15.58) | 2.43; (−8.60, 13.5); NMD; (Baseline-24 h); −0.14; (−10.93, 10.65) | NR
Kidney Function | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d | 1000 mL/d | Baseline | Urea, mg/dL | 66 | 62 (4) | - | NS
Kidney Function | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | Baseline | Urea, mg/dL | 67 | 59 (4) | - | NS
Kidney Function | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d | 1000 mL/d | 6 (d) | Urea, mg/dL | 66 | 52 (4) | −41; (−43.0, −38.9); NMD; (Baseline-6 d); −44; (−45.75, −42.25) | <0.0001
Kidney Function | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | 6 (d) | Urea, mg/dL | 67 | 93 (7) | −41; (−43.0, −38.9); NMD; (Baseline-6 d); −44; (−45.75, −42.25) | <0.0001
Kidney Function | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Baseline | Urea, mg/dL | 122 | 67.7 (32.0) | - | 0.48
Kidney Function | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Baseline | Urea, mg/dL | 126 | 65 (28) | - | 0.48
Kidney Function | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Discharge | Urea, mg/dL | 122 | 78.1 (32.4) | −28.9; (−36.0, −21.8); NMD; (Baseline-Discharge); −31.6; (−38.92, −24.28) | P value between-group; Discharge; 0.0001
Kidney Function | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Discharge | Urea, mg/dL | 126 | 107 (24) | −28.9; (−36.0, −21.8); NMD; (Baseline-Discharge); −31.6; (−38.92, −24.28) | P value between-group; Discharge; 0.0001
Kidney Function | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Urea, mg/dL | 30 | 62.1 (4.1) | - | -
Kidney Function | Paterna, 2000, 10938493 | Furosemide without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | Baseline | Urea, mg/dL | 30 | 58.1 (3.7) | - | -
Kidney Function | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Urea, mg/dL | 30 | 70 (9.5) | −27; (−32.91, −21.09); NMD; (Baseline-Discharge); −31; (−36.24, −25.76) | <0.001
Kidney Function | Paterna, 2000, 10938493 | Furosemide without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | Discharge | Urea, mg/dL | 30 | 97 (13.5) | −27; (−32.91, −21.09); NMD; (Baseline-Discharge); −31; (−36.24, −25.76) | <0.001
Kidney Function | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Urea, mg/dL | 48 | 62 (4) | - | NR
Kidney Function | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | Baseline | Urea, mg/dL | 46 | 56.1 (3.5) | - | NR
Kidney Function | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | 6 (d) | Urea, mg/dL | 48 | 64 (9.5) | −35; (−39.1, −30.8); NMD; (Baseline-6 d); −40.9; (−44.56, −37.24) | P value between-group:; At 6 days; <0.0001
Kidney Function | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | 6 (d) | Urea, mg/dL | 46 | 99 (11) | −35; (−39.1, −30.8); NMD; (Baseline-6 d); −40.9; (−44.56, −37.24) | P value between-group:; At 6 days; <0.0001
Kidney Function | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Urea, mg/dL | 48 | 65 (10) | −33; (−37.5, −28.5); NMD; (Baseline-Discharge); −38.9; (−42.9, −34.9) | P value between-group:; At discharge; <0.0001
Kidney Function | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | Discharge | Urea, mg/dL | 46 | 98 (12) | −33; (−37.5, −28.5); NMD; (Baseline-Discharge); −38.9; (−42.9, −34.9) | P value between-group:; At discharge; <0.0001
Kidney Function | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Urea, mg/dL | 953 | 58.2 (3.5) | - | NR
Kidney Function | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Baseline | Urea, mg/dL | 974 | 56 (4) | - | NR
Kidney Function | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Urea, mg/dL | 953 | 71 (13) | −30; (−31.1, −28.9); NMD; (Baseline-Discharge); −32.2; (−33.19, −31.21) | P value between groups; <0.0001
Kidney Function | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Discharge | Urea, mg/dL | 974 | 101 (12) | −30; (−31.1, −28.9); NMD; (Baseline-Discharge); −32.2; (−33.19, −31.21) | P value between groups; <0.0001
Kidney Function | Wan, 2017, 28701670 | Furosemide with compound HSS | 100 mL c-HSS^8^ (2.8% NaCl) twice daily until clinical compensation^9^; Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Baseline | Urea, mg/dL | 132 | 56.1 (2.3) | - | NR
Kidney Function | Wan, 2017, 28701670 | Furosemide without compound HSS | Normal sodium diet 2.76 g/d; until clinical compensation^9^; Total Na ~2.8 g/d | < 500 mL/d | Baseline | Urea, mg/dL | 132 | 54.5 (4.7) | - | NR
Kidney Function | Wan, 2017, 28701670 | Furosemide with compound HSS | 100 mL c-HSS^8^ (2.8% NaCl) twice daily until clinical compensation^9^; Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Discharge | Urea, mg/dL | 132 | 50.4 (6.4) | 0.2; (−1.34, 1.74); NMD; (Baseline-Discharge); −1.4; (−2.77, −0.03) | NR
Kidney Function | Wan, 2017, 28701670 | Furosemide without compound HSS | Normal sodium diet 2.76 g/d; until clinical compensation^9^; Total Na ~2.8 g/d | < 500 mL/d | Discharge | Urea, mg/dL | 132 | 50.2 (6.4) | 0.2; (−1.34, 1.74); NMD; (Baseline-Discharge); −1.4; (−2.77, −0.03) | NR
Kidney Function | Yayla, 2015, 26135463 | Furosemide with HSS | 150 mL HSS (1.95% NaCl); once daily for 48 (h); Sodium Diet NR; Total Na 1.15 g/d^5^ | NR | Baseline-to-compensation | Uea, mg/dL | 14 | 37.9 (16.8) | NMD; HSS vs bIV^17^; (Baseline-compensation); 3.8; (−9.37, 16.97) | 0.72
Kidney Function | Yayla, 2015, 26135463 | Furosemide (continuous) cIV without HSS | Sodium Diet NR | NR | Baseline-to-compensation | Uea, mg/dL | 15 | 38.8 (15.3) | NMD; HSS vs bIV^17^; (Baseline-compensation); 3.8; (−9.37, 16.97) | 0.72
Kidney Function | Yayla, 2015, 26135463 | Furosemide (bolus) bIV without HSS | Sodium Diet NR | NR | Baseline-to-compensation | Uea, mg/dL | 14 | 34.1 (18.7) | NMD; HSS vs bIV^17^; (Baseline-compensation); 3.8; (−9.37, 16.97) | 0.72
Kidney Function | Montgomery, 2023, 37044281 | Furosemide With Oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | 4 (d) | Urea change from enrollment to day 4, mEq/L, mg/dL (1mg/dL= 0.357 mEq/L) | 34 | 3.1 (13), 8.68 (36.41)^2^ | Cohen d^α^; −0.57; (−1.07, −0.07); NMD; −7.9; (−14.754, −1.046), −22.1 (−41.32, −2.93) | 0.025
Kidney Function | Montgomery, 2023, 37044281 | Furosemide without Oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | 4 (d) | Urea change from enrollment to day 4, mEq/L, mg/dL (1mg/dL= 0.357 mEq/L) | 31 | 11 (15); 30.81 (42.01)^2^ | Cohen d^α^; −0.57; (−1.07, −0.07); NMD; −7.9; (−14.754, −1.046), −22.1 (−41.32, −2.93) | 0.025
Kidney Function | Montgomery, 2023, 37044281 | Furosemide With Oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | Discharge | Urea change from enrollment to discharge, mEq/L, mg/dL (1mg/dL = 0.357 mEq/L) | 34 | 3.2 (15), 8.96 (42.02)^2^ | Cohen d^α^; −0.55; (−1.05, −0.05); NMD; −9.8; (−18.460, −1.140), −27.5 (−51.7, −3.19) | 0.036
Kidney Function | Montgomery, 2023, 37044281 | Furosemide without Oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | Discharge | Urea change from enrollment to discharge, mEq/L, mg/dL (1mg/dL = 0.357 mEq/L) | 31 | 13 (20), 36.42 (56.02)^2^ | Cohen d^α^; −0.55; (−1.05, −0.05); NMD; −9.8; (−18.460, −1.140), −27.5 (−51.7, −3.19) | 0.036
Kidney Function | Kidney Function (eGFR, mL/min or mL/min/1.73 m^2^)
Kidney Function | HSS
Kidney Function | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Creatinine clearance^##^, x (Unit: NR) | 953 | 52.5 (2.2) | - | NR
Kidney Function | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Baseline | Creatinine clearance^##^, x (Unit: NR) | 974 | 52.1 (2.3) | - | NR
Kidney Function | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Creatinine clearance^##^, x(Unit: NR) | 953 | 55.4 (3.3) | 6.7; (6.5, 6.9); NMD; (Baseline-Discharge); 6.3; (6.07, 6.53) | P value between groups:; Discharge; <0.0001
Kidney Function | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Discharge | Creatinine clearance^##^, x(Unit: NR) | 974 | 48.7 (2.1) | 6.7; (6.5, 6.9); NMD; (Baseline-Discharge); 6.3; (6.07, 6.53) | P value between groups:; Discharge; <0.0001
Kidney Function | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Baseline | MDRD GFR, mL/min/1.73 m^2^ | 122 | 58.8 (26.8) | - | 0.84
Kidney Function | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Baseline | MDRD GFR, mL/min/1.73 m^2^ | 126 | 59.4 (22.2) | - | 0.84
Kidney Function | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Discharge | MDRD GFR, mL/min/1.73 m^2^ | 122 | 59.1 (31.9) | 17.1; (11.06, 23.14); NMD; (Baseline-Discharge); 17.7; (11.45, 23.95) | P value between-group.; At discharge; 0.0001
Kidney Function | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Discharge | MDRD GFR, mL/min/1.73 m^2^ | 126 | 42 (12) | 17.1; (11.06, 23.14); NMD; (Baseline-Discharge); 17.7; (11.45, 23.95) | P value between-group.; At discharge; 0.0001
Kidney Function | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d | 1000 mL/d | Baseline | GFR, mL/min | 66 | 52 (8) | - | NS
Kidney Function | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | Baseline | GFR, mL/min | 67 | 51 (5) | - | NS
Kidney Function | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d | 1000 mL/d | 6 (d) | GFR, mL/min | 66 | 58 (6) | 14; (11.8, 16.2); NMD; (Baseline-6 d); 13; (10.71, 15.29) | <0.0001
Kidney Function | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | 6 (d) | GFR, mL/min | 67 | 44 (7) | 14; (11.8, 16.2); NMD; (Baseline-6 d); 13; (10.71, 15.29) | <0.0001
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | Baseline | GFR, mL min^−1^ 1.73 m^−2^ | 22 | 42.9 (22.6) | - | NR
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with Glucose (5%) | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | Baseline | GFR, mL min^−1^ 1.73 m^−2^ | 22 | 44.3 (25.6) | - | NR
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | 24 (h) | GFR, mL min^−1^ 1.73 m^−2^, | 22 | 43.1 (21.9) | 2; (−11.1, 15.1); NMD; (Baseline-24 h); 3.4; (−10.35, 17.15) | NR
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with Glucose (5%) | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | 24 (h) | GFR, mL min^−1^ 1.73 m^−2^, | 22 | 41.1 (22.5) | 2; (−11.1, 15.1); NMD; (Baseline-24 h); 3.4; (−10.35, 17.15) | NR
Kidney Function | Wan, 2017, 28701670 | Furosemide with compound HSS | 100 mL c-HSS^8^ (2.8% NaCl) twice daily until clinical compensation^9^; Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Baseline | Creatinine clearance^##^ | 132 | 56.5 (3.5) | - | -
Kidney Function | Wan, 2017, 28701670 | Furosemide without compound HSS | Normal sodium diet 2.76 g/d; until clinical compensation^9^; Total Na ~2.8 g/d | < 500 mL/d | Baseline | Creatinine clearance^##^ | 132 | 45.7 (2.4) | - | -
Kidney Function | Wan, 2017, 28701670 | Furosemide with compound HSS | 100 mL c-HSS^8^ (2.8% NaCl) twice daily until clinical compensation^9^; Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Discharge | Creatinine clearance^##^ | 132 | 53.8 (4.1) | MD; 9.6; (8.71, 10.49); NMD; (Baseline-Discharge); −1.2; (−2.02, −0.38) | -
Kidney Function | Wan, 2017, 28701670 | Furosemide without compound HSS | Normal sodium diet 2.76 g/d; until clinical compensation^9^; Total Na ~2.8 g/d | < 500 mL/d | Discharge | Creatinine clearance^##^ | 132 | 44.2 (3.2) | MD; 9.6; (8.71, 10.49); NMD; (Baseline-Discharge); −1.2; (−2.02, −0.38) | -
Kidney Function | Montgomery, 2023, 37044281 | Furosemide With Oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | 4 (d) | eGFR change from enrollment to day 4, mL/min/1.73 m^2^, median | 34 | 1.67 (−4.55, 4.11) | Rank Biserial^α^ (r_rb_); 0.17; (−0.11, 0.42); Net Median Difference; 4.5 | 0.25
Kidney Function | Montgomery, 2023, 37044281 | Furosemide without Oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | 4 (d) | eGFR change from enrollment to day 4, mL/min/1.73 m^2^, median | 31 | −2.83 (−7.45, 3.13) | Rank Biserial^α^ (r_rb_); 0.17; (−0.11, 0.42); Net Median Difference; 4.5 | 0.25
Kidney Function | Montgomery, 2023, 37044281 | Furosemide With Oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | Discharge | eGFR change from enrollment to discharge, mL/min/1.73 m^2^ | 34 | 1.4 (12) | Rank Biserial^α^ (r_rb_); 0.24; (−0.25, 0.73); NMD; 2.8; (−2.792, 8.392) | 0.34
Kidney Function | Montgomery, 2023, 37044281 | Furosemide without Oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | Discharge | eGFR change from enrollment to discharge, mL/min/1.73 m^2^ | 31 | −1.4 (11) | Rank Biserial^α^ (r_rb_); 0.24; (−0.25, 0.73); NMD; 2.8; (−2.792, 8.392) | 0.34
Kidney Function | Kidney Function (Serum Cystatin c, mg/L)
Kidney Function | HSS (% NaCl)
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | Baseline | Cystatin C, mg/L^###^ | 20 | 1.53 (0.40) | - | P group * time interaction; 0.03
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | Baseline | Cystatin C, mg/L^###^ | 12 | 1.45 (0.50) | - | P group * time interaction; 0.03
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 1 (d) | Cystatin C, mg/L^###^ | 20 | 1.49 (0.39) | - | P group * time interaction; 0.03
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 1 (d) | Cystatin C, mg/L^###^ | 12 | 1.73 (0.63) | - | P group * time interaction; 0.03
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 2 (d) | Cystatin C, mg/L^###^ | 20 | 1.43 (0.31) | - | P group * time interaction; 0.03
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 2 (d) | Cystatin C, mg/L^###^ | 12 | 1.65 (0.53) | - | P group * time interaction; 0.03
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 3 (d) | Cystatin C, mg/L^###^ | 20 | 1.47 (0.30) | −0.23; (−0.52, 0.06); NMD; (Baseline-3 d); −0.31; (−0.63, 0.01) | P group * time interaction; 0.03
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 3 (d) | Cystatin C, mg/L^###^ | 12 | 1.70 (0.46) | −0.23; (−0.52, 0.06); NMD; (Baseline-3 d); −0.31; (−0.63, 0.01) | P group * time interaction; 0.03
Kidney Function | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Cystatin C, mg/L^###^ | 20 | 1.63 (0.46) | −0.07; (−0.4, 0.3); NMD; −0.15; (−0.50, 0.20) | P group * time interaction; 0.03
Kidney Function | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Cystatin C, mg/L^###^ | 12 | 1.70 (0.55) | −0.07; (−0.4, 0.3); NMD; −0.15; (−0.50, 0.20) | P group * time interaction; 0.03
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | Baseline | Serum Cystatin C, mg/L | 22 | 2.04 (0.98) | - | NR
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with Glucose (5%) | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | Baseline | Serum Cystatin C, mg/L | 22 | 1.94 (0.90) | - | NR
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | 24 (h) | Serum Cystatin C, mg/L | 22 | 2.04 (0.92) | 0; (−0.54, 0.54); NMD; (Baseline-24 h); −0.1; (−0.65, 0.45) | NR
Kidney Function | Okuhara, 2014, 24462960 | Furosemide with Glucose (5%) | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | 24 (h) | Serum Cystatin C, mg/L | 22 | 2.04 (0.92) | 0; (−0.54, 0.54); NMD; (Baseline-24 h); −0.1; (−0.65, 0.45) | NR
Urine Output (mL/24h) | Diet (Na g/d)
Urine Output (mL/24h) | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | Baseline-7 d | Urine output (water loss), L^†^ | 16 | −4.3 (3.0) | NMD; (Baseline-7 d); 1.4; (−0.58, 3.38) | P value (NMD); 0.17
Urine Output (mL/24h) | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | Baseline-7 d | Urine output (water loss), L^†^ | 15 | −2.9 (2.1) | NMD; (Baseline-7 d); 1.4; (−0.58, 3.38) | P value (NMD); 0.17
Urine Output (mL/24h) | HSS (%NaCl)
Urine Output (mL/24h) | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | Baseline | Urine output (mL/kg/h), Urine output mL/24 h | 20 | 0.93 (0.55), 1870 (1106.1)^2^ | - | P interaction; 0.11
Urine Output (mL/24h) | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | Baseline | Urine output (mL/kg/h), Urine output mL/24 h | 12 | 0.73 (0.33), 1384 (625.7)^2^ | - | P interaction; 0.11
Urine Output (mL/24h) | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 1 (d) | Urine output (mL/kg/h), Urine output mL/24 h | 20 | 1.15 (0.44), 2285 (874.4)^2^ | 239.3; (−712.1, 1190.7) | P interaction; 0.11
Urine Output (mL/24h) | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 1 (d) | Urine output (mL/kg/h), Urine output mL/24 h | 12 | 1.09 (0.82), 2045.7 (1539)^2^ | 239.3; (−712.1, 1190.7) | P interaction; 0.11
Urine Output (mL/24h) | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 2 (d) | Urine output (mL/kg/h), Urine output mL/24 h | 20 | 1.29 (0.46), 2539 (905.2)^2^ | 822.4; (215.7, 1429.1) | P interaction; 0.11
Urine Output (mL/24h) | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 2 (d) | Urine output (mL/kg/h), Urine output mL/24 h | 12 | 0.91 (0.43), 1716.6 (811.2)^2^ | 822.4; (215.7, 1429.1) | P interaction; 0.11
Urine Output (mL/24h) | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 3 (d) | Urine output (mL/kg/h), Urine output mL/24 h, | 20 | 1.12 (0.41), 2185.3 (800)^2^ | −151.7; (−1009.4, 706.0); NMD; (Baseline-3 d); −637.7; (−1443.21, 167.81) | P interaction; 0.11
Urine Output (mL/24h) | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 3 (d) | Urine output (mL/kg/h), Urine output mL/24 h, | 12 | 1.25 (0.74), 2337 (1383.5)^2^ | −151.7; (−1009.4, 706.0); NMD; (Baseline-3 d); −637.7; (−1443.21, 167.81) | P interaction; 0.11
Urine Output (mL/24h) | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Urine output (mL/kg/h), Urine output mL/24 h | 20 | 0.83 (0.32), 1611.5 (621.3)^2^ | −736; (−1609.0, 138.0); NMD; −1221.5; (−2056.65,−386.35) | P interaction; 0.11
Urine Output (mL/24h) | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Urine output (mL/kg/h), Urine output mL/24 h | 12 | 1.28 (0.8), 2347 (1466.9)^2^ | −736; (−1609.0, 138.0); NMD; −1221.5; (−2056.65,−386.35) | P interaction; 0.11
Urine Output (mL/24h) | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Urine output, ml/24 h | 48 | 410 (141) | -NR | NR
Urine Output (mL/24h) | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | Baseline | Urine output, ml/24 h | 46 | 425 (129) | -NR | NR
Urine Output (mL/24h) | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | 6 (d) | Urine output, ml/24 h | 48 | 2250 (652) | 450 (154, 745) | P value between groups; At day 6; <0.0001
Urine Output (mL/24h) | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | 6 (d) | Urine output, ml/24 h | 46 | 1660 (515) | 450 (154, 745) | P value between groups; At day 6; <0.0001
Urine Output (mL/24h) | Wan, 2017, 28701670 | Furosemide with compound HSS | 100 mL c-HSS^8^ (2.8% NaCl) twice daily until clinical compensation^9^; Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Baseline | -Urine output, mL/24 h | 132 | 737(298) | - | NR
Urine Output (mL/24h) | Wan, 2017, 28701670 | Furosemide without compound HSS | Normal sodium diet 2.76 g/d; until clinical compensation^7^; Total Na ~2.8 g/d | < 500 mL/d | Baseline | -Urine output, mL/24 h | 132 | 792 (201) | - | NR
Urine Output (mL/24h) | Wan, 2017, 28701670 | Furosemide with compound HSS | 100 mL c-HSS^8^ (2.8% NaCl) twice daily until clinical compensation^9^; Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Discharge | Urine output, (mL/24 h) | 132 | 2048 (471) | 486; (362.5, 609.5); NMD; (Baseline-Discharge); 541; (432.75, 649.25) | P value between groups NR
Urine Output (mL/24h) | Wan, 2017, 28701670 | Furosemide without compound HSS | Normal sodium diet 2.76 g/d; until clinical compensation^7^; Total Na ~2.8 g/d | < 500 mL/d | Discharge | Urine output, (mL/24 h) | 132 | 1562 (550) | 486; (362.5, 609.5); NMD; (Baseline-Discharge); 541; (432.75, 649.25) | P value between groups NR
Urine Output (mL/24h) | Mahjoob, 2021, 34903983 | Furosemide with HSS | Normal sodium diet 2.76 g/d = ~2.8 g/d Na; until clinical compensation^9^; Total Na ~2.8 g/d | < 500 mL/d | Baseline | Urine Output, mL/24 h | 14 | 1254 (321) | - | 0.48^11^
Urine Output (mL/24h) | Mahjoob, 2021, 34903983 | Furosemide without HSS | 150 mL (0.9% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na ~1.1 g/d^5^ | NR | Baseline | Urine Output, mL/24 h | 14 | 1450 (1100) | - | 0.48^11^
Urine Output (mL/24h) | Mahjoob, 2021, 34903983 | Furosemide with HSS | 150 mL (5% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na 5.9=~6 g/d^5^ | NR | 3 (d) | Urine Output, mL/24 h | 14 | 2282 (790) | 243; (−303.7, 789.7); NMD; (Baseline-3 d); 439; (−180.43, 1058.43) | 0.39^12^
Urine Output (mL/24h) | Mahjoob, 2021, 34903983 | Furosemide without HSS | 150 mL (0.9% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na ~1.1 g/d^5^ | NR | 3 (d) | Urine Output, mL/24 h | 14 | 2039 (682) | 243; (−303.7, 789.7); NMD; (Baseline-3 d); 439; (−180.43, 1058.43) | 0.39^12^
Urine Output (mL/24h) | Licata, 2003, 12660669 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily for 6 to 12 (d); Normal sodium diet 2.76 g/d= ~2.8 g/d Na; Total Na= ~4.5-8.2 g/d | 1000 mL/d | Baseline | Urine Output, mL/24 h | 53 | 390 (151) | - | NR
Urine Output (mL/24h) | Licata, 2003, 12660669 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for; 6 to 12 (d); Total Na 1.8 g/d | 1000 mL/d | Baseline | Urine Output, mL/24 h | 54 | 435 (139) | - | NR
Urine Output (mL/24h) | Licata, 2003, 12660669 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily for 6 to 12 (d); Normal sodium diet 2.76 g/d= ~2.8 g/d Na; Total Na= ~4.5-8.2 g/d | 1000 mL/d | Discharge | Urine Output, mL/24 h | 53 | 2100 (622) | 450; (230.3, 669.7); NMD; (Baseline-Discharge); 495; (296.68, 693.32) | P value between groups; At discharge; <0.001
Urine Output (mL/24h) | Licata, 2003, 12660669 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for; 6 to 12 (d); Total Na 1.8 g/d | 1000 mL/d | Discharge | Urine Output, mL/24 h | 54 | 1650 (535) | 450; (230.3, 669.7); NMD; (Baseline-Discharge); 495; (296.68, 693.32) | P value between groups; At discharge; <0.001
Urine Output (mL/24h) | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) for 24 (h); Restricted sodium to 2.4 g/d Na; Total Na 5.7=~6 g/d | 500 mL/d | 24 (h) | Urine Output, mL/24 h | 22 | 2701 (920) | 924; (415.37, 1432.63) | <0.001
Urine Output (mL/24h) | Okuhara, 2014, 24462960 | Furosemide wutg Glucose (5%) | 500 mL/d 5% glucose; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | 24 (h) | Urine Output, mL/24 h | 22 | 1777 (797) | 924; (415.37, 1432.63) | <0.001
Urine Output (mL/24h) | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Urine Output, mL/24 h | 30 | 390 (155) | - | NR
Urine Output (mL/24h) | Paterna, 2000, 10938493 | Furosemide without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | Baseline | Urine Output, mL/24 h | 30 | 433 (141) | - | NR
Urine Output (mL/24h) | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Urine Output, mL/24 h | 30 | 2100 (626) | 450; (154.9, 745.1); NMD; (Baseline-Discharge); 493; (227.28, 758.72) | P value between groups; At discharge; <0.001
Urine Output (mL/24h) | Paterna, 2000, 10938493 | Furosemide without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | Discharge | Urine Output, mL/24 h | 30 | 1650 (537) | 450; (154.9, 745.1); NMD; (Baseline-Discharge); 493; (227.28, 758.72) | P value between groups; At discharge; <0.001
Urine Output (mL/24h) | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Urine Output, mL/24 h | 953 | 635 (145) | - | NR
Urine Output (mL/24h) | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Baseline | Urine Output, mL/24 h | 974 | 690 (155) | - | NR
Urine Output (mL/24h) | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Urine Output, mL/24 h | 953 | 2150 (565) | 475; (425.2, 524.8); NMD; (Baseline-Discharge); 530; (485.36 574.64) | P value between- group:; At discharge; <0.0001
Urine Output (mL/24h) | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Discharge | Urine Output, mL/24 h | 974 | 1675 (550) | 475; (425.2, 524.8); NMD; (Baseline-Discharge); 530; (485.36 574.64) | P value between- group:; At discharge; <0.0001
Urine Output (mL/24h) | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Baseline | Urine Output, mL/24 h | 122 | 427 (128) | - | 0.18
Urine Output (mL/24h) | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Baseline | Urine Output, mL/24 h | 126 | 447 (106) | - | 0.18
Urine Output (mL/24h) | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Discharge | Urine Output, mL/24 h | 122 | 2180 (545) | 730; (362.2, 1097.8); NMD; (Baseline-Discharge); 750; (646.78, 853.22) | P value between- group.; Discharge; 0.0001
Urine Output (mL/24h) | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Discharge | Urine Output, mL/24 h | 126 | 1450 (352) | 730; (362.2, 1097.8); NMD; (Baseline-Discharge); 750; (646.78, 853.22) | P value between- group.; Discharge; 0.0001
Urine Output (mL/24h) | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d | 1000 mL/d | Baseline | Urine Output, mL/24 h | 66 | 425 (129) | - | NS
Urine Output (mL/24h) | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | Baseline | Urine Output, mL/24 h | 67 | 410 (141) | - | NS
Urine Output (mL/24h) | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d | 1000 mL/d | 6 (d) | Urine Output, mL/24 h | 66 | 2180 (545) | 630; (473.4, 786.6); NMD; (Baseline-6 d); 615; (474.79, 755.21) | P value between-group; At 6 d; <0.0001
Urine Output (mL/24h) | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | 6 (d) | Urine Output, mL/24 h | 67 | 1550 (355) | 630; (473.4, 786.6); NMD; (Baseline-6 d); 615; (474.79, 755.21) | P value between-group; At 6 d; <0.0001
Urine Output (mL/24h) | Tuttolomondo, 2021, 34288546 | Furosemide with HSS | 150 mL of HSS (1.4–4.6% NaCl) twice daily for 6 days; 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 3.3-7 g/d^18^ | NR | Baseline | Urine Output, mL/24 h | 68 | 1031.62 (212.29) | - | NR
Urine Output (mL/24h) | Tuttolomondo, 2021, 34288546 | Furosemide without HSS | 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 1.61 g/d^18^ | NR | Baseline | Urine Output, mL/24 h | 68 | 1001.47 (167.72) | - | NR
Urine Output (mL/24h) | Tuttolomondo, 2021, 34288546 | Furosemide with HSS | 150 mL of HSS (1.4−4.6% NaCl) twice daily for 6 days; 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 3.3-7 g/d^18^ | NR | 6 (d) | Urine Output, mL/24 h | 68 | 2260.74 (466.37) | 353.4; (225.4, 481.4); NMD; (Baseline-6 d); 323.20; (211.96, 434.44) | NR
Urine Output (mL/24h) | Tuttolomondo, 2021, 34288546 | Furosemide without HSS | 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 1.61 g/d^18^ | NR | 6 (d) | Urine Output, mL/24 h | 68 | 1907.35 (269.36) | 353.4; (225.4, 481.4); NMD; (Baseline-6 d); 323.20; (211.96, 434.44) | NR
Urine Output (mL/24h) | Montgomery, 2023, 37044281 | Furosemide with Oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | 4 (d) | Urine output, total amount from enrollment to day 4, mean urine output per day, mL | 34 | 10000 (4200), 2500 (1050) | Cohen d^α^; 0.13; (−0.36, 0.61); MD; 600; (−1469.89), 2669.89); MD; 150 (−362.73, 662.73) | 0.61
Urine Output (mL/24h) | Montgomery, 2023, 37044281 | Furosemide without Oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | 4 (d) | Urine output, total amount from enrollment to day 4, mean urine output per day, mL | 31 | 9400 (4300), 2350 (1075) | Cohen d^α^; 0.13; (−0.36, 0.61); MD; 600; (−1469.89), 2669.89); MD; 150 (−362.73, 662.73) | 0.61
Urine Output (mL/24h) | Montgomery, 2023, 37044281 | Furosemide with Oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | 4 (d) | Cumulative diuretic efficiency from enrollment to day 4 (urine output (L) per 40 mg oral FE), median (IQR) | 34 | 0.17 (0.06, 0.24) | Rank Biserial^α^ (r_rb_); 0.11; (−0.17, 0.37); Median Difference; 0.03 | 0.45
Urine Output (mL/24h) | Montgomery, 2023, 37044281 | Furosemide without Oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | 4 (d) | Cumulative diuretic efficiency from enrollment to day 4 (urine output (L) per 40 mg oral FE), median (IQR) | 31 | 0.14 (0.07, 0.21) | Rank Biserial^α^ (r_rb_); 0.11; (−0.17, 0.37); Median Difference; 0.03 | 0.45
BNP/NT-proBNP | Diet (g/d Na)
BNP/NT-proBNP | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | Baseline | BNP, pg/mL, median (IQR), | 38 | 1084 (608, 1820) | - | 0.67
BNP/NT-proBNP | Aliti, 2013, 23689381 | Unrestricted sodium | diet ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | Baseline | BNP, pg/mL, median (IQR), | 37 | 1425 (632, 2297) | - | 0.67
BNP/NT-proBNP | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | 7 (d) | BNP, pg/mL, median (IQR), | 38 | 954 (488, 1331) | Median Difference; 184; Net Median Difference; 525 | P value between-group; Study end 0.92^20^; From baseline to study end; 0.51^21^
BNP/NT-proBNP | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | 7 (d) | BNP, pg/mL, median (IQR), | 37 | 770 (4485, 1400) | Median Difference; 184; Net Median Difference; 525 | P value between-group; Study end 0.92^20^; From baseline to study end; 0.51^21^
BNP/NT-proBNP | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | Baseline | BNP, pg/mL, median (IQR) | 30 | 301 (215, 524) | - | NR
BNP/NT-proBNP | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | Baseline | BNP, pg/mL, median (IQR) | 23 | 186 (100, 325) | - | NR
BNP/NT-proBNP | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | 7 (d)^#^ | BNP, pg/mL, median (IQR), | 30 | 286 (161, 368) | Median Difference; 102; Net Median Difference; −13 | P group * time = 0.85^21^
BNP/NT-proBNP | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | 7 (d)^#^ | BNP, pg/mL, median (IQR), | 23 | 184 (113, 286) | Median Difference; 102; Net Median Difference; −13 | P group * time = 0.85^21^
BNP/NT-proBNP | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | NT-proBNP, pg/mL, median (IQR) | 16 | 4733 (503, 25000) | - | NR
BNP/NT-proBNP | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | NT-proBNP, pg/mL, median (IQR) | 15 | 4069 (1486, 25000) | - | NR
BNP/NT-proBNP | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | NT-proBNP. pg/mL, median (IQR) | 16 | 3954 (273, 10816) | Median Difference; 803; Net Median Difference; 139 | NS
BNP/NT-proBNP | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | NT-proBNP. pg/mL, median (IQR) | 15 | 3151 (282, 6157) | Median Difference; 803; Net Median Difference; 139 | NS
BNP/NT-proBNP | HSS (% NaCl)
BNP/NT-proBNP | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | Baseline | BNP, median (IQR)^##^ | 20 | 2077 (1046, 3353) | - | No difference in baseline values between HSS and placebo.
BNP/NT-proBNP | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | Baseline | BNP, median (IQR)^##^ | 12 | 1219 (574, 2336) | - | No difference in baseline values between HSS and placebo.
BNP/NT-proBNP | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 4 (d) which is 24 h after intervention | BNP, median (IQR)^##^, | 20 | 1728 (1067, 3574) | Median Difference; 344; Net Median Difference; −514 | NR
BNP/NT-proBNP | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 4 (d) which is 24 h after intervention | BNP, median (IQR)^##^, | 12 | 1384 (682, 1816) | Median Difference; 344; Net Median Difference; −514 | NR
BNP/NT-proBNP | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | Baseline | NT-proBNP, pg/mL, median (IQR), | 22 | 6776 (4341, 10079) | - | NR
BNP/NT-proBNP | Okuhara, 2014, 24462960 | Furosemide with glucose (5%) | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | Baseline | NT-proBNP, pg/mL, median (IQR), | 22 | 6525 (3547, 16116) | - | NR
BNP/NT-proBNP | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | 24 (h) | NT-proBNP, pg/mL, , median (IQR), | 22 | 4913 (2818, 8667) | Median Difference; −2280; Net Median Difference; −2531 | NR
BNP/NT-proBNP | Okuhara, 2014, 24462960 | Furosemide with glucose (5%) | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | 24 (h) | NT-proBNP, pg/mL, , median (IQR), | 22 | 7193 (3604, 15670) | Median Difference; −2280; Net Median Difference; −2531 | NR
BNP/NT-proBNP | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d | 1000 mL/d | 6 (d) | BNP, pg/mL | 66 | NR | - | P value between-group; at 6 d; Significant but not reported (BNP plasma levels were significantly lower for the HSS group compared with those without HSS)
BNP/NT-proBNP | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | 6 (d) | BNP, pg/mL | 67 | NR | - | P value between-group; at 6 d; Significant but not reported (BNP plasma levels were significantly lower for the HSS group compared with those without HSS)
BNP/NT-proBNP | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Baseline | BNP, pg/mL | 122 | 1284 (515) | - | 0.64
BNP/NT-proBNP | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Baseline | BNP, pg/mL | 126 | 1255 (475) | - | 0.64
BNP/NT-proBNP | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Discharge | BNP, pg/mL | 122 | 542 (285) | −140; (−210.5, −69.5)^3^; NMD; (Baseline-Discharge); −169; (−276.47, −61.53) | P value (MD) between-group; At discharge; 0.0001
BNP/NT-proBNP | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Discharge | BNP, pg/mL | 126 | 682 (296) | −140; (−210.5, −69.5)^3^; NMD; (Baseline-Discharge); −169; (−276.47, −61.53) | P value (MD) between-group; At discharge; 0.0001
BNP/NT-proBNP | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | BNP, pg/mL | 953 | 355 (105) | −30; (−39.8, −20.2) | <0.0001
BNP/NT-proBNP | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Discharge | BNP, pg/mL | 974 | 385 (115) | −30; (−39.8, −20.2) | <0.0001
BNP/NT-proBNP | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | BNP, pg/mL | 48 | 1212 (491) | - | <0.6
BNP/NT-proBNP | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | Baseline | BNP, pg/mL | 46 | 1265 (515) | - | <0.6
BNP/NT-proBNP | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | 6 (d) | BNP, pg/mL | 48 | 343 (196) | −125; (−216.3, −33.7); NMD; (Baseline-6 d); −72; (−248.86, 104.86) | P value (MD) between-group; At 6 d; <0.008
BNP/NT-proBNP | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | 6 (d) | BNP, pg/mL | 46 | 468 (251) | −125; (−216.3, −33.7); NMD; (Baseline-6 d); −72; (−248.86, 104.86) | P value (MD) between-group; At 6 d; <0.008
BNP/NT-proBNP | Tuttolomondo, 2011, 20346637 | Furosemide with HSS | 150 mL of HSS (1.4–4.6% NaCl) twice daily for 8 (d); 15 mL/kg of 0.9% NaCl (over 60 min) after 8 (d) once only.; Low sodium diet 1.61 g/d Na for 10 (d); Total Na 3.3-7 g/d^18^ | NR | Baseline | BNP, pg/mL, median (IQR) | 120 | 215.5 (80.5, 487 | - | NR
BNP/NT-proBNP | Tuttolomondo, 2011, 20346637 | Furosemide without HSS | 15 mL/kg of 0.9% NaCl (over 60 min) after 8 (d) once only.; Low sodium diet 1.61 g/d Na for 10 (d); Total Na 1.61 g/d^18^ | NR | Baseline | BNP, pg/mL, median (IQR) | 30 | NR | - | NR
BNP/NT-proBNP | Tuttolomondo, 2011, 20346637 | Furosemide with HSS | 150 mL of HSS (1.4–4.6% NaCl) twice daily for 8 (d); 15 mL/kg of 0.9% NaCl (over 60 min) after 8 (d) once only.; Low sodium diet 1.61 g/d Na for 10 (d); Total Na 3.3-7 g/d^18^ | NR | 8 (d) | BNP, pg/mL, median (IQR) | 120 | 87 (66, 141.5) | Median difference; −48; Net Median Difference could not be calculated due to NR at baseline for the second group | NR
BNP/NT-proBNP | Tuttolomondo, 2011, 20346637 | Furosemide without HSS | 15 mL/kg of 0.9% NaCl (over 60 min) after 8 (d) once only.; Low sodium diet 1.61 g/d Na for 10 (d); Total Na 1.61 g/d^18^ | NR | 8 (d) | BNP, pg/mL, median (IQR) | 30 | 135 (78.5, 202) | Median difference; −48; Net Median Difference could not be calculated due to NR at baseline for the second group | NR
BNP/NT-proBNP | Tuttolomondo, 2021, 34288546 | Furosemide with HSS | 150 mL of HSS (1.4–4.6% NaCl) twice daily for 6 days; 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 3.3-7 g/d^18^ | NR | Baseline | NT-proBNP, pg/mL | 68 | 7237 (7931) | - | 0.102
BNP/NT-proBNP | Tuttolomondo, 2021, 34288546 | Furosemide without HSS | 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 1.61 g/d^18^ | NR | Baseline | NT-proBNP, pg/mL | 68 | 5381 (4829) | - | 0.102
BNP/NT-proBNP | Tuttolomondo, 2021, 34288546 | Furosemide with HSS | 150 mL of HSS (1.4–4.6% NaCl) twice daily for 6 days; 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 3.3-7 g/d^18^ | NR | 6 (d) | NT-proBNP, pg/mL | 68 | 3244 (4159) | −1222; (−2660.9, 216.9)^3^; NMD; (Baseline-6 d); −3078; (−5043.5, −1112.5) | P value between-group; at 6 d; 0.096
BNP/NT-proBNP | Tuttolomondo, 2021, 34288546 | Furosemide without HSS | 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 1.61 g/d^18^ | NR | 6 (d) | NT-proBNP, pg/mL | 68 | 4466 (4332) | −1222; (−2660.9, 216.9)^3^; NMD; (Baseline-6 d); −3078; (−5043.5, −1112.5) | P value between-group; at 6 d; 0.096
BNP/NT-proBNP | Wan, 2017, 28701670 | Furosemide with compound HSS | 100 mL c-HSS^8^ (2.8% NaCl) twice daily until clinical compensation^9^; Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Baseline | BNP, pg/ml | 132 | 859 (154) | - | NR
BNP/NT-proBNP | Wan, 2017, 28701670 | Furosemide without compound HSS | Normal sodium diet 2.76 g/d; until clinical compensation^7^; Total Na ~2.8 g/d | < 500 mL/d | Baseline | BNP, pg/ml | 132 | 911 (277) | - | NR
BNP/NT-proBNP | Wan, 2017, 28701670 | Furosemide with compound HSS | 100 mL c-HSS^8^ (2.8% NaCl) twice daily until clinical compensation^9^; Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Discharge | BNP, pg/ml | 132 | 134 (56) | NMD; (Baseline-Discharge); −90; (−138.08, −41.92) | NR
BNP/NT-proBNP | Wan, 2017, 28701670 | Furosemide without compound HSS | Normal sodium diet 2.76 g/d; until clinical compensation^7^; Total Na ~2.8 g/d | < 500 mL/d | Discharge | BNP, pg/ml | 132 | 276 (78) | NMD; (Baseline-Discharge); −90; (−138.08, −41.92) | NR
BNP/NT-proBNP | Montgomery, 2023, 37044281 | Furosemide With Oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | Enrollment | NT-proBNP at admission, pg/mL, median (IQR) | 25 | 4540 (2690, 10700) | - | -
BNP/NT-proBNP | Montgomery, 2023, 37044281 | Furosemide without oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | Enrollment | NT-proBNP at admission, pg/mL, median (IQR) | 21 | 3550 (2350, 6490) | - | -
BNP/NT-proBNP | Montgomery, 2023, 37044281 | Furosemide With oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | ≤ 5 (d) | NT-proBNP at the end of study visit (≤ 5 (d)), pg/mL, median (IQR) | 26 | 2840 (1630, 4550) | Rank biserial^α^ (r_rb_); −0.16; (−0.46, 0.17); Median Difference; −680 | 0.34
BNP/NT-proBNP | Montgomery, 2023, 37044281 | Furosemide without oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | ≤ 5 (d) | NT-proBNP at the end of study visit (≤ 5 (d)), pg/mL, median (IQR) | 22 | 3520 (2430, 5980) | Rank biserial^α^ (r_rb_); −0.16; (−0.46, 0.17); Median Difference; −680 | 0.34
BNP/NT-proBNP | Montgomery, 2023, 37044281 | Furosemide With oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted Sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | Enrollment to ≤ 5 (d) | NT-proBNP change from enrollment to the end of study visit (≤ 5 (d)), pg/mL, median (IQR) | 25 | −1050 (−3050, 207) | Rank biserial^α^ (r_rb_); −0.11; (−0.41, 0.22); Net Median Difference; −10 | 0.52
BNP/NT-proBNP | Montgomery, 2023, 37044281 | Furosemide without oral NaCl | Restricted Sodium Diet ~0.8 g/d Na | No restriction | Enrollment to ≤ 5 (d) | NT-proBNP change from enrollment to the end of study visit (≤ 5 (d)), pg/mL, median (IQR) | 21 | −1040 (−1730, 212) | Rank biserial^α^ (r_rb_); −0.11; (−0.41, 0.22); Net Median Difference; −10 | 0.52
Serum Na (mEq/L) | Diet (g/d Na)
Serum Na (mEq/L) | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | Baseline | Sodium, mEq/L | 38 | 139 (4) | - | NR
Serum Na (mEq/L) | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | Baseline | Sodium, mEq/L | 37 | 139 (5) | - | NR
Serum Na (mEq/L) | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | ≤ 7 (d) | Sodium, mEq/L | 38 | 139 (4) | 0 (−1.6, 1.6); NMD 0; (−1.90, 1.90) | P value between-groups; Study end; > 0.99^20^; From baseline to the study end; 0.48^21^
Serum Na (mEq/L) | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | ≤ 7 (d) | Sodium, mEq/L | 37 | 139 (3) | 0 (−1.6, 1.6); NMD 0; (−1.90, 1.90) | P value between-groups; Study end; > 0.99^20^; From baseline to the study end; 0.48^21^
Serum Na (mEq/L) | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | Baseline | Sodium, mEq/L | 30 | 140 (4) | - | NR
Serum Na (mEq/L) | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | Baseline | Sodium, mEq/L | 23 | 141 (3) | - | NR
Serum Na (mEq/L) | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | ≤ 7 (d) | Sodium, mEq/L | 30 | 140 (4) | 0; (−1.89, 1.89); NMD 1; (−0.88, 2.88) | P value Between-group; (Baseline vs study end); 0.64^21^
Serum Na (mEq/L) | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | ≤ 7 (d) | Sodium, mEq/L | 23 | 140 (3) | 0; (−1.89, 1.89); NMD 1; (−0.88, 2.88) | P value Between-group; (Baseline vs study end); 0.64^21^
Serum Na (mEq/L) | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | Sodium, mEq/L | 16 | 136.3 (3.2) | - | NR
Serum Na (mEq/L) | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | Sodium, mEq/L | 15 | 136.5 (2.2) | - | NR
Serum Na (mEq/L) | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Sodium, mEq/L | 16 | 135.3 (3.7) | −2.4; (−4.45, −0.35); NMD; (Baseline-7 d); −2.2; (−4.19, −0.20) | P value (MD); < 0.05
Serum Na (mEq/L) | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Sodium, mEq/L | 15 | 137.7 (1.9) | −2.4; (−4.45, −0.35); NMD; (Baseline-7 d); −2.2; (−4.19, −0.20) | P value (MD); < 0.05
Serum Na (mEq/L) | HSS (% NaCl)
Serum Na (mEq/L) | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | Baseline | Sodium, mEq/L | 20 | 137.6 (3.5) | - | P interaction; 0.92
Serum Na (mEq/L) | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | Baseline | Sodium, mEq/L | 12 | 134.4 (5.6) | - | P interaction; 0.92
Serum Na (mEq/L) | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 1 (d) | Sodium, mEq/L | 20 | 138.7 (3.7) | - | P interaction; 0.92
Serum Na (mEq/L) | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 1 (d) | Sodium, mEq/L | 12 | 135.0 (5.5) | - | P interaction; 0.92
Serum Na (mEq/L) | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 2 (d) | Sodium, mEq/L | 20 | 139.1 (3.9) | - | P interaction; 0.92
Serum Na (mEq/L) | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 2 (d) | Sodium, mEq/L | 12 | 134.9 (6.1) | - | P interaction; 0.92
Serum Na (mEq/L) | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 3 (d) | Sodium, mEq/L | 20 | 139.5 (4.6) | 3.5; (0.03, 6.97); NMD; (Baseline-3 d); 0.3; (−3.22, 3.82) | P interaction; 0.92
Serum Na (mEq/L) | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 3 (d) | Sodium, mEq/L | 12 | 136.0 (5.0) | 3.5; (0.03, 6.97); NMD; (Baseline-3 d); 0.3; (−3.22, 3.82) | P interaction; 0.92
Serum Na (mEq/L) | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Sodium, mEq/L | 20 | 137.8 (4.3) | NMD; (Baseline-24 h after intervention); −0.3; (−3.8, 3.2) | P interaction; 0.92
Serum Na (mEq/L) | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Sodium, mEq/L | 12 | 134.9 (5.2) | NMD; (Baseline-24 h after intervention); −0.3; (−3.8, 3.2) | P interaction; 0.92
Serum Na (mEq/L) | Roul, 2017 | HSS | HSS (NaCl% NR); Sodium diet NR^19^ | NR^19^ | In-hospital | Sodium, mEq/L | 11 | 137 (7) | 8; (2.1, 13.8) | 0.007
Serum Na (mEq/L) | Roul, 2017 | without HSS | NR^19^ | NR^19^ | In-hospital | Sodium, mEq/L | 156 | 129 (3) | 8; (2.1, 13.8) | 0.007
Serum Na (mEq/L) | Licata, 2003, 12660669 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily for 6 to 12 ds; Normal sodium diet 2.76 g/d= ~2.8 g/d Na; Total Na= ~4.5-8.2 g/d | 1000 mL/d | Baseline | Sodium, mEq/L | 53 | 135.8 (7) | - | NR
Serum Na (mEq/L) | Licata, 2003, 12660669 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for; 6 to 12 days; Total Na 1.8 g/d | 1000 mL/d | Baseline | Sodium, mEq/L | 54 | 134.8 (8) | - | NR
Serum Na (mEq/L) | Licata, 2003, 12660669 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily for 6 to 12 ds; Normal sodium diet 2.76 g/d= ~2.8 g/d Na; Total Na= ~4.5-8.2 g/d | 1000 mL/d | Discharge | Sodium, mEq/L | 53 | 142.3 (3.9) | 12.1; (10.6, 13.6); NMD; (Baseline-Discharge); 11.1; (8.63, 13.57) | P value between-group; (Discharge); <0.001
Serum Na (mEq/L) | Licata, 2003, 12660669 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for; 6 to 12 days; Total Na 1.8 g/d | 1000 mL/d | Discharge | Sodium, mEq/L | 54 | 130.2 (4) | 12.1; (10.6, 13.6); NMD; (Baseline-Discharge); 11.1; (8.63, 13.57) | P value between-group; (Discharge); <0.001
Serum Na (mEq/L) | Mahjoob, 2021, 34903983 | Furosemide with HSS | 150 mL (5% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na 5.9=~6 g/d^5^ | NR | Baseline | Sodium, mEq/L | 14 | 135.21 (4) | - | 0.91^11^
Serum Na (mEq/L) | Mahjoob, 2021, 34903983 | Furosemide without HSS | 150 mL (0.9% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na ~1.1 g/d^5^ | NR | Baseline | Sodium, mEq/L | 14 | 134.93 (4.2) | - | 0.91^11^
Serum Na (mEq/L) | Mahjoob, 2021, 34903983 | Furosemide with HSS | 150 mL (5% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na 5.9=~6 g/d^5^ | NR | 3 (d) | Sodium, mEq/L | 14 | 138.86 (2.35) | 0.28; (−0.05, 0.61); NMD; (Baseline-3 d); 0.79; (−1.90, 3.48) | 0.10^11^
Serum Na (mEq/L) | Mahjoob, 2021, 34903983 | Furosemide without HSS | 150 mL (0.9% NaCl) twice daily for 48 (h); Sodium diet NR; Total Na ~1.1 g/d^5^ | NR | 3 (d) | Sodium, mEq/L | 14 | 137.79 (3.14) | 0.28; (−0.05, 0.61); NMD; (Baseline-3 d); 0.79; (−1.90, 3.48) | 0.10^11^
Serum Na (mEq/L) | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | Baseline | Sodium, mEq/L, median (IQR) | 22 | 138 (136, 141) | - | NR
Serum Na (mEq/L) | Okuhara, 2014, 24462960 | Furosemide with glucose (5%) | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | Baseline | Sodium, mEq/L, median (IQR) | 22 | 140.5 (137.3, 142) | - | NR
Serum Na (mEq/L) | Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | 24 (h) | Sodium, mEq/L, at 24 h end of intervention, median (IQR) | 22 | 140.5 (138, 142) | Median Difference; 1; Net Median Difference; (Baseline-24 h); 3.5 | NR
Serum Na (mEq/L) | Okuhara, 2014, 24462960 | Furosemide with glucose (5%) | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | 24 (h) | Sodium, mEq/L, at 24 h end of intervention, median (IQR) | 22 | 139.5 (135.3, 141) | Median Difference; 1; Net Median Difference; (Baseline-24 h); 3.5 | NR
Serum Na (mEq/L) | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d | 1000 mL/d | Baseline | Sodium, mEq/L | 66 | 136 (6) | - | NS
Serum Na (mEq/L) | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | Baseline | Sodium, mEq/L | 67 | 135 (4) | - | NS
Serum Na (mEq/L) | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d 8 | 1000 mL/d | 6 (d) | Sodium, mEq/L | 66 | 140 (5) | 1; (−0.7, 2.7); NMD; (Baseline-6 d); 8; (6.27, 9.73) | <0.0001
Serum Na (mEq/L) | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | 6 (d) | Sodium, mEq/L | 67 | 131 (5) | 1; (−0.7, 2.7); NMD; (Baseline-6 d); 8; (6.27, 9.73) | <0.0001
Serum Na (mEq/L) | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Baseline | Sodium, mEq/L | 122 | 139.5 (5.6) | - | 0.12
Serum Na (mEq/L) | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Baseline | Sodium, mEq/L | 126 | 138 (4.7) | - | 0.12
Serum Na (mEq/L) | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Discharge | Sodium, mEq/L | 122 | 140.2 (3.5) | 8.2; (4.1, 12.3)^3^; NMD; (Baseline-Discharge); 6.7; (5.58, 7.82) | P value between-group; At discharge; 0.0001
Serum Na (mEq/L) | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Discharge | Sodium, mEq/L | 126 | 132 (2.5) | 8.2; (4.1, 12.3)^3^; NMD; (Baseline-Discharge); 6.7; (5.58, 7.82) | P value between-group; At discharge; 0.0001
Serum Na (mEq/L) | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Sodium, mEq/L | 30 | 135.9 (6.8) | - | NR
Serum Na (mEq/L) | Paterna, 2000, 10938493 | Furosemide without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | Baseline | Sodium, mEq/L | 30 | 134.7 (7.9) | - | NR
Serum Na (mEq/L) | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Sodium, mEq/L | 30 | 142.2 (3.8) | 12.1; (10.0, 14.2); NMD; (Baseline-Discharge); 10.9; (7.66, 14.14) | P value between-group; At discharge; <0.001
Serum Na (mEq/L) | Paterna, 2000, 10938493 | Furosemide without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | Discharge | Sodium, mEq/L | 30 | 130.1 (4.3) | 12.1; (10.0, 14.2); NMD; (Baseline-Discharge); 10.9; (7.66, 14.14) | P value between-group; At discharge; <0.001
Serum Na (mEq/L) | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Sodium, mEq/L | 48 | 133.8 (6) | - | NR
Serum Na (mEq/L) | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | Baseline | Sodium, mEq/L | 46 | 134.9 (7) | - | NR
Serum Na (mEq/L) | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | 6 (d) | Sodium, mEq/L | 48 | 142.3 (3.4) | 12.2; (10.9, 13.5); NMD; (Baseline-6 d); 13.3; (11.01, 15.59) | P value between-group; At 6 days; <0.0001
Serum Na (mEq/L) | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | 6 (d) | Sodium, mEq/L | 46 | 130.1 (3) | 12.2; (10.9, 13.5); NMD; (Baseline-6 d); 13.3; (11.01, 15.59) | P value between-group; At 6 days; <0.0001
Serum Na (mEq/L) | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Baseline | Sodium, mEq/L | 953 | 137.8 (8) | - | NR
Serum Na (mEq/L) | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Baseline | Sodium, mEq/L | 974 | 138.8 (7) | - | NR
Serum Na (mEq/L) | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Sodium, mEq/L | 953 | 143.2 (4) | 7.9; (7.5, 8.3); NMD; (Baseline-Discharge); 8.9; (8.32, 9.48) | P value between-group; At discharge; <0.0001
Serum Na (mEq/L) | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Discharge | Sodium, mEq/L | 974 | 135.3 (3.9) | 7.9; (7.5, 8.3); NMD; (Baseline-Discharge); 8.9; (8.32, 9.48) | P value between-group; At discharge; <0.0001
Serum Na (mEq/L) | Wan, 2017, 28701670 | Furosemide with compound HSS | 100 mL c-HSS^8^ (2.8% NaCl) twice daily until clinical compensation^9^; Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Baseline | Sodium, mEq/L | 132 | 135.2 (2.3) | - | NR
Serum Na (mEq/L) | Wan, 2017, 28701670 | Furosemide without compound HSS | Normal sodium diet 2.76 g/d; until clinical compensation^7^; Total Na ~2.8 g/d | < 500 mL/d | Baseline | Sodium, mEq/L | 132 | 136.1 (4.8) | - | NR
Serum Na (mEq/L) | Wan, 2017, 28701670 | Furosemide with compound HSS | 100 mL c-HSS^8^ (2.8% NaCl) twice daily until clinical compensation^9^; Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Discharge | Sodium, mEq/L | 132 | 137.5 (2.9) | 3.9; (3.11, 4.68); NMD; (Baseline-Discharge); 4.8; (3.93, 5.67) | NR
Serum Na (mEq/L) | Wan, 2017, 28701670 | Furosemide without compound HSS | Normal sodium diet 2.76 g/d; until clinical compensation^7^; Total Na ~2.8 g/d | < 500 mL/d | Discharge | Sodium, mEq/L | 132 | 133.6 (3.6) | 3.9; (3.11, 4.68); NMD; (Baseline-Discharge); 4.8; (3.93, 5.67) | NR
Serum Na (mEq/L) | Yayla, 2015, 26135463 | Furosemide with HSS | 150 mL HSS (1.95% NaCl); once daily for 48 (h); Sodium Diet NR; Total Na 1.15 g/d^5^ | NR | Baseline-to-compensated | Sodium, mEq/ | 14 | 136.7 (4.1) | NMD; HSS vs bIV^17^; (Baseline-to-compensation); 0.7; (−2.2, 3.6) | P value between-group; 0.37
Serum Na (mEq/L) | Yayla, 2015, 26135463 | Furosemide (continuous) cIV without HSS | Sodium Diet NR | NR | Baseline-to-compensated | Sodium, mEq/ | 15 | 134.0 (7.2) | NMD; HSS vs bIV^17^; (Baseline-to-compensation); 0.7; (−2.2, 3.6) | P value between-group; 0.37
Serum Na (mEq/L) | Yayla, 2015, 26135463 | Furosemide (bolus) bIV without HSS | Sodium Diet NR | NR | Baseline-to-compensated | Sodium, mEq/ | 14 | 136.0 (3.8) | NMD; HSS vs bIV^17^; (Baseline-to-compensation); 0.7; (−2.2, 3.6) | P value between-group; 0.37
Serum Na (mEq/L) | Montgomery, 2023, 37044281 | Furosemide with oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | 4 (d) | Sodium change from enrollment to day 4, mEq/L | 34 | −0.03 (3.3) | Cohen d^α^; 0.86; (0.35, 1.37); NMD; 2.57; (1.109, 4.031) | <0.001
Serum Na (mEq/L) | Montgomery, 2023, 37044281 | Furosemide without oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | | Sodium change from enrollment to day 4, mEq/L | 31 | −2.6 (2.7) | Cohen d^α^; 0.86; (0.35, 1.37); NMD; 2.57; (1.109, 4.031) | <0.001
Serum Na (mEq/L) | Montgomery, 2023, 37044281 | Furosemide with oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | Discharge | Sodium change from enrollment to discharge, mEq/L | 34 | −0.91 (3.5) | Cohen d^α^; 0.66; (0.16, 1.17); NMD; 2.29; (0.612, 3.968) | 0.010
Serum Na (mEq/L) | Montgomery, 2023, 37044281 | Furosemide without oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | | Sodium change from enrollment to discharge, mEq/L | 31 | −3.2 (3.4) | Cohen d^α^; 0.66; (0.16, 1.17); NMD; 2.29; (0.612, 3.968) | 0.010
Aldosterone, pg/mL | Diet (g/d Na)
Aldosterone, pg/mL | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | Baseline | Aldosterone, pg/mL, median (IQR) | 30 | 65 (44, 159) | - | NR
Aldosterone, pg/mL | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | Baseline | Aldosterone, pg/mL, median (IQR) | 23 | 61 (35, 126) | - | NR
Aldosterone, pg/mL | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | at 7 days or at discharge which came first (study end)?; (d)^#^ | Aldosterone, pg/mL, median (IQR). | 30 | 81 (58, 164) | Median Difference; 15; Net Median Difference; (Baseline-7 d); 11 | P value Between-group; (Baseline vs study end); 0.85^21^
Aldosterone, pg/mL | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | at 7 days or at discharge which came first (study end)?; (d)^#^ | Aldosterone, pg/mL, median (IQR). | 23 | 66 (36, 129) | Median Difference; 15; Net Median Difference; (Baseline-7 d); 11 | P value Between-group; (Baseline vs study end); 0.85^21^
Aldosterone, pg/mL | HSS (% NaCl)
Aldosterone, pg/mL | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | Baseline | Aldosterone, median (IQR)^##^ | 20 | 10 (3.7, 17.2) | - | P value between-group; At baseline NS
Aldosterone, pg/mL | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | Baseline | Aldosterone, median (IQR)^##^ | 12 | 9.7 (6.2, 41.6) | - | P value between-group; At baseline NS
Aldosterone, pg/mL | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 days; Total Na 5.9 =~6 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Aldosterone, median (IQR)^##^, after intervention) | 20 | 12 (4.6, 19.7) | Median Difference; 4.4; Net Median Difference; (Baseline-after-intervention); 4.1 | NR
Aldosterone, pg/mL | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 days; Total Na 0.7 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Aldosterone, median (IQR)^##^, after intervention) | 12 | 7.6 (3.1, 79.9) | Median Difference; 4.4; Net Median Difference; (Baseline-after-intervention); 4.1 | NR
Aldosterone, pg/mL | Okuhara, 2014, 24462960 | HSS Furosemide | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | Baseline | Plasma aldosterone, pg/mL, median (IQR). | 22 | 71 (35.1, 112.0) | - | NR
Aldosterone, pg/mL | Okuhara, 2014, 24462960 | Glucose (5%) Furosemide | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | Baseline | Plasma aldosterone, pg/mL, median (IQR). | 22 | 76.4 (42.6, 94.6) | - | NR
Aldosterone, pg/mL | Okuhara, 2014, 24462960 | HSS Furosemide | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | 24 (h) | Plasma aldosterone, pg/mL, median (IQR). | 22 | 42.7 (23.3, 68.3) | Median Difference; (Baseline-24 h); −2.1; Net Median Difference; (Baseline-24 h); 3.3 | NR
Aldosterone, pg/mL | Okuhara, 2014, 24462960 | Glucose (5%) Furosemide | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | 24 (h) | Plasma aldosterone, pg/mL, median (IQR). | 22 | 44.8 (26.5, 66.2) | Median Difference; (Baseline-24 h); −2.1; Net Median Difference; (Baseline-24 h); 3.3 | NR
Aldosterone, pg/mL | Montgomery, 2023, 37044281 | Furosemide with oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | Enrollment | Aldosterone, pd/mL, median (IQR) | 25 | 280 (131, 585) | - | -
Aldosterone, pg/mL | Montgomery, 2023, 37044281 | Furosemide without oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | Enrollment | Aldosterone, pd/mL, median (IQR) | 21 | 303 (230, 481) | - | -
Aldosterone, pg/mL | Montgomery, 2023, 37044281 | Furosemide with oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | ≤ 5 (d) | Aldosterone, pd/mL, median (IQR) | 26 | 284 (194, 593) | Rank biserial^α^ (r_rb_); −0.03; (−0.35, 0.30); Median Difference; −7 | 0.87
Aldosterone, pg/mL | Montgomery, 2023, 37044281 | Furosemide without oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | ≤ 5 (d) | Aldosterone, pd/mL, median (IQR) | 22 | 291 (159, 639) | Rank biserial^α^ (r_rb_); −0.03; (−0.35, 0.30); Median Difference; −7 | 0.87
Aldosterone, pg/mL | Montgomery, 2023, 37044281 | Furosemide with oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | Enrollment to ≤ 5 (d) | Aldosterone change from enrollment to end of stud visit (≤ 5 (d)), pd/mL, median (IQR) | 25 | 17.1 (−51.2, 123) | Rank biserial^α^ (r_rb_); 0.17; (−0.16, 0.47); Net Median Difference; 64.5 | 0.32
Aldosterone, pg/mL | Montgomery, 2023, 37044281 | Furosemide without oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | Enrollment to ≤ 5 (d) | Aldosterone change from enrollment to end of stud visit (≤ 5 (d)), pd/mL, median (IQR) | 21 | −47.4 (−116, 85.1) | Rank biserial^α^ (r_rb_); 0.17; (−0.16, 0.47); Net Median Difference; 64.5 | 0.32
Renin | HSS (%NaCl)
Renin | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 (d); Total Na 5.9 =~6 g/d^5^ | NR | Baseline | Renin, median (IQR) | 20 | 20.6 (5.4, 35.4) | - | No difference in baseline values between groups
Renin | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 (d); Total Na 0.7 g/d^5^ | NR | Baseline | Renin, median (IQR) | 12 | 32.9 (17.9, 42.6) | - | No difference in baseline values between groups
Renin | Issa, 2013, 22243938 | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 (d); Total Na 5.9 =~6 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Renin, median (IQR) | 20 | 13.7 (5.6, 35.1) | Median Difference; −10.1; Net Median Difference; 2.2 | NR
Renin | Issa, 2013, 22243938 | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 (d); Total Na 0.7 g/d^5^ | NR | 4 (d) which is 24 h after intervention | Renin, median (IQR) | 12 | 23.8 (17.8, 45.1) | Median Difference; −10.1; Net Median Difference; 2.2 | NR
PRA (ng/ml/h) | Diet (g/d Na)
PRA (ng/ml/h) | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | Baseline | PRA, ng/mL/h, median (IQR) | 30 | 2.4 (0.6−9.1) | - | NR
PRA (ng/ml/h) | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | Baseline | PRA, ng/mL/h, median (IQR) | 23 | 2.8 (0.4−6.4) | - | NR
PRA (ng/ml/h) | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | ≤ 7 (d) | PRA, ng/mL/h,median (IQR). | 30 | 4.5 (2.3−22.1) | Median Difference; −1.3; Net Median Difference; (Baseline-7d or less); −0.9 | P value Between-group; (Baseline vs ≤ 7 (d)); 0.42^21^
PRA (ng/ml/h) | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | ≤ 7 (d) | PRA, ng/mL/h,median (IQR). | 23 | 5.8 (1.5−21.3) | Median Difference; −1.3; Net Median Difference; (Baseline-7d or less); −0.9 | P value Between-group; (Baseline vs ≤ 7 (d)); 0.42^21^
PRA (ng/ml/h) | HSS (% NaCl)
PRA (ng/ml/h) | Okuhara, 2014, 24462960 | HSS Furosemide | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | Baseline | Plasma renin activity, (ng/ml/h), median (IQR) | 22 | 1.1 (0.5, 6.5) | - | NR
PRA (ng/ml/h) | Okuhara, 2014, 24462960 | Glucose (5%) Furosemide | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | Baseline | Plasma renin activity, (ng/ml/h), median (IQR) | 22 | 0.7 (0.3, 5.2) | - | NR
PRA (ng/ml/h) | Okuhara, 2014, 24462960 | HSS Furosemide | 500 mL/d of HSS (1.7% NaCl) per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 5.7=~6 g/d | 500 mL/d | 24 (h) | Plasma renin activity, (ng/ml/h), at 24 h, end of intervention, median (IQR) | 22 | 0.9 (0.4, 8.1) | Median Difference; 0.3; Net Median Difference; (Baline-24 h); −0.1
PRA (ng/ml/h) | Okuhara, 2014, 24462960 | Glucose (5%) Furosemide | 500 mL/d 5% glucose per day; Restricted sodium to 2.4 g/d Na for 24 (h); Total Na 2.4 g/d | 500 mL/d | 24 (h) | Plasma renin activity, (ng/ml/h), at 24 h, end of intervention, median (IQR) | 22 | 0.6 (0.3, 4.1) | Median Difference; 0.3; Net Median Difference; (Baline-24 h); −0.1
Calorie intake (kcal/kg)/Fluid intake | Calorie Intake/Fluid Intake
Calorie intake (kcal/kg)/Fluid intake | Diet (g/d Na)
Calorie intake (kcal/kg)/Fluid intake | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | ≤ 7d | Calorie intake (kcal/kg/d) | 30 | 15.1 (5.1) | −4.4; (−7.26, −1.53) | 0.01
Calorie intake (kcal/kg)/Fluid intake | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | ≤ 7d | Calorie intake (kcal/kg/d) | 23 | 19.5 (5.4) | −4.4; (−7.26, −1.53) | 0.01
Calorie intake (kcal/kg)/Fluid intake | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | ≤ 7d | Fluid intake, mL/d, median (IQR) | 30 | 582.7 (496.9, 662.4) | Median Difference; −312.7 | <0.001^11^
Calorie intake (kcal/kg)/Fluid intake | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | ≤ 7d | Fluid intake, mL/d, median (IQR) | 23 | 895.4 (751.2, 1121.8) | Median Difference; −312.7 | <0.001^11^
Calorie intake (kcal/kg)/Fluid intake | Inuzuka, 2016 | Low sodium diet | Max 2.4 g/d for NR days | NR | NR | Caloric intake represented as a percentage of estimated daily requirements (timepoint was not reported) | 145 | 96% (25) | −16; (−6.6, −25.4) | <0.01
Calorie intake (kcal/kg)/Fluid intake | Inuzuka, 2016 | Unrestricted sodium diet | ~4 g/d for NR days | NR | NR | Caloric intake represented as a percentage of estimated daily requirements (timepoint was not reported) | 45 | 112% (29) | −16; (−6.6, −25.4) | <0.01
Clinical Outcomes
Clinical congestion score (CCS) | Diet (g/d Na)
Clinical congestion score (CCS) | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | Baseline | CCS^22^ | 38 | 12.6 (3.1) | - | 0.67
Clinical congestion score (CCS) | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | Baseline | CCS^22^ | 37 | 12.8 (2.8) | - | 0.67
Clinical congestion score (CCS) | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | 3 (d) | CCS change from baseline to day 3 (a primary end point) | 38 | −4.03 (3.3) | NMD −0.59; (−2.10, 0.92)^3^ | 0.47
Clinical congestion score (CCS) | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | 3 (d) | CCS change from baseline to day 3 (a primary end point) | 37 | −3.44 (3.35) | NMD −0.59; (−2.10, 0.92)^3^ | 0.47
Clinical congestion score (CCS) | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | 7 (d) | CCS at study end | 38 | 6.4 (3.0) | −0.7; (−1.97, 0.57); NMD −0.5; (−1.76, 0.76) | NR
Clinical congestion score (CCS) | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | 7 (d) | CCS at study end | 37 | 7.1 (2.6) | −0.7; (−1.97, 0.57); NMD −0.5; (−1.76, 0.76) | NR
Clinical congestion score (CCS) | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | Baseline | CCS^22^ | 30 | 12.2 (3.2) | - | 0.36
Clinical congestion score (CCS) | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | Baseline | CCS^22^ | 23 | 11.4 (2.7) | - | 0.36
Clinical congestion score (CCS) | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | 3 (d) | CCS change from baseline to day 3. | 30 | NR | - | 0.1
Clinical congestion score (CCS) | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | 3 (d) | CCS change from baseline to day 3. | 23 | NR | - | 0.1
Clinical congestion score (CCS) | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | 7 (d) | CCS change from baseline to day 7. | 30 | −3.4 (3.5) | NMD 0.4; (−1.6, 2.4) | 0.70
Clinical congestion score (CCS) | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | 7 (d) | CCS change from baseline to day 7. | 23 | −3.8 (3.4) | NMD 0.4; (−1.6, 2.4) | 0.70
HF-Related Symptom | HF-Related Symptom (Thirst)
HF-Related Symptom | Diet (g/d Na)
HF-Related Symptom | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | Baseline | Perceived thirst using; Visual analogue scale^26^ | 38 | 4.08 (2.6) | | 0.65
HF-Related Symptom | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | Baseline | Perceived thirst using; Visual analogue scale^26^ | 37 | 3.95 (2.5) | | 0.65
HF-Related Symptom | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | 7 (d) | Perceived thirst using; Visual analogue scale^26^ | 38 | 5.1 (2.9) | 0.67; (0.2-1.13); NMD; (Baseline-7 d); 1.53; (0.38, 2.67) | Time x group; P 0.01^27^
HF-Related Symptom | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | 7 (d) | Perceived thirst using; Visual analogue scale^26^ | 37 | 3.44 (2) | 0.67; (0.2-1.13); NMD; (Baseline-7 d); 1.53; (0.38, 2.67) | Time x group; P 0.01^27^
HF-Related Symptom | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | Baseline | Perceived thirst using; Visual analogue scale^26^ | 30 | 4.2 (3.6) | - | 0.14
HF-Related Symptom | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | Baseline | Perceived thirst using; Visual analogue scale^26^ | 23 | 5.8 (2.6) | - | 0.14
HF-Related Symptom | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | ≤ 7 d | Perceived thirst using; Visual analogue scale | 30 | NR | - | Time x group; P 0.03
HF-Related Symptom | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | ≤ 7 d | Perceived thirst using; Visual analogue scale | 23 | NR | - | Time x group; P 0.03
HF-Related Symptom | HSS (% NaCl)
HF-Related Symptom | Montgomery, 2023, 37044281 | Furosemide with oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | 4 (d) | TDS-HF score change from enrollment to day 4 | 34 | −1.2 (5.1) | Cohen d^α^; −0.23; (−0.73, 0.28); NMD; −1.31; (−4.169, 1.549) | 0.39
HF-Related Symptom | Montgomery, 2023, 37044281 | Furosemide without oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | 4 (d) | TDS-HF score change from enrollment to day 4 | 31 | 0.11 (6.5) | Cohen d^α^; −0.23; (−0.73, 0.28); NMD; −1.31; (−4.169, 1.549) | 0.39
HF-Related Symptom | HF-Related Symptom (Shortness of Breath)
HF-Related Symptom | Diet (g/d Na)
HF-Related Symptom | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | Perceived dyspnea using; Visual analogue scale^28^ | 16 | 4.8 (1.6) | - | NR
HF-Related Symptom | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | Perceived dyspnea using; Visual analogue scale^28^ | 15 | 6.3 (1.8) | - | NR
HF-Related Symptom | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Perceived dyspnea using; Visual analogue scale^28^ | 16 | 8.5 (1.4) | −0.7; (−1.55, 0.15); NMD (Baseline-7 d); 0.8; (−0.28, 1.88) | P between-group; 0.3
HF-Related Symptom | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Perceived dyspnea using; Visual analogue scale^28^ | 15 | 9.2 (1.0) | −0.7; (−1.55, 0.15); NMD (Baseline-7 d); 0.8; (−0.28, 1.88) | P between-group; 0.3
HF-Related Symptom | HF-Related Symptom (General Well-Being)
HF-Related Symptom | Diet (g/d Na)
HF-Related Symptom | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | Perceived General well-being using Visual analogue scale^29^ | 16 | 5.0 (2.3) | - | -
HF-Related Symptom | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | Baseline | Perceived General well-being using Visual analogue scale^29^ | 15 | 5.7 (2.2) | - | -
HF-Related Symptom | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Perceived General well-being using Visual analogue scale^29^ | 16 | 8.1 (1.9) | −0.1; (−1.47, 1.27); NMD; (Baseline-7 d); 0.6; (−0.89, 2.09) | P between-group; 0.59
HF-Related Symptom | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Perceived General well-being using Visual analogue scale^29^ | 15 | 8.2 (2.0) | −0.1; (−1.47, 1.27); NMD; (Baseline-7 d); 0.6; (−0.89, 2.09) | P between-group; 0.59
Diuretics Dose During Hospitalization | Diet (g/d Na)
Diuretics Dose During Hospitalization | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | Baseline | Mean dose of loop diuretics (furosemide), mg/d | 30 | 72.7 (29) | - | 0.64
Diuretics Dose During Hospitalization | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | Baseline | Mean dose of loop diuretics (furosemide), mg/d | 23 | 69 (26.9) | - | 0.64
Diuretics Dose During Hospitalization | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | 3 (d) | Mean dose of loop diuretics (furosemide), mg/d. | 30 | 74.7 (34.8) | - | 0.36
Diuretics Dose During Hospitalization | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | 3 (d) | Mean dose of loop diuretics (furosemide), mg/d. | 23 | 66.1 (31.0) | - | 0.36
Diuretics Dose During Hospitalization | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days ora less^**^ | 800 mL/d | ≤7 (d) | Mean dose of loop diuretics (furosemide) administered, mg/d | 30 | 68 (34.3) | NMD; 4.3; (−11.97, 20.57) | 0.38
Diuretics Dose During Hospitalization | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | ≤7 (d) | Mean dose of loop diuretics (furosemide) administered, mg/d | 23 | 60 (29.5) | NMD; 4.3; (−11.97, 20.57) | 0.38
Diuretics Dose During Hospitalization | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Final dose of furosemide, mg/d | 16 | 81.3 (36.6) | 14.2; (−6.80, 35.20) | NS
Diuretics Dose During Hospitalization | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Final dose of furosemide, mg/d | 15 | 67.1 (21.6) | 14.2; (−6.80, 35.20) | NS
Diuretics Dose During Hospitalization | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | During hospitalization | Cumulative dose of diuretic during hospitalization, mg | 16 | 517.5 (209.6) | 103.5; (−14.25, 221.25) | NS
Diuretics Dose During Hospitalization | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | During hospitalization | Cumulative dose of diuretic during hospitalization, mg | 15 | 414.0 (113.8) | 103.5; (−14.25, 221.25) | NS
Diuretics Dose During Hospitalization | Velloso, 1991, 1824218 | Low sodium diet | 0.8 g/d Na for NR days^4^ | 800 mL/d | During compensation period | Cumulative dose of furosemide, mg. | 14 | 568 (343) | −31; (−265.74, 203.74) | P value 0.80^25^
Diuretics Dose During Hospitalization | Velloso, 1991, 1824218 | Unrestricted sodium diet | 4 g/d Na for NR days^4^ | 800 mL/d | During compensation period | Cumulative dose of furosemide, mg. | 18 | 599 (327) | −31; (−265.74, 203.74) | P value 0.80^25^
Diuretics Dose During Hospitalization | Velloso, 1991, 1824218 | Low sodium diet | 0.8 g/d Na for NR days^4^ | 800 mL/d | During compensation period | Daily furosemide dose, mg/h/day | 14 | 1.43 (0.74) | −0.15; (−0.64, 0.34) | P value 0.57^25^
Diuretics Dose During Hospitalization | Velloso, 1991, 1824218 | Unrestricted sodium diet | 4 g/d Na for NR days^4^ | 800 mL/d | During compensation period | Daily furosemide dose, mg/h/day | 18 | 1.58 (0.62) | −0.15; (−0.64, 0.34) | P value 0.57^25^
Diuretics Dose During Hospitalization | HSS (% NaCl)
Diuretics Dose During Hospitalization | Montgomery, 2023, 37044281 | Furosemide with oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | 4 (d) | Total oral furosemide equivalent (FE) dosage from enrollment to day 4, mg | 34 | 1840 (915, 2810) | Rank Biserial^α^ (r_rb_); −0.02; (−0.29, 0.26); Median Difference; 220 | 0.91
Diuretics Dose During Hospitalization | Montgomery, 2023, 37044281 | Furosemide without oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | 4 (d) | Total oral furosemide equivalent (FE) dosage from enrollment to day 4, mg | 31 | 1620 (1070, 3080) | Rank Biserial^α^ (r_rb_); −0.02; (−0.29, 0.26); Median Difference; 220 | 0.91
Time on IV Diuretics | Diet (g/d Na)
Time on IV Diuretics | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | During hospitalization | The median days to transition from IV to oral diuretic therapy | 38 | 4 (2.0, 7.2) | Median Difference; 0 | 0.58
Time on IV Diuretics | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^ | ≥2500 mL/d | During hospitalization | The median days to transition from IV to oral diuretic therapy | 37 | 4 (2.0, 7.0) | Median Difference; 0 | 0.58
Time on IV Diuretics | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | ≤ 7 (d) | The mean days to transition from IV to oral diuretic therapy | 30 | 3 (2.3) | 0.3; (−0.86, 1.46) | 0.63
Time on IV Diuretics | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | ≤ 7 (d) | The mean days to transition from IV to oral diuretic therapy | 23 | 2.7 (2) | 0.3; (−0.86, 1.46) | 0.63
Time to Clinical Stability | Diet (g/d Na)
Time to Clinical Stability | Velloso, 1991, 1824218 | Low sodium diet | 0.8 g/d Na for NR days^4^ | 800 mL/d | During compensation period | Days to compensation (d) | 14 | 7.5 (1.9) | 0.9; (−0.34, 2.14)^3^ | P value 0.18^25^
Time to Clinical Stability | Velloso, 1991, 1824218 | Unrestricted sodium diet | 4 g/d Na for NR days^4^ | 800 mL/d | During compensation period | Days to compensation (d) | 18 | 6.6 (1.6) | 0.9; (−0.34, 2.14)^3^ | P value 0.18^25^
Adherence to Prescribed Diet Inpatient Setting
| Diet (g/d Na)
| d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | ≤ 7 (d) | Consumption of dietary Na g/d, median (IQR) | 30 | 1.2 (1.1, 1.3) | Median Difference; −1.3 | <0.001^21^
| d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | ≤ 7 (d) | Consumption of dietary Na g/d, median (IQR) | 23 | 2.5 (2.4, 2.8) | Median Difference; −1.3 | <0.001^21^
| Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Consumption of dietary Na g/d, g/d (through the 24-h dietary recall), | 16 | 0.10 (0.17) | −1.47; (−1.70, −1.23) | NR
| Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Consumption of dietary Na g/d, g/d (through the 24-h dietary recall), | 15 | 2.47 (0.43) | −1.47; (−1.70, −1.23) | NR
| Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Consumption of at least 80% of the entire meal | 16 | 79.6 (14.3%) | −8.5; (−17.87, 0.87)^3^ | 0.08
| Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | 7 (d) | Consumption of at least 80% of the entire meal | 15 | 88.1 (12.3%) | −8.5; (−17.87, 0.87)^3^ | 0.08
Utilization Measures
Length of Hospital Stay | Diet (g/d Na)
Length of Hospital Stay | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less^*^ | Max 800 mL/d | Discharge | The overall median length of stay (d) | 38 | 7 (3.8, 13) | Median Difference; 1 | 0.89
Length of Hospital Stay | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less^*^. | ≥2500 mL/d | Discharge | The overall median length of stay (d) | 37 | 6 (4, 12.5) | Median Difference; 1 | 0.89
Length of Hospital Stay | Aliti, 2013, 23689381 | Low sodium diet | Max 0.8 g/d Na for 7 days or less | Max 800 mL/d | Discharge | The length of stay among patients remained hospitalized after day 7 | NR | NR | - | 0.9
Length of Hospital Stay | Aliti, 2013, 23689381 | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less | ≥2500 mL/d | Discharge | The length of stay among patients remained hospitalized after day 7 | NR | NR | - | 0.9
Length of Hospital Stay | d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na for 7 days or less^**^ | 800 mL/d | Discharge | The overall median length of stay (d) | 30 | 6 (1, 17) | Median Difference; 2 | 0.52
Length of Hospital Stay | d’Almeida, 2018, 29793053 | Unrestricted sodium | ~4 g/d Na for 7 days or less^**^ | Unlimited fluid intake | Discharge | The overall median length of stay (d) | 23 | 4 (2, 8) | Median Difference; 2 | 0.52
Length of Hospital Stay | Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na for 7 days^***^ | 1000 mL/d | Discharge | Mean hospitalization duration (d) | 16 | 18.1 (9.6) | 6.7 (1.67, 11.73)^3^ | 0.02
Length of Hospital Stay | Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na for 7 days^***^ | 1000 mL/d | Discharge | Mean hospitalization duration (d) | 15 | 11.4 (3.5) | 6.7 (1.67, 11.73)^3^ | 0.02
Length of Hospital Stay | HSS (% NaCl)
Length of Hospital Stay | Licata, 2003, 12660669 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily for 6 to 12 ds; Normal sodium diet 2.76 g/d= ~2.8 g/d Na; Total Na= ~4.5-8.2 g/d | 1000 mL/d | Discharge | Hospitalization (d) | 53 | 8.57 (2.3) | −3.13; (−4.06, −2.20) | <0.001
Length of Hospital Stay | Licata, 2003, 12660669 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for; 6 to 12 days; Total Na 1.8 g/d | 1000 mL/d | Discharge | Hospitalization (d) | 54 | 11.7 (2.6) | −3.13; (−4.06, −2.20) | <0.001
Length of Hospital Stay | Parrinello, 2011, 21440872 | Furosemide with HSS | 150 mL of HSS (3% NaCl) twice daily; Light sodium diet 2.76 g/d Na for 6 (d); Total Na 6.3 g/d | 1000 mL/d | Discharge | Hospitalization (d) | 66 | 6.3 (3) | −5.7; (−6.90, −4.50) | <0.0001
Length of Hospital Stay | Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of 0.9% NaCl twice daily; Low sodium diet 1.8 g/d Na for 6 (d); Total Na 2.9 g/d = ~3 g/d | 1000 mL/d | Discharge | Hospitalization (d) | 67 | 12 (4) | −5.7; (−6.90, −4.50) | <0.0001
Length of Hospital Stay | Parrinello, 2012, 22980301 | Furosemide with HSS | HSS (1.4%-4.6% NaCl)^6^ twice daily; Normosodic diet until compensation^14^; Total Na: assumed at least 3.5-4.5 g/d^15^ | 1000 mL/d | Discharge | Hospitalization (d) | 122 | 6.25 (2.12) | −3.95; (−4.53, −3.37) | <0.0001
Length of Hospital Stay | Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | Discharge | Hospitalization (d) | 126 | 10.2 (2.54) | −3.95; (−4.53, −3.37) | <0.0001
Length of Hospital Stay | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Hospitalization (d) | 30 | 8.57 (2.3) | −3.1; (−4.34, −1.86)^3^ | 0.001
Length of Hospital Stay | Paterna, 2000, 10938493 | Furosemide without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | Discharge | Hospitalization (d) | 30 | 11.67 (2.6) | −3.1; (−4.34, −1.86)^3^ | 0.001
Length of Hospital Stay | Paterna, 2011, 21701268 | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl)^6^ twice daily until compensation^13^; Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Hospitalization (d) | 953 | 3.5 (1) | −2; (−2.09, −1.91) | <0.0001
Length of Hospital Stay | Paterna, 2011, 21701268 | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^13^; Total Na 1.8 g/d^7^ | 1000 mL/d | Discharge | Hospitalization (d) | 974 | 5.5 (1) | −2; (−2.09, −1.91) | <0.0001
Length of Hospital Stay | Paterna, 2005, 15963399 | Furosemide with HSS | 150 mL of HSS (1.4%- 4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Hospitalization (d) | 48 | 6.57 (2.3) | −3.93; (−4.92, −2.94) | <0.0001
Length of Hospital Stay | Paterna, 2005, 15963399 | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | Discharge | Hospitalization (d) | 46 | 10.5 (2.6) | −3.93; (−4.92, −2.94) | <0.0001
Length of Hospital Stay | Roul, 2017 | HSS | HSS (NaCl% NR); Sodium diet NR^19^ | NR^19^ | Discharge | Median length of stay (d) | 11 | 21 (IQR: NR) | Median Difference; 11 | NR
Length of Hospital Stay | Roul, 2017 | without HSS | NR^19^ | NR^19^ | Discharge | Median length of stay (d) | 156 | 10 (IQR:NR) | Median Difference; 11 | NR
Length of Hospital Stay | Tuttolomondo, 2011, 20346637 | Furosemide with HSS | 150 mL of HSS (1.4–4.6% NaCl) twice daily for 8 (d); 15 mL/kg of 0.9% NaCl (over 60 min) after 8 (d) once only.; Low sodium diet 1.61 g/d Na for 10 (d); Total Na 3.3-7 g/d^18^ | NR | Discharge | Hospitalization (d), median (IQR) | 120 | 10; (9, 11) | Median Difference; 0 | NR
Length of Hospital Stay | Tuttolomondo, 2011, 20346637 | Furosemide without HSS | 15 mL/kg of 0.9% NaCl (over 60 min) after 8 (d) once only.; Low sodium diet 1.61 g/d Na for 10 (d); Total Na 1.61 g/d^18^ | NR | Discharge | Hospitalization (d), median (IQR) | 30 | 10 (8,11) | Median Difference; 0 | NR
Length of Hospital Stay | Wan, 2017, 28701670 | Furosemide with compound HSS | 100 mL c-HSS^8^ (2.8% NaCl) twice daily until clinical compensation^9^; Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Discharge | Hospitalization time (d) | 132 | 4 (2) | −3; (−3.48, −2.52) | <0.01
Length of Hospital Stay | Wan, 2017, 28701670 | Furosemide without compound HSS | Normal sodium diet 2.76 g/d; until clinical compensation^9^; Total Na ~2.8 g/d | < 500 mL/d | Discharge | Hospitalization time (d) | 132 | 7 (2) | −3; (−3.48, −2.52) | <0.01
Length of Hospital Stay | Yayla, 2015, 26135463 | Furosemide with HSS | 150 mL HSS (1.95% NaCl); once daily for 48 (h); Sodium Diet NR; Total Na 1.15 g/d^5^ | NR | Until compensation | Hospitalization (d), from baseline to compensated state. | 14 | 3.7 (1.3) | HSS vs bIV^17^; −4.2; (−6.45, −1.95) | <0.01
Length of Hospital Stay | Yayla, 2015, 26135463 | Furosemide (continuous) cIV without HSS | Sodium Diet NR | NR | Until compensation | Hospitalization (d), from baseline to compensated state. | 15 | 6.6 (3.4) | HSS vs bIV^17^; −4.2; (−6.45, −1.95) | <0.01
Length of Hospital Stay | Yayla, 2015, 26135463 | Furosemide (bolus) bIV without HSS | Sodium Diet NR | NR | Until compensation | Hospitalization (d), from baseline to compensated state. | 14 | 7.9 (4.1) | HSS vs bIV^17^; −4.2; (−6.45, −1.95) | <0.01
Length of Hospital Stay | Montgomery, 2023, 37044281 | Furosemide with oral NaCl | 2 g Oral NaCl three times per day for 4 days.; Restricted sodium Diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | Discharge | Time to discharge from enrollment (days), median (IQR) | 34 | 8.0 (6.00, 12.5) | Median Difference; 1.0 | NR
Length of Hospital Stay | Montgomery, 2023, 37044281 | Furosemide without oral NaCl | Restricted sodium Diet ~0.8 g/d Na | No restriction | Discharge | Time to discharge from enrollment (days), median (IQR) | 31 | 7.0 (5.00, 13.5) | Median Difference; 1.0 | NR

Notes.

1 Calculated by research team based on IV Na (saline) and oral sodium intake (diet Na) if reported;

2 Calculated by research team;

3 95% CI was calculated based on p value reported in the study;

4 The duration of intervention was not reported; however, most outcomes were reported at compensation which was defined as return to functional classes 1 or II and without edema;

5 Total sodium per day provided by IV fluid Na only, sodium diet in both groups was not reported and we assume it was at least 2.8 g/d;

6 The dose of HSS was determined according to serum Na (HSS 4.6%, 3.5%, between 1.4% and 2.4% were administered for patients with serum Na < 125 mEq/L, between 126 and 135 mEq/L, > 135 mEq/L respectively). In Tuttolomondo 2011, it was reported that HSS 3.5%, and between 1.4% and 2.4% were administered to patients with serum Na <125 mEq/L, and > 135 mEq/L respectively. In Tuttolomondo 2021, it was reported that HSS 3.5%, and between 1.4% and 2.4% were administered to patients with serum Na <135 mEq/L, and > 135 mEq/L respectively;

7 Total sodium per day provided by oral sodium intake (diet only) as no IV Na (saline) was reported or administered;

8 c-HSS contains, additional to the 2.8% NaCl, 0.2% KCl, 0.9% MgSO4;

9 Did not clearly define the duration of intervention; however, it was mentioned that the intervention would stop once patients reached compensation. Patients were considered clinically compensable when they achieved an improved NYHA classification and appropriate BW calculated by the Lorenz formula and bioelectrical impedance measurement;

10 The reported weight was not consistent with adult weight and not corresponding to the mean age reported, and it was not the difference or BMI, we did not include these values in our analysis. We contacted the author for clarification, but there has been no response;

11 Based on Mann-Whitney U test;

12 Based on Independent Sample T-test;

13 Defined as dry status, change in NYHA functional class to at least II on clinical judgment and the accomplishment of ideal BW, as calculated by the Lorenz formula and detected by bioimpedance vector analysis;

14 Compensation was defined, when the NYHA functional class reached at least class II with the accomplishment of dry weight, as detected by bioimpedance vector analysis;

15 The study did not mention the amount of HSS per day, or the amount of normal sodium diet; we assumed that patients received at least 100 mL of HSS per day and that normal sodium diet provided at least 2.8 g/d, based on the previous assumption the research team calculated the total sodium intake per day;

16 Weight change was reported here as (-) to denote the direction of change (reduction). SD was calculated by research team as it was not reported for weight change in the study;

17 We considered bIV group as reference to compare with HSS group;

18 We calculated here the total sodium per day during the 6 days of intervention (first phase of therapy), not including the sodium from the 0.9% NaCl loading (second phase of therapy);

19 Data about HSS concentration, amount, frequency, Na diet, total fluid per day was not reported in the abstract;

20 Multiple comparison test with Bonferroni correction;

21 Repeated-measures analysis (generalized estimating equations method) for the between-group difference from baseline to the end of the study period;

22 The CCS is an instrument composed of 7 items that assess clinical signs and symptoms of congestion, including presence of rales, a third heart sound, jugular venous distension, peripheral edema, hepatojugular reflux, orthopnea, paroxysmal nocturnal dyspnea, and New York Heart Association functional class. The score ranges from 1 to 22 points, with higher scores being directly indicative of increased clinical congestion;

23 Significance determined using multiple comparison test with Bonferroni correction;

24 Difference significant at P = .002; adjusted covariance matrix for correction of different CCS at hospital day 7;

25 Determined by Student’s t test;

26 Assessment of perceived thirst was performed using a visual analog scale. In this setting, patients were asked to grade their thirst on a scale of 0 to 10;

27 By mixed-effects models;

28 With 0 corresponding to marked shortness of breath and 10 to no shortness of breath;

29 With 0 representing the greatest possible malaise and 10 the maximum sensation of well-being;

* For 7 days or less until hospital day 7 or until discharge in patients whose length of stay was less than 7 days;

** For 7 days or less until day 7 of admission or at hospital discharge, whichever came first;

*** For 7 days 7 days (or less based on clinical indication, a clinical indication defined by the medical team responsible for the treatment of the patient based on the occurrence of hypotension, hyponatremia, or worsening of renal function, the intervention could be stopped before the 7th day of hospitalization);

α Reported in the study;

# At day 7 or at discharge, whichever came first;

## Unit was not reported;

### Research team converted the data from ng/mL to mg/L.

† Complete unit was not reported.

Abbreviations. BNP=brain (or B-type) natriuretic peptide; BUN=blood urea nitrogen; ccs=clinical congestion score; d=day; C-HSS=Compound hypertonic saline solution; dL=deciliter; eGFR=estimated glomerular filtration rate; g=gram; GFR=glomerular filtration rate; h=hour; HSS=hypertonic saline solution; IQR=interquartile range; IV=intravenous; L=liter; Max=maximum; MD= mean difference; MDRD=Modification of Diet in Renal Disease; mEq=milliequivalent; mg=milligram; NMD=net mean difference; mL=milliliter; min=minute; m=meter; N=sample size; Na=sodium; NaCl=sodium chloride; ng=nanogram; NR=not reported; NT-proBNP=N-terminal brain (or B-type) natriuretic peptide; NYHA=New York Heart Association; pg=picogram; SD=standard deviation; TDS-HF=Thirst Distress Scale for Heart Failure (higher scores indicates more thirst distress).