# APPENDIX G CATEGORICAL OUTCOMES

Outcome | Study Year PMID | Arm | Total Sodium Intake^1^ | Fluid Intake | Time | Outcome Definition | n/N (%) | Effect Size (95% CI)^2^ | Reported P value
Clinical Outcomes
Mortality | Diet (g/d Na)
Mortality | Aliti, 2013, 23689381; RCT | Low sodium diet | Max 0.8 g/d Na for 7 days or less | Max 800 mL/d | 7 (d) | All-cause mortality | 0/38 (0) | RD 0.0; (−0.051, 0.051) | -
Mortality | Aliti, 2013, 23689381; RCT | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less | ≥2500 mL/d | 7 (d) | All-cause mortality | 0/37 (0) | RD 0.0; (−0.051, 0.051) | -
Mortality | d’Almeida, 2018, 29793053; RCT | Low sodium diet | 0.8 g/d Na for 7 days or less | 800 mL/d | 30 (d) after discharge | All-cause mortality | 2/30 (6.7) | RR 0.77; (0.12, 5.04) | > 0.99
Mortality | d’Almeida, 2018, 29793053; RCT | Unrestricted sodium | ~4 g/d Na for 7 days or less | Unlimited fluid intake | 30 (d) after discharge | All-cause mortality | 2/23 (8.7) | RR 0.77; (0.12, 5.04) | > 0.99
Mortality | Fabricio, 2019, 31221280; RCT | Low sodium diet | 1.2 g/d Na for 7 days | 1000 mL/d | During hospitalization | All-cause mortality | 0/16 (0) | RD 0.0; (−0.117, 0.117) | -
Mortality | Fabricio, 2019, 31221280; RCT | Unrestricted sodium diet | 2.8 g/d Na for 7 days | 1000 mL/d | During hospitalization | All-cause mortality | 0/15 (0) | RD 0.0; (−0.117, 0.117) | -
Mortality | Fabricio, 2019, 31221280; RCT | Low sodium diet | 1.2 g/d Na for 7 days | 1000 mL/d | 30 (d) after discharge | All-cause mortality | 2/16 (12.5) | RR 0.93; (0.15, 5.84) | 1.0
Mortality | Fabricio, 2019, 31221280; RCT | Unrestricted sodium diet | 2.8 g/d Na for 7 days | 1000 mL/d | 30 (d) after discharge | All-cause mortality | 2/15 (13.3) | RR 0.93; (0.15, 5.84) | 1.0
Mortality | Velloso, 1991, 1824218; RCT | Low sodium diet | 0.8 g/d Na for NR days^3^ | 800 mL/d | NR | Mortality not directly related to congestive heart failure (one a sudden death and one septic shock due to lung disease) | 1/14 (7.1) | RR 1.29; (0.09,18.8) | NR
Mortality | Velloso, 1991, 1824218; RCT | Unrestricted sodium diet | 4 g/d Na for NR days^3^ | 800 mL/d | NR | Mortality not directly related to congestive heart failure (one a sudden death and one septic shock due to lung disease) | 1/18 (5.6) | RR 1.29; (0.09,18.8) | NR
Mortality | HSS (%NaCl)
Mortality | Issa, 2013, 22243938; RCT | Furosemide with HSS | 100 mL/d HSS (7.5% NaCl) twice daily for 3 (d); Total Na 5.9 =~6 g/d^4^ | NR | During hospitalization | All-cause mortality | 10/20 (50) | RR 1.5; (0.60, 3.74) | NR
Mortality | Issa, 2013, 22243938; RCT | Furosemide without HSS | 100 mL (0.9% NaCl) twice daily for 3 (d); Total Na 0.7 g/d^4^ | NR | During hospitalization | All-cause mortality | 4/12 (33.3)^5^ | RR 1.5; (0.60, 3.74) | NR
Mortality | Paterna, 2005, 15963399; RCT | Furosemide with HSS | 150 mL of HSS (1.4%-4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | 30 (d) | Death during the 30-day study period, all-cause (2 sudden death and 1 irreversible HF) | 0/48 (0) | RD −0.065; (−0.145, 0.015) | NR
Mortality | Paterna, 2005, 15963399; RCT | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | 30 (d) | Death during the 30-day study period, all-cause (2 sudden death and 1 irreversible HF) | 3/46 (6.5) | RD −0.065; (−0.145, 0.015) | NR
Mortality | Paterna, 2011, 21701268; RCT | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl) twice daily until compensation^6^ (1.65-5.42 g/d Na); Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | During hospitalization | Mortality from cardiac cause during hospitalization | 0/953 (0) | RD 0.0; (−0.002, 0.002) | -
Mortality | Paterna, 2011, 21701268; RCT | Furosemide without HSS | Low sodium diet 1.8 g/d Na; until compensation^6^; Total Na 1.8 g/d | 1000 mL/d | During hospitalization | Mortality from cardiac cause during hospitalization | 0/974 (0) | RD 0.0; (−0.002, 0.002) | -
Mortality | Wan, 2017, 28701670,; RCT | Furosemide with compound HSS | 100 mL c-HSS^7^ (2.8% NaCl) twice daily until clinical compensation^8^ (2.2 g/d Na); Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | During hospitalization | All-cause mortality | 0/132 (0) | RD 0.0; (−0.015, 0.015) | -
Mortality | Wan, 2017, 28701670,; RCT | Furosemide without compound HSS | Normal sodium diet 2.76 g/d Na; until clinical compensation^8^; Total Na 2.76 g/d = ~2.8 g/d | < 500 mL/d | During hospitalization | All-cause mortality | 0/132 (0) | RD 0.0; (−0.015, 0.015) | -
HF-Related Symptom | HF-Related Symptom (Change in NYHA Functional Class)
HF-Related Symptom | HSS (% NaCl)
HF-Related Symptom | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%-4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Number of patients who had their NYHA changed from IV to III at discharge | 2/30 (6.67) | RR 0.11; (0.03, 0.44) | < 0.05
HF-Related Symptom | Paterna, 2000, 10938493 | Furosemide without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | Discharge | Number of patients who had their NYHA changed from IV to III at discharge | 18/30 (60) | RR 0.11; (0.03, 0.44) | < 0.05
HF-Related Symptom | Paterna, 2000, 10938493 | Furosemide with HSS | 150 mL of HSS (1.4%-4.6% NaCl)^6^ twice daily; Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | | Number of patients who had their NYHA changed from IV to IIa or IIb at discharge | 28/30 (93.33) | RR (2.42); (1.55, 3.76) | -
HF-Related Symptom | Paterna, 2000, 10938493 | Furosemide without HSS | Sodium diet 2.76 g/d Na for 6 to 12 (d); Total Na ~2.8 g/d^7^ | 1000 mL/d | | Number of patients who had their NYHA changed from IV to IIa or IIb at discharge | 12/30 (40) | RR (2.42); (1.55, 3.76) | -
HF-Related Symptom | Paterna, 2011, 21701268; RCT | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl) twice daily until compensation^6^ (1.65- 5.42 g/d Na); Moderate sodium diet 2.76 g/d Na; Total Na 4.4-8.1 g/d | 1000 mL/d | Discharge | Number of patients who had their NYHA changed from III to II at discharge | 736/953 (77.2) | RR 0.93; (0.89, 0.97) | <0.29^9^
HF-Related Symptom | Paterna, 2011, 21701268; RCT | Furosemide without HSS | Low sodium diet 1.8 g/d Na until compensation^6^; Total Na 1.8 g/d | 1000 mL/d | Discharge | Number of patients who had their NYHA changed from III to II at discharge | 813/974 (83.5) | RR 0.93; (0.89, 0.97) | <0.29^9^
HF-Related Symptom | Paterna, 2011, 21701268; RCT | Furosemide with HSS | 150 mL of HSS (1.4%–4.6% NaCl) twice daily until compensation^6^ (1.65- 5.42 g/d Na); Moderate sodium diet 2.76 g/d Na; Total Na ~4.5-8.2 g/d | 1000 mL/d | Discharge | Number of patients who had their NYHA changed from III to I at discharge | 217/953 (22.8) | RR 1.38; (1.15, 1.65) | <0.006
HF-Related Symptom | Paterna, 2011, 21701268; RCT | Furosemide without HSS | Low sodium diet 1.8 g/d Na until compensation^6^; Total Na 1.8 g/d | 1000 mL/d | Discharge | Number of patients who had their NYHA changed from III to I at discharge | 161/974 (16.5) | RR 1.38; (1.15, 1.65) | <0.006
HF-Related Symptom | Wan, 2017, 28701670; RCT | Furosemide with compound HSS | 100 mL c-HSS^7^ (2.8% NaCl) twice daily until clinical compensation^8^ (2.2 g/d Na); Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Discharge | Number of patients who had their NYHA change from NYHA class III to II at discharge | 92/132^10^ (69.7),; 89/132 (67.4) | RR 0.96; (0.82, 1.12); RR (second data); 0.93; (0.79, 1.09) | >0.05
HF-Related Symptom | Wan, 2017, 28701670; RCT | Furosemide without compound HSS | Normal sodium diet 2.76 g/d Na; until clinical compensation^8^; Total Na 2.76 g/d = ~2.8 g/d | < 500 mL/d | Discharge | Number of patients who had their NYHA change from NYHA class III to II at discharge | 96/132 (72.7) | RR 0.96; (0.82, 1.12); RR (second data); 0.93; (0.79, 1.09) | >0.05
HF-Related Symptom | Wan, 2017, 28701670; RCT | Furosemide with compound HSS | 100 mL c-HSS^7^ (2.8% NaCl) twice daily until clinical compensation^8^ (2.2 g/d Na); Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | Discharge | Number of patients who had their NYHA class change from III to I at discharge | 26/132^10^ (19.7), 43/132 (32.6) | RR 1.53; (0.87, 2.68); RR (second data); RR 1.19; (0.82, 1.73) | <0.05
HF-Related Symptom | Wan, 2017, 28701670; RCT | Furosemide without compound HSS | Normal sodium diet 2.76 g/d Na; until clinical compensation^8^; Total Na 2.76 g/d = ~2.8 g/d | < 500 mL/d | Discharge | Number of patients who had their NYHA class change from III to I at discharge | 17/132^10^ (12.9); 36/132 (27.3) | RR 1.53; (0.87, 2.68); RR (second data); RR 1.19; (0.82, 1.73) | <0.05
HF-Related Symptom | HF-Related Symptom (Shortness of Breath)
HF-Related Symptom | HSS (%NaCl)
HF-Related Symptom | Okuhara, 2014, 24462960; RCT | Furosemide with HSS | 500 mL/d of HSS (1.7% NaCl) for 24 hs (3.34 g/d Na); Restricted sodium to 2.4 g/d Na; Total Na 5.7 g/d = ~6 g/d | 500 mL/d | 24 (h) | Rapid relief from dyspnea^11^ and systemic venous congestion provided by HSS infusion (duration of intervention = 24 hours) | 19/22 (86) | RR 1.73; (1.10, 2.71) | 0.01
HF-Related Symptom | Okuhara, 2014, 24462960; RCT | Furosemide with glucose (5%) | 500 mL/d 5% glucose; Restricted sodium to 2.4 g/d Na for 24 hs; Total Na 2.4 g/d | 500 mL/d | 24 (h) | Rapid relief from dyspnea^11^ and systemic venous congestion provided by HSS infusion (duration of intervention = 24 hours) | 11/22 (50) | RR 1.73; (1.10, 2.71) | 0.01
HF-Related Symptom | Tuttolomondo, 2021, 34288546; RCT | Furosemide with HSS | 150 mL of HSS (1.4–4.6% NaCl) twice daily for 6 days (1.65-5.42 g/d Na); 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 3.3-7 g/d^12^ | NR | Baseline | Resting dyspnea (not specified how it was assessed or what was score or scale used) | 12/68 (17.6) | - | 0.97
HF-Related Symptom | Tuttolomondo, 2021, 34288546; RCT | Furosemide without HSS | 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 1.61 g/d^12^ | NR | Baseline | Resting dyspnea (not specified how it was assessed or what was score or scale used) | 11/68 (16.2) | - | 0.97
HF-Related Symptom | Tuttolomondo, 2021, 34288546,; RCT | Furosemide with HSS | 150 mL of HSS (1.4–4.6% NaCl) twice daily for 6 days (1.65-5.42 g/d Na); 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 3.3-7 g/d^12^ | NR | 6 (d) | Resting dyspnea (not specified how it was assessed or what was score or scale used) at the end of the first phase of the therapy. | 2/12^13^ (16.7) | RR 0.46; (0.1, 2.03) | 0.24
HF-Related Symptom | Tuttolomondo, 2021, 34288546,; RCT | Furosemide Without HSS | 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 1.61 g/d^12^ | NR | 6 (d) | Resting dyspnea (not specified how it was assessed or what was score or scale used) at the end of the first phase of the therapy. | 4/11^13^ (36.4) | RR 0.46; (0.1, 2.03) | 0.24
HF-Related Symptom | Tuttolomondo, 2021, 34288546,; RCT | Furosemide with HSS | 150 mL of HSS (1.4–4.6% NaCl) twice daily for 6 days (1.65-5.42 g/d Na); 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 3.3-7 g/d^12^ | NR | Baseline | Work/effort dyspnea (not specified how it was assessed or what was score or scale used) | 61/68 (89.7) | - | 1.0
HF-Related Symptom | Tuttolomondo, 2021, 34288546,; RCT | Furosemide Without HSS | 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 1.61 g/d^12^ | NR | Baseline | Work/effort dyspnea (not specified how it was assessed or what was score or scale used) | 61/68 (89.7) | - | 1.0
HF-Related Symptom | Tuttolomondo, 2021, 34288546,; RCT | Furosemide with HSS | 150 mL of HSS (1.4–4.6% NaCl) twice daily for 6 days (1.65-5.42 g/d Na); 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 3.3-7 g/d^12^ | NR | 6 (d) | Work/effort dyspnea (not specified how it was assessed or what was score or scale used) at the end of the first phase of the therapy. | 11/61^13^ (18.0) | RR 0.52; (0.278, 0.99) | 0.044
HF-Related Symptom | Tuttolomondo, 2021, 34288546,; RCT | Furosemide without HSS | 15 mL/kg of 0.9% NaCl (over 60 min) after 6 days once only.; Low sodium diet 1.61 g/d Na; Total Na 1.61 g/d^12^ | NR | 6 (d) | Work/effort dyspnea (not specified how it was assessed or what was score or scale used) at the end of the first phase of the therapy. | 21/61^13^ (34.4) | RR 0.52; (0.278, 0.99) | 0.044
HF-Related Symptom | HF-Related Symptom (Clinical Parameter Indicates Dyspnea, Lower Edema, Weakness, Palpitation and Fatigue)
HF-Related Symptom | HSS (%NaCl)
HF-Related Symptom | Wan, 2017, 28701670,; RCT | Furosemide with compound HSS | 100 mL c-HSS^7^ (2.8% NaCl) twice daily until clinical compensation^8^ (2.2 g/d Na); Normal sodium diet 2.76 g/d Na; Total Na 5 g/d | < 500 mL/d | At discharge | Improvement in clinical symptoms after treatment (clinical parameter indicates dyspnea, lower edema, weakness, palpitation and fatigue), compensated state (discharge). | 119/132 (90.33) | RR 0.99; (0.92, 1.07) | >0.05
HF-Related Symptom | Wan, 2017, 28701670,; RCT | Furosemide without compound HSS | Normal sodium diet 2.76 g/d Na; until clinical compensation^8^; Total Na 2.76 g/d= ~2.8 g/d | < 500 mL/d | At discharge | Improvement in clinical symptoms after treatment (clinical parameter indicates dyspnea, lower edema, weakness, palpitation and fatigue), compensated state (discharge). | 120/132 (91.2) | RR 0.99; (0.92, 1.07) | >0.05
Patients Received Diuretic in Hospital | Diet (g/d Na)
Patients Received Diuretic in Hospital | Aliti, 2013, 23689381; RCT | Low sodium diet | Max 0.8 g/d Na for 7 days or less | Max 800 mL/d | 3 (d) | Patients administered IV furosemide during the first 3 days of hospitalization | 36/38 (94.7) | RR 0.97; (0.89, 1.07) | >0.99
Patients Received Diuretic in Hospital | Aliti, 2013, 23689381; RCT | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less | ≥2500 mL/d | 3 (d) | Patients administered IV furosemide during the first 3 days of hospitalization | 36/37 (97.3) | RR 0.97; (0.89, 1.07) | >0.99
Patients Received Diuretic in Hospital | Fabricio, 2019, 31221280; RCT | Low sodium diet | 1.2 g/d Na for 7 days | 1000 mL/d | During hospitalization | Patients administered furosemide (route not specified) | 15/16 (94) | RR 1.0; (0.83, 1.20) | NR
Patients Received Diuretic in Hospital | Fabricio, 2019, 31221280; RCT | Unrestricted sodium diet | 2.8 g/d Na for 7 days | 1000 mL/d | During hospitalization | Patients administered furosemide (route not specified) | 14/15 (93) | RR 1.0; (0.83, 1.20) | NR
Utilization Measure
30-Day Readmission | Diet (g/d Na)
30-Day Readmission | Aliti, 2013, 23689381; RCT | Low sodium diet | Max 0.8 g/d Na for 7 days or less | Max 800 mL/d | 30 (d) | Readmission because of heart failure | 11/38 (29) | RR 1.53; (0.67, 3.52) | 0.41
30-Day Readmission | Aliti, 2013, 23689381; RCT | Unrestricted sodium diet | ~3- 5 g/d Na for 7 days or less | ≥2500 mL/d | 30 (d) | Readmission because of heart failure | 7/37 (19) | RR 1.53; (0.67, 3.52) | 0.41
30-Day Readmission | d’Almeida, 2018, 29793053; RCT | Low sodium diet | 0.8 g/d Na for 7 days or less | 800 mL/d | 30 (d) | Readmission | 12/30 (40) | RR 0.92; (0.49, 1.74) | > 0.99
30-Day Readmission | d’Almeida, 2018, 29793053; RCT | Unrestricted sodium | ~4 g/d Na for 7 days or less | Unlimited fluid intake | 30 (d) | Readmission | 10/23 (43.5) | RR 0.92; (0.49, 1.74) | > 0.99
30-Day Readmission | Fabricio, 2019, 31221280; RCT | Low sodium diet | 1.2 g/d Na for 7 days | 1000 mL/d | 30 (d) | Readmission | 5/16 (31) | RR 0.94; (0.34, 2.6) | 1.0
30-Day Readmission | Fabricio, 2019, 31221280; RCT | Unrestricted sodium diet | 2.8 g/d Na for 7 days | 1000 mL/d | 30 (d) | Readmission | 5/15 (33) | RR 0.94; (0.34, 2.6) | 1.0
30-Day Readmission | HSS (%NaCl)
30-Day Readmission | Paterna, 2005, 15963399; RCT | Furosemide with HSS | 150 mL of HSS (1.4%-4.6% NaCl)^6^ twice daily; Normal sodium diet 2.76 g/d for 4 to 6 (d); Total Na 4.4-8.1 g/d | 1000 mL/d | 30 (d) | Readmissions in the 30-day follow-up for clinical signs of HF^14^ | 0/48 (0) | RD −0.261; (−0.39, −0.13) | <0.05
30-Day Readmission | Paterna, 2005, 15963399; RCT | Furosemide without HSS | Iposodic diet 1.8 g/d Na for 4 to 6 (d); Total Na 1.8 g/d^7^ | 1000 mL/d | 30 (d) | Readmissions in the 30-day follow-up for clinical signs of HF^14^ | 12/46 (26.1) | RD −0.261; (−0.39, −0.13) | <0.05
30-Day Readmission | Montgomery, 2023, 37044281; RCT | Furosemide with oral NaCl | 2 g oral NaCl three times per day for 4 days.; Restricted sodium diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | 30 (d) | Readmissions | 7/34 (21) | RR 0.91 (0.36, 2.31) | NR
30-Day Readmission | Montgomery, 2023, 37044281; RCT | Furosemide without oral NaCl | Restricted sodium diet ~0.8 g/d Na | No restriction | 30 (d) | Readmissions | 7/31 (23) | RR 0.91 (0.36, 2.31) | NR
Transfer to ICU (Proxy for Clinical Deterioration) | HSS (%NaCl)
Transfer to ICU (Proxy for Clinical Deterioration) | Montgomery, 2023, 37044281; RCT | Furosemide with oral NaCl | 2 g oral NaCl three times per day for 4 days.; Restricted sodium diet ~0.8 g/d Na.; Total Na ~ 3.2 g/d | No restriction | During hospitalization | ICU stay during hospitalization | 3/34 (9) | RR 0.56 (0.15, 2.15) | NR
Transfer to ICU (Proxy for Clinical Deterioration) | Montgomery, 2023, 37044281; RCT | Furosemide without oral NaCl | Restricted sodium diet ~0.8 g/d Na | No restriction | During hospitalization | ICU stay during hospitalization | 5/31 (16) | RR 0.56 (0.15, 2.15) | NR
Laboratory/Intermediate Measures
Kidney Function (Creatinine) | Diet (g/d Na)
Kidney Function (Creatinine) | Fabricio, 2019, 31221280; RCT | Low sodium diet | 1.2 g/d Na for 7 days | 1000 mL/d | 7 (d) | Worsening of renal function, represented by an increase in serum creatinine ≥ 0.3 mg/dL | 7/16 (43.8) | RR 0.94; (0.43, 2.04) | NR
Kidney Function (Creatinine) | Fabricio, 2019, 31221280; RCT | Unrestricted sodium diet | 2.8 g/d Na for 7 days | 1000 mL/d | 7 (d) | Worsening of renal function, represented by an increase in serum creatinine ≥ 0.3 mg/dL | 7/15 (46.7) | RR 0.94; (0.43, 2.04) | NR
Calorie Intake | Diet (g/d Na)
Calorie Intake | Inuzuka, 2016; NRCS | Low sodium diet | Max 2.4 g/d Na for NR days^15^ | NR | Time point was not explicitly reported | The incidence of low caloric intakes (caloric intakes less than 20 kcal/kg per day) | 77/145 (53) | RR 3.4; (1.7, 6.86); OR 6.15; (2.58, 14.67) | 0.02
Calorie Intake | Inuzuka, 2016; NRCS | Unrestricted sodium diet | 4 g/d Na for NR days^15^ | NR | Time point was not explicitly reported | The incidence of low caloric intakes (caloric intakes less than 20 kcal/kg per day) | 7/45 (15) | RR 3.4; (1.7, 6.86); OR 6.15; (2.58, 14.67) | 0.02

Notes.

1 Review team calculated based on IV and oral sodium intake if reported;

2 Review team calculated effect size and 95% CI;

3 The duration of intervention was not reported; however, most outcomes were reported at compensation which was defined as return to functional classes 1 or II and without edema;

4 Total sodium per day provided by IV fluid only, sodium diet was not reported;

5 Percentage has been corrected from the one reported in the text (33.3 instead of 30);

6 Defined as dry status, change in NYHA functional class to at least II on clinical judgment and the accomplishment of ideal body weight, as calculated by the Lorenz formula and detected by bioimpedance vector analysis;

7 c-HSS contains, additional to the 2.8% NaCl, 0.2% KCl, 0.9% MgSO4;

8 Patients were considered clinically compensated when they achieved an improved NYHA classification and appropriate body weight calculated by the Lorenz formula and bioelectrical impedance measurement;

9 Adjusted for multiple comparison;

10 Discrepancy between the data in the table and the text – we report data from the table;

11 Using 5-point Likert scale (patients with worse dyspnea and no change of score between baseline and 24 hours after initiation of the treatment were categorized as “no dyspnea improvement,” and those with improved dyspnea score were categorized as “dyspnea improvement”);

12 Total sodium per day during the 6 days of intervention (first phase of therapy), not including the sodium from the 0.9% NaCl (second phase of therapy);

13 The denominator is the number of patients who had dyspnea at admission (baseline) and not the sample (group) size;

14 They presented, at entry, higher functional class than at discharge (NYHA functional class III), while the remaining patients maintained the same NYHA functional class achieved at the time of hospital discharge;

15 Intervention duration was not reported.

Abbreviations. C-HSS=Compound hypertonic saline solution; d=day; HF=heart failure; HSS=hypertonic saline solution; IV=intravenous; Max=maximum; Na=sodium; NaCl=sodium chloride; n/N=n number of event; N sample size; NR=not reported; NYHA=New York Heart Association; OR=odds ratio; RD=risk difference; RR=risk ratio.