# APPENDIX F DESCRIPTION INTERVENTIONS

Table F.1 Description of Dietary Sodium Interventions

Author, Year, PMID | Arm | Sodium Intake | Fluid Intake | Duration of Interventions
Aliti, 2013, 23689381 | Low sodium diet | 0.8g/d Na | Maximum intake, 800 mL/d | Until hospital day 7 or until discharge; in patients whose length of stay was less than 7 days
Aliti, 2013, 23689381 | Unrestricted sodium diet | Standard hospital diet, 3-5 g/d Na | Liberal fluid, at least 2500 mL/d | Until hospital day 7 or until discharge; in patients whose length of stay was less than 7 days
Fabricio, 2019, 31221280 | Low sodium diet | 1.2 g/d Na | 1000 mL/d | 7 days (or less based on clinical indication^a^)
Fabricio, 2019, 31221280 | Unrestricted sodium diet | 2.8 g/d Na | 1000 mL/d | 7 days (or less based on clinical indication^a^)
d’Almeida, 2018, 29793053 | Low sodium diet | 0.8 g/d Na | 800 mL/d | Until day 7 of admission or at hospital discharge, whichever came first
d’Almeida, 2018, 29793053 | Unrestricted sodium diet | Standard hospital diet, ~4 g/d Na | Unlimited fluid intake | Until day 7 of admission or at hospital discharge, whichever came first
Inuzuka, 2016 | Low sodium diet | 2.4 g/d Na | NR | NR^b^
Inuzuka, 2016 | Unrestricted sodium diet | 4 g/d Na | NR | NR^b^
Velloso, 1991, 1824218 | Low sodium diet | 0.8 g/d Na | 800 mL/d | NR^b^
Velloso, 1991, 1824218 | Unrestricted sodium diet | 4 g/d Na | 800 mL/d | NR^b^

Notes.

a Clinical indication defined by the medical team responsible for the treatment of the patient based on the occurrence of hypotension, hyponatremia, or worsening of renal function, the intervention could be stopped before the 7th day of hospitalization;

b The study did not clearly define the duration of intervention.

Abbreviations. d=day; g=gram; mL=milliliter; Na=sodium; NR=not reported.

Table F.2 Description of Hypertonic Saline Solution Interventions

Author, Year, PMID | Arm | Saline Solution | Fluid Intake | Diuretic | Other interventions | Sodium Intake via Saline Solution^a^ | Sodium Intake from Diet^b^ | Total Sodium Intake^c^ | Duration of Interventions
Issa, 2013, 22243938 | Furosemide with HSS | 100 mL of HSS^d^ (7.5% NaCl) twice daily | NR | IV furosemide^e^ Bolus per day | NR | 5.9 g/d | NR | 5.9 g/d | 3 (d)
Issa, 2013, 22243938 | Furosemide without HSS | 100 mL of NS^d^ (0.9% NaCl) twice daily | NR | IV furosemide^e^ Bolus per day | NR | 0.7 g/d | NR | 0.7 g/d | 3 (d)
Licata, 2003, 12660669 | Furosemide with HSS | 150 mL of HSS^f^ (1.4%-4.6% NaCl) twice daily | 1000 mL/d | IV furosemide^g,h^ (500-1000 mg) 30-min infusion twice daily | Sodium diet (2.76 g/d Na) | 1.65 g/d –5.43 g/d | 2.76 g/d | 4.41–8.1 g/d | 6-12 (d)
Licata, 2003, 12660669 | Furosemide without HSS | NR | 1000 mL/d | IV furosemide^g,h^ (500-1000 mg) bolus twice daily | Sodium diet (1.84 g/d Na) | NR | 1.84 g/d | 1.84 g/d | 6-12 (d)
Mahjoob, 2021, 34903983 | Furosemide with HSS | 150 mL of HSS (5% NaCl) twice daily | NR | IV furosemide (250 mg) per day | NR | 5.9 g/d | NR | 5.9 g/d | 48 (h)
Mahjoob, 2021, 34903983 | Furosemide without HSS | 150 mL of NS every 12 h | NR | IV furosemide (250 mg) per day | NR | 1.06 g/d | NR | 1.06 g/d | 48 (h)
Okuhara, 2014, 24462960 | Furosemide with HSS | 500 mL of HSS (1.7% NaCl) per day | 500 mL/d | IV furosemide (40 mg) per day | Sodium diet (2.4 g/d Na) | 3.34 g | 2.4 g/d | 5.7 g/d | 24 (h)
Okuhara, 2014, 24462960 | Furosemide with glucose | 500 mL of glucose (5%) per day | 500 mL/d | IV furosemide (40 mg) per day | Sodium diet (2.4 g/d) | 0 g/d | 2.4 g/d | 2.4 g/d | 24 (h)
Paterna, 2000, 10938493 | Furosemide with HSS | 150 ml of HSS^f^ (1.4-4.6% NaCl) twice daily | 1000 mL/d | IV furosemide^g,h^ (500-1000 mg) 30-min infusion twice daily | Sodium diet (2.76 g/d Na) | 1.65 g/d – 5.42 g/d | 2.76 g/d | 4.41– 8.1 g/d | 6-12 (d)
Paterna, 2000, 10938493 | Furosemide without HSS | NR | 1000 mL/d | IV furosemide^g,h^ (500-1000 mg) bolus twice daily | Sodium diet (2.76 g/d Na) | NR | 2.3 g/d | 2.3 g/d | 6-12 (d)
Paterna, 2005, 15963399 | Furosemide with HSS | 150 ml of HSS^f^ (1.4%- 4.6%) NaCl twice daily | 1000 mL/d | IV furosemide^h^ (500-1000 mg) 30-min infusion twice daily | Sodium diet (2.76 g/d Na) | 1.65 g/d – 5.42 g/d | 2.76 g/d | 4.41– 8.1 g/d | 4-6 (d)
Paterna, 2005, 15963399 | Furosemide without HSS | NR | 1000 mL/d | IV furosemide^h^ (500-1000 mg) bolus twice daily | Sodium diet (1.84 g/d Na) | NR | 1.84 g/d | 1.84 g/d | 4-6 (d)
Paterna, 2011, 21701268 | Furosemide with HSS | 150 ml of HSS^f^ (1.4%–4.6% NaCl) twice daily | 1000 mL/d | IV furosemide^h^ (250 mg) 30-minute infusion twice daily | Sodium diet (2.76 g/d Na) | 1.65 g/d – 5.42 g/d | 2.76 g/d | 4.41 – 8.1 g/d | NR
Paterna, 2011, 21701268 | Furosemide without HSS | NR | 1000 mL/d | IV furosemide^h^ (500-1000 mg) bolus twice daily | Sodium diet (1.84 g/d Na) | NR | 1.8 g/d | 1.8 g/d | NR^1^
Parrinello, 2011, 21440872 | Furosemide with HSS | 150 ml of HSS (3% NaCl) twice daily | 1000 mL/d | IV furosemide (250 mg) twice daily | Sodium diet (2.76 g/d Na) | 3.54 g/d | 2.76 g/d | 6.3 g/d | 6 (d)
Parrinello, 2011, 21440872 | Furosemide without HSS | 150 mL of NS (0.9% NaCl) twice daily | 1000 mL/d | IV furosemide (250 mg) twice daily | Sodium diet (1.84 g/d Na) | 1.06 g/d | 1.84 g/d | 2.9 g/d | 6 (d)
Parrinello, 2012, 22980301 | Furosemide with HSS | HSS^f^ (1.4%–4.6% NaCl) twice daily | 1000 mL/d | IV furosemide (250 mg) 30-min infusion twice daily | Normal sodium diet | NR | NR | NR | NR
Parrinello, 2012, 22980301 | Furosemide without HSS | NR | 1000 mL/d | IV infusion furosemide (250 mg) twice daily | NR | NR | NR | NR | NR
Roul, 2017 | HSS | HSS | NR | NR | NR | NR | NR | NR | NR
Roul, 2017 | Without HSS | NR | NR | NR | NR | NR | NR | NR | NR
Tuttolomondo, 2011, 20346637 | Furosemide with HSS | 150 mL of HSS^i,k^ (1.4-4.6% NaCl) twice daily | NR | IV infusion furosemide^g,^ ^h^ (125-1000 mg) 30-min infusion twice daily | Sodium diet (1.61 g/d Na) | 1.65 g/d – 5.43 g/d | 1.61 g/d | 3.3 g/d – 7 g/d | 8 (d)
Tuttolomondo, 2011, 20346637 | Furosemide without HSS | NR | NR | IV infusion furosemide^g,h^ (125-1000 mg) 30-min infusion twice daily | Sodium diet (1.61 g/d Na) | NR | 1.61 g/d | 1.61 g/d | 8 (d)
Tuttolomondo, 2021, 34288546 | Furosemide with HSS | 150 ml of HSS^j,^ ^k^ (1.4-4.6% NaCl) twice daily | NR | IV infusion furosemide^g,h^ (120–250 mg) 30-min infusion twice daily | Sodium diet (1.61 g/d Na) | 1.65 g/d – 5.43 g/d | 1.61 g/d | 3.3 g/d – 7 g/d | 6 (d)
Tuttolomondo, 2021, 34288546 | Furosemide without HSS | NR^k^ | NR | IV infusion furosemide (120–250 mg) 30-min infusion twice daily | Sodium diet (1.61 g/d Na) | NR | 1.61 g/d | 1.61 g/d | 6 (d)
Wan, 2017, 28701670 | Furosemide with HSS | 100 ml of c-HSS^l^ twice daily | < 500 mL | IV furosemide (100 mg) 1 h infusion twice daily | Normal sodium diet (2.76 g/d Na) | 2.2 g/d | 2.76 g/d | 4.96 g/d | Until compensated^m^
Wan, 2017, 28701670 | Furosemide without HSS | NR | < 500 mL | IV furosemide (100 mg) 1 h infusion twice daily | Normal sodium diet (2.76 g/d Na) | NR | 2.76 g/d | 2.76 g/d | Until compensated^m^
Yayla, 2015,^n^ 26135463 | Furosemide with HSS | 150 ml of HSS (1.95% NaCl) in 30 min once daily | NR | IV furosemide (160 mg) in 30 min once daily | NR | 1.15 g/d | NR | 1.15 g/d | 48 (h)
Yayla, 2015,^n^ 26135463 | Furosemide (cIV) without HSS | NR | NR | IV furosemide (160 mg) continuous infusion in 16h/d | NR | NR | NR | NR | 48 (h)
Yayla, 2015,^n^ 26135463 | Furosemide (bI) without HSS | NR | NR | IV furosemide (80 mg) bolus twice daily | NR | NR | NR | NR | 48 (h)
Montgomery, 2023, 37044281; United States | Furosemide with oral NaCl | NR | Unlimited | IV furosemide | 2 g Oral NaCl thrice per day + Restricted Na diet (~0.8 g/d Na) | NR | 3.2 g/d | 3.2 g/d | 4 (d)
Montgomery, 2023, 37044281; United States | Furosemide without oral NaCl | NR | Unlimited | IV furosemide | Restricted Na diet (~0.8 g/d Na) | NR | 0.8 g/d | 0.8 g/d | 4 (d)

Notes.

a Calculated by the research team based on sodium intake from IV HSS if reported;

b Calculated by the research team based on oral sodium intake from diet if reported;

c Calculated by the research team based on combined sodium intake from IV HSS and oral diet if reported;

d 100 mL of solution was infused during 1 h;

e Initial dose of furosemide was estimated based on the dose previously administered to patient, renal function and body weight, and initial dose could be modified according to the initial patient response with pre-established objective to achieve a weight loss of 500-1000 g/d;

f The dose of HSS was determined according to serum Na (HSS 4.6%, 3.5%, between 1.4% and 2.4% were administered for patients with serum Na < 125 mEq/L, between 126 and 135 mEq/L, > 135 mEq/L respectively);

g Daily dosage of furosemide was defined considering diuretics, urinary volume, BP, severity of signs of symptoms of congestion;

h Once the clinically compensated state was reached, IV furosemide and HSS were stopped and replaced with oral furosemide and oral KCl supplementation, and the best therapy continued without changes after discharge with the standard therapy (eg, ACEIs, digitalis, and nitrates) in both groups;

i The dose of HSS was determined in each patient according to these schedules: for serum Na values <125 mEq/L, the HSS concentration was 3.5% and for serum Na values >135 mEq/L, the HSS concentration varied between 1.4% and 2.4%;

j The dose of HSS was determined in each patient as follows: the HSS concentration 3.5% for serum Na values < 135 mEq/L and between 1.4% and 2.4% for serum Na values > 135 mEq/L;

k All patients underwent an acute saline load with 15 mL/kg of 0.9% NaCl (over 60 min) on the day after the end of the treatment period (6 days);

l Compound hypertonic saline solution: the concentrations of NaCl, KCl, and MgSO4 were 2.8%, 0.2%, and 0.9% respectively;

m Did not clearly define the duration of intervention;

n Furosemide with HSS (N=14) and furosemide bolus (N=14) groups were included in the analysis.

Abbreviations. bI=bolus IV; cIV=continuous intravenous infusion; d=day; g=gram; HSS=hypertonic saline solution; h=hour; IV=intravenous; kg=kilograms; mg=milligram; min=minute; mL=milliliter; Na=sodium; NaCl=sodium chloride; NR=not reported.