# APPENDIX E BASELINE CHARACTERISTICS

Author, Year, PMID | N Analyzed | Race/Ethnicity, % | Age, Mean (SD) or % | Male, % | Clinical Features, Mean (SD) or % | Heart Failure Classification, Mean (SD) or % | Medication History, %
Aliti, 2013, 23689381 | 75 | White, 84; Other races, NR | 60 (11.0) | 69 | NR | LVEF (%), 26.0 (8.7); NYHA III, 47; NYHA IV, 45 | Metoprolol tartrate, 56; Carvedilol, 3; Captopril, 48; Enalapril maleate, 29; ARBs, 11; Spironolactone, 51; Hydralazine, 29; Furosemide, 81; Hydrochlorothiazide, 12
Fabricio, 2019, 31221280 | 44 | NR | 57.9 (12.0) | 59.1 | Weight, 77.1 (23.7); SBP, 109.2 (23.1); DBP, 70.8 (18.2); MAP, 83.7 (19.5); HR, 73.6 (12.2); Serum Na, 135.3 (4.9) | LVEDD (mm), 63.2 (12.2); LVEF (%), 28.9 (12.6) | β-blockers, 79.5^a^; ACEIs, 43.2^a^; ARBs, 20.5^a^; Hydralazine, 29.5^a^; Furosemide, 88.6^a^; Nitrate, 29.5^a^
d’Almeida, 2018, 29793053 | 53 | White, 81.1; Other races, NR | 72.3 (11.7) | 32.1 | SBP, 127.0 (25.9); DBP, 70.5 (12.9) | LVEF (%), 60.9 (7.5); NYHA II, 9.5; NYHA III, 50.9; NYHA IV, 39.6 | β-blockers, 75.5; ACEIs, 64.2; ARBs, 17; Spironolactone, 26.4; Hydralazine, 18.9; Furosemide, 83; Hydrochlorothiazide, 11.3
Inuzuka, 2016 | 190 | NR | 79 (Med) | NR | BNP, 856 (Med) | NYHA II-IV, 100 | NR
Velloso, 1991, 1824218 | 32 | NR | 54 | 56.3 | NR | NYHA III, 28.6% in low sodium diet group; NYHA IV, 71.4% in low sodium diet group | Furosemide, 100; Hydrochlorothiazide, 100; Digitalis, 100; Amiloride, 100
Issa, 2013, 22243938 | 32 | NR | 47.4 (13.1) | 81.3 | BMI, 27.7 (6.1); SBP, 101.6 (15.5); DBP, 65.2 (9.1); Serum Na, 136.7 (3.5) | LVEDD (mm), 71.6 (9.7); LVEF (%), 23.9 (6.3) | β-blockers, 78.1; ACEIs, 56.4; Spironolactone, 43.8; Hydralazine, 56.3; Digoxin, 28.1; Dobutamine, 34.4
Licata, 2003, 12660669 | 107 | NR | 74.6 (7) | 63.6 | SBP, 143.5 (23.5); DBP, 81 (13.5); HR, 83.5 (14); Serum Na, 135.3 (7.5) | LVEF (%), 30.4 (4); NYHA IV, 100 | NR^b^
Mahjoob, 2021, 34903983 | 28 | NR | 65.1(12.9) | 53.6 | Weight, 83.2 (20.5); SBP, 123.3 (19.7); DBP, 72.5 (8.7); HR, 80.3 (72-110) [Med (full range)]; Serum Na, 135.1 (4.1) | NR | NR
Okuhara, 2014, 24462960 | 44 | NR | 72 (10.5) | 68.2 | NR | LVEF (%), 34.5 (26.5,41) [Med (IQR)]; NYHA III, 54.5; NYHA IV, 45.5 | ACEIs/ARBs, 65.9; Loop diuretics, 68.2; Aldosterone antagonists, 40.9; Thiazide diuretics, 15.9; β-blockers, 65.9
Paterna, 2000, 10938493 | 60 | NR | 73.9 (6.9); 65-90 yo (Range) | 65 | Weight, 73.4 (9.2); SBP, 143.5 (25.7); DBP, 81.4 (14.1); HR, 83.3 (14.6); Serum Na, 135.3 (7.4) | LVEF (%), 30.3 (4.3); NYHA IV, 100 | NR
Paterna, 2005, 15963399 | 94 | NR | 74.6 (7) | 63.8 | Weight, 75.9 (15.5); SBP, 145.5 (21.5); DBP, 81 (13.5); HR, 83 (13.5); Serum Na, 134.4 (6.5) | LVEF (%), 30.2 (3); NYHA IV, 100 | NR
Paterna, 2011, 21701268 | 1927 | NR | 74.1(12) | 62.9 | Weight, 83.6 (14); SBP, 135.5 (15.5); DBP, 76 (7.5); HR, 89 (19.5); Serum Na, 138.3 (7.5) | LVEF (%), 34.1 (4.5); NYHA III, 100 | Carvedilol, 69.4; Captopril, 100; Spironolactone, 84.9; Furosemide, 100; Digitalis, 11.5
Parrinello, 2011, 21440872 | 133 | NR | 76.0 (8); 65-82 yo (range) | 64.7 | Weight, 75.9 (15.5); SBP, 134 (23); DBP, 80.5 (12.5); HR, 81.5 (12); Serum Na, 135.5 (5) | LVEF<40%, 100; NYHA IV, 100 | NR^b^
Parrinello, 2012, 22980301 | 248 | NR | 73.5 (9.7) | 59.7 | SBP, 143.5 (23); DBP, 81.0 (12); HR, 84.0 (11); Serum Na, 138.8 5.2) | LVEF<45%, 100; NYHA III or IV, 100 | β-blockers, 46; ACEIs, 100; Spironolactone, 64.9; Furosemide, 62.9; Digitalis, 40.3
Roul, 2017 | 167 | NR | 78 | 55 | NR | NR | NR
Tuttolomondo, 2011, 20346637 | 150^c^ | NR | 65 (61.5, 80.5) [Med (IQR)] | 54 | Weight, 73.5 (69.5, 83) [Med (IQR)]^a^; SBP, 142.5 (134, 150) [Med (IQR)]^a^; DBP, 80.5 (77.5, 95) [Med (IQR)]^a^; HR, 84 (80, 97) [Med (IQR)]; Serum Na, 138 (129.5, 140.5) [Med (IQR)]^a^ | LVEF (%), 37 (28.5, 42.5) [Med (IQR)]; NYHA II, 40; NYHA III, 34.7; NYHA IV, 25.3 | NR
Tuttolomondo, 2021, 34288546 | 136 | NR | 76.2 (7.7) | 49.3 | Weight, 78.1 (14.2); SBP, 127.1 (17.5); DBP, 70.4 (10.5) | LVEF (%), 56.4 (10.6); NYHA II, 16.9; NYHA III, 66.2; NYHA IV, 16.9 | β-blockers, 61; ACEIs, 73.5; ARBs, 13.2; Mineralocorticoid receptor antagonists, 18.4
Wan, 2017, 28701670 | 264 | NR | 60.9 (10.1) | 38.3 | SBP, 143 (17.5; DBP, 67 (10.5); Serum Na: 135.7 (3.6 | LVEF (%), 38.3 (1.6); NYHA III, 100 | β-blockers, 39.4; ACEIs, 85.2; Spironolactone, 91.7; Digitalis, 77.7; Furosemide, 100
Yayla, 2015, 26135463 | 28^d^ | NR | 69.2 (10.4) | 56 | Weight, 81 (17.5); Serum Na, 137.4 (4.8) | LVEF (%), 42.1 (14.2) | β-blockers, 55.8; ACEIs or ARB, 60.5; Aldosterone antagonist, 25.6; Furosemide, 65.1
Montgomery, 2023, 37044281 | 65 | White 86; Black 14 | 70 (12) | 63 | Weight, 100 (29); SBP, 113 (17); DBP, 62 (7.9); HR, 76 (14); Serum Na, 140 (3.4) | LVEF (%), 45 (16) | β-blockers, 72.3; ACEIs or ARB, 32.3; Spironolactone, 52.3; Hydralazine, 52.3; Furosemide, 100

Notes.

a Calculated by the research team based on data of low sodium and normal sodium diet groups;

b Patients received medications (eg, ACEIs, digitalis, nitrates) during the study period; did not report the % of patients;

c NRCS, prospective study with 4 arms (furosemide with HSS group [N=120], furosemide group [N=30], asymptomatic group [N=30], healthy group [N=30]); we included furosemide with HSS group and furosemide group in the analysis;

d Furosemide with HSS (N=14) and furosemide bolus (N=14) groups were included in the analysis.

Abbreviations. ACE=angiotensin converting enzyme; ACEIs= angiotensin converting enzyme inhibitors; ARB=angiotensin receptor blockers; BMI=body mass index; BNP=brain (or B-type) natriuretic peptide; DBP=diastolic blood pressure; LVEDD=left ventricle end-diastolic diameter; LVEF=left ventricular ejection fraction; mm=millimeters; Na=sodium; NR=not reported; NRCS=nonrandomized comparative studies; NYHA= New York Heart Association; SBP=systolic blood pressure; yo=year.