# APPENDIX D DESIGN DETAILS

Author, Year, PMID, Protocol Number, Country | Study Design | Study Dates | Study Location Details (Hospital Type, Centers) | Inclusion Criteria | Exclusion Criteria
Aliti, 2013, 2368938, NCT01133236, Brazil | RCT | 2009-2012 | Academic, Single center | Boston criteria ≥ 8, (LV)EF ≤ 45%; Length of stay of no more than 36 hours after hospital admission, ≥ 18 yo | Cardiogenic shock, endogenous creatinine clearance rate of 30 mL/min/1.73m^2^, survival compromised due to other underlying disease or hinder treatment adherence (eg, dementia, cognitive deficits)
Fabricio, 2019, 31221280, NCT03722069, Brazil | RCT | 2014-2016 | Academic, Single center | Framingham, ≥ 18 yo | ACS, ADHF secondary to acute renal failure, creatinine clearance <30 ml/min/1.73 m^2^, stroke, dementia, severe cognitive impairment, cancer, decompensated DM, severe liver disease, septic shock, acute or chronic primary disease of the renal parenchyma, cerebrovascular accident, nutritional disorders or unable to ingest food by mouth, vomiting, dysphagia, or gastroenteritis
d’Almeida, 2018, 29793053, NCT01896908, Brazil | RCT | 2013-2016 | Academic, Single center | (LV)EF ≥50%, ≥18 yo, Overt clinical signs of congestion, dyspnea, orthopnea in the week before hospitalization, BNP >100 pg/mL | Cardiogenic shock, eGFR ≤ 30 mL/min, HF due to severe valvular disease, difficulty in adhering to treatment (eg, dementia or cognitive deficits)
Inuzuka, 2016, Japan | NRCS | 2011-2012 | Not reported | NYHA: II-IV, median BNP 856 pg/mL | NR
Velloso, 1991, 1824218, Brazil | RCT | NR | Academic, Single center | NYHA: III or IV | Systemic arterial hypertension (upper DBP to 110mmHg), significant pulmonary arterial hypertension, renal insufficiency (serum creatinine > 2mg%), restrictive syndrome cases
Issa, 2013, 22243938; NCT00555685; Brazil | RCT | 2008-2010 | Academic^a^, Single center | ≥18 yo, diagnosed DHF with congestive phenomena, (LV)EF: < 40% | Patient refusal, signs of hypoperfusion, alcohol abuse, primary valvular disease, MI or unstable angina within 6 months, cardiac surgery or angioplasty, restrictive cardiomyopathy, COPD, immunosuppressive therapy, malignant tumors, acute pulmonary embolism, surgical intervention or infections in last 30 days, serum creatinine > 3.0 mg/dL, serum potassium > 5.5 mg/dL, severe systemic disease expected to impair survival, pregnancy or childbearing potential, no clinical parameters of hypoperfusion at the time of enrollment
Licata, 2003, 12660669; Italy | RCT | 1996-1999 | Single center | Refractory CHF according to Framingham criteria and NYHA, uncompensated CHF (dyspnea, weakness, lower limb edema, or anasarca) of NYHA IV, unresponsive to treatment with high oral doses of furosemide and/or combinations of diuretics (thiazide, loop diuretic, and spironolactone), ACEIs, digitalis, nitrates, and receiving this therapy at least 2 weeks before the study and hospitalization.; Patients being unresponsive when they showed with a reduction of urine volume and a constant increase of body weight (BW) and the impairment of clinical signs of CHF despite the increase of furosemide and the combination of other diuretics.; LV(EF) < 35%, serum creatinine < 2 mg/dL, BUN ≤ 60 mg/dL, a reduced urinary volume, and a low natriuresis.; None of the patients had to take non-steroid anti-inflammatory drugs. | NR
Mahjoob, 2021, 34903983; IRCT20200812048380N1; Iran | RCT | 2018-2019 | Academic, Single center^b^ | ≥18 yo with diffuse peripheral edema with no response to oral furosemide (80 mg), patients with proteinuria and edema resistant to treatment and nephrotic syndrome | Candidate for hemodialysis, pacemaker implantation, SBP ≤ 80 mmHg, GFR ≤ 15 mL/min, serum albumin ≤ 2.5 g/dL, serum potassium ≥ 5.5 mEq/L, serum sodium > 145 mEq/L, urine volume ≤ 100 mL/d, dementia, cerebral vascular disease, substance or alcohol addiction, receiving mineralocorticoids, inability to give informed consent
Okuhara, 2014, 24462960; Japan | RCT | 2011-2012 | Academic, Single center^c^ | ADHF with symptoms of NYAH III/IV and SBP > 80 mmHg, eGFR > 15 mL/min/1.73 m^2^, serum sodium < 148 mmol/L | Use of inotropic agents, carperitide, hemodiafiltration or noninvasive positive pressure ventilation (NPPV), complicated by systemic infection, ACS, or distinct endocrine diseases (eg, syndrome of inappropriate secretion of antidiuretic hormone)
Paterna, 2000, 10938493; Italy | RCT | 1996-1998 | NR | Refractory CHF according to Framingham criteria and NYHA, DCHF (dyspnea, weakness, lower limb edema, or anasarca) of NYHA IV, unresponsive to treatment with high oral doses of furosemide and/or combinations of diuretics (thiazide, loop diuretic, and spironolactone), ACEIs, digitalis, nitrates, and receiving this therapy at least 2 weeks before the study and hospitalization. Patients being unresponsive with a reduction of urine volume and a constant increase of body weight and impairment of clinical signs of CHF despite the increase of furosemide and the combination of other diuretics.; LV(EF) < 35%, serum creatinine < 2 mg/dL, BUN ≤ 60 mg/dL, a reduced urinary volume, and a low natriuresis. None of the patients had to take non-steroid anti-inflammatory drugs. | NR
Paterna, 2005, 15963399, Italy | RCT | 2000-2002 | NR | Refractory CHF according to Framingham criteria and NYHA, DCHF (dyspnea, weakness, lower limb edema, or anasarca) of NYHA IV, unresponsive to treatment with high oral doses of furosemide and/or combinations of diuretics (thiazide, loop diuretic, and spironolactone), ACEIs, digitalis, nitrates for at least 2 weeks before the study and hospitalization. Patients being unresponsive with a reduction of urine volume and a constant increase of body weight and impairment of clinical signs of CHF despite the increase of furosemide and the combination of other diuretics.; LV(EF) < 35%, serum creatinine < 2 mg/dL, BUN ≤ 60 mg/dL, a reduced urinary volume (<500 ml/24 h), and a low natriuresis. None of the patients had to take non-steroid anti-inflammatory drugs | NR
Paterna, 2011, 21701268; NCT01156337; Italy | RCT | 2000-2007 | Academic, Single center^d^ | DHF by chronic ischemic or nonischemic cardiomyopathy, > 18 years, Framingham criteria and NYHA functional classification for HF, uncompensated HF (dyspnoea, weakness and lower limb edema), in NYHA III functional class, was unresponsive to treatment with oral high doses of furosemide, spironolactone, ACEIs, digitalis nitrates at least 4 weeks before the study and before hospitalization. Patients were judged unresponsive with a reduction of urine volume, a constant increase of body weight and an impairment of clinical HF despite the increase of furosemide.; LV(EF) < 40%, serum creatinine < 2.5 mg/dL, BUN < 60 mg/dL and reduced urinary volume (800 mL/d) despite the established treatments. No patients received NSAIDs. | NYHA class < III or > III on admission or with NYHA class III at discharge, with concomitant main comorbidities, cerebral vascular disease, dementia, cancer, uncompensated diabetes, severe hepatic disease, inability to give informed consent, requiring pacemaker implantation and those with an alcoholic habit, declined to take part in the study protocol, patients with side effects for ACEI treatment (cough), patients who did not follow the assigned treatment, did not attend the scheduled clinical visits, did not adhere to prescribed diet and the fluid intake of 1000 mL/day or had a reduction or discontinuation of prescribed treatments during follow-up.
Parrinello, 2011, 21440872; Italy | RCT | 2007-2008 | Academic, Single center | Framingham criteria, NYHA functional classification for CHF; DCHF (dyspnea, weakness, lower limb edema or anasarca), NYHA functional class IV, unresponsive to treatment with oral high doses of furosemide and combinations of diuretics (thiazide, furosemide, and spironolactone), ACEIs, digitalis, beta-blockers, nitrates for at least 2 weeks before the study and hospitalization. Patients being unresponsive with reduction in urine volume, a constant increase in body weight, and an impairment in the clinical signs of HF, despite the increase in furosemide and its combination with other diuretics.; LV(EF) < 40%; serum creatinine < 2.0 mg/d; BUN < 60 mg/dL; reduced urinary volume (<500 mL/24 h); low natriuresis (< 60 mEq/24 h), despite having received the established treatments and no cardiac resynchronization therapy. None of the patients had taken NSAIDs. | Patients unable to provide informed consent; those with cardiac resynchronization therapy (to avoid interference with echocardiographic measurements); patients with concomitant important comorbidities, such as end-stage of renal insufficiency or those on dialysis; uncompensated diabetes; cerebral vascular disease; dementia; cancer; liver cirrhosis or other edematous syndromes; patients being treated with steroids or nonsteroidal antiinflammatory drugs (NSAIDs) or who were alcohol dependent; and those who did not follow the treatment protocol (a fluid intake of 1,000 mL day and prescribed sodium diet). In addition, patients with side effects for ACE inhibitors (a cough), even if these patients were taking angiotensin-2 blockers, were excluded from the study to maximize the homogeneity of the treatments.
Parrinello, 2012, 22980301; NCT01419132; Italy | RCT | 2011 | Academic, Single center | ADHF according to the AHA/ESC guidelines and who met criteria on hospital admission as follows; signs/symptoms of HF; NYHA functional class III or IV on admission due to an exacerbation of symptoms with at least 1 class deterioration; evidence of systolic dysfunction on echocardiographic examination on admission ([EF] < 45%); BNP levels on admission > 100 pg/mL.; 18-95 yo | NYHA class < III on admission; patients with ASC, pulmonary thromboembolism, cardiac tamponade, pericarditis, renal insufficiency (serum creatinine > 2.5 mg/dL, BUN > 60 mg/dL), dialysis, chronic liver disease, pleuropneumonia, blood and autoimmune diseases, concomitant other important comorbidity, cerebral vascular disease, dementia, cancer, or uncompensated diabetes; decline to provide informed consent, patients requiring pacemaker implantation and those with issues of excessive alcohol consumption. None of the patients took NSAIDS.
Roul, 2017; France | NRCS, Retrospective | 2013-2015 | Single center | Patients admitted for heart failure with low plasma sodium level at entry or treated with hypertonic saline solution during hospitalization | NR
Tuttolomondo, 2011, 20346637; Italy | NRCS, Prospective | 2005-2009 | Single center | Patients admitted with heart failure according to ESC or NYHA functional class II or worse plus objective evidence of cardiac dysfunction (LV)EF: < 30% or abnormal diastolic function echocardiographically detected, normal systolic function at rest without signs of CHF | Acute myocarditis, active pulmonary and liver disease, autoimmune disorders, infections, malignant diseases, muscle diseases, renal insufficiency (serum creatinine ≥ 2.5 mg/dL), chronic inflammatory diseases, rheumatological diseases, hematological disease, regular treatment with anti-inflammatory drugs
Tuttolomondo, 2021, 34288546; NCT04628325; Italy | RCT | 2017-2019 | Single center^e^ | ADHF due to HFrEF according to the European Society of Cardiology (ESC) criteria or NYHA functional class II or worse plus objective evidence of cardiac dysfunction; (LV)EF < 40%, >18 yo | Acute myocarditis, active pulmonary and liver disease, autoimmune disorders, infections, malignant diseases, muscle disorders, renal insufficiency (serum creatinine ≥ 2.5 mg/dL), chronic inflammatory diseases, rheumatological diseases, hematological diseases, regular treatment with anti-inflammatory drugs.
Wan, 2017, 28701670; China | RCT | 2017 | Single center | DHF (dyspnoea, weakness, lower limb edema or anasarca) and chronic ischemic or nonischemic cardiomyopathy according to the definition of HF, Framingham criteria, and NYHA functional classification for HF; unresponsive to treatment with high doses of furosemide, spironolactone, ACEIs, digitalis, and nitrates (reduction of urine volume, a constant increase of body weight, and impairments caused by clinical HF as reported above, in spite of an increase in furosemide and a combination of other diuretics; had started this therapy at least 6 months before hospitalization.; LV(EF) < 40%, serum creatinine < 1.73 mg/dL, BUN < 60 mg/dL, urinary volume < 500 mL/d. | Age < 18 years; plasma albumin < 30 g/L; cancer, severe diabetes, cerebral vascular disease, dementia, or severe hepatic disease; NYHA class > III or < III on admission; or with NYHA class III at discharge; failure to follow the assigned treatment; did not attend scheduled clinical visits, did not follow the prescribed diet, or serious water or activity restrictions.
Yayla, 2015, 26135463; Turkey | RCT | 2011-2012 | Academic, Single center | ADHF with reduced or preserved LVEF, Patients who were admitted to the emergency department within the previous 24 h with diagnosis of ADHF, pro-BNP > 300 pg/ml | IV diuretic use before admission to hospital, serum creatinine levels > 2.0 mg/dl, SBP < 90 mmHg; requiring IV vasodilators or inotropic agents other than digoxin, patients with suspected ACS
Montgomery, 2023, 37044281; United States | RCT | 2020-2022 | Academic, Single center | ≥ 18 yo, admitted to cardiology floor (non-ICU) with primary diagnosis of DHF, NT-proBNP >1000 ng/L, Initiation of continuous furosemide infusion of ≥ 10 mg/hr | Renal replacement therapy, ultrafiltration, eGFR < 15mL/min/1.73m2, average SBP > 180mmHg, DBP > 100mmHg for 24 h, serum sodium concentration <120mEq/L or >145mEq/L, admission with intention to undergo open heart surgery, inability to swallow or absorb oral medications, diagnosis of diabetes insipidus, use of IV inotropes, vasopressors or vasodilators at enrollment, anticipated stay of fewer than 72 h, use of intravenous radiocontrast in the prior 72 h or anticipated use during current hospitalization, current use of NaCl tablets or vasopressin antagonist medication.

Notes.

a Tertiary hospital dedicated to cardiology;

b Patients admitted to post CCU ward;

c Patients admitted to Division of Cardiovascular Medicine;

d Patients admitted to Emergency Medicine and Cardiology Department;

e Patients admitted to Internal Medicine ward.

Abbreviations. ACE=angiotensin converting enzyme; ACEI= angiotensin converting enzyme inhibitor; ACS=acute coronary syndrome; ADHF=acute decompensated heart failure; AHA=American Heart Association; BNP=brain (or B-type) natriuretic peptide; BP=blood pressure; BUN=blood urea nitrogen; CCU=critical care unit; COPD=chronic obstructive pulmonary disease; DBP=diastolic blood pressure; DHF=decompensated heart failure; DM=diabetes mellitus; ED=emergency department; eGFR=estimated glomerular filtration rate; ESC=European Society of Cardiology; GFR=glomerular filtration rate; h=hour; HF=heart failure; ICU=intensive care unit; IV=intravenous; LVEF=left ventricular ejection fraction; m=meter; MI=myocardial infraction; min=minute; mL=milliliter; mmHg= millimeters of mercury; NR=not reported; NRCS=nonrandomized comparative studies; NSAIDs=non-steroidal anti-inflammatory drugs; NT-proBNP=N-terminal pro-brain (or B-type) natriuretic peptide; NYHA= New York Heart Association; pro-BNP= pro B-type Natriuretic Peptide; RAAS= renin-angiotensin-aldosterone system; RCT=randomized controlled trial; SBP=systolic blood pressure; yo=years old.