# APPENDIX C CRITERIA USED IN QUALITY ASSESSMENT

Question | | Yes | No | Unclear
Clarity
1. | Clear reporting with no discrepancies (Y/N)
2. | Were eligibility criteria clear? (Y/N)
3. | Were interventions adequately described? (Y/N)
4. | Were the outcomes fully defined? (Y/N)
Bias Assessment
5. | Random sequence generation: Selection bias (biased allocation to interventions) due to inadequate generation of a randomized sequence.
6. | Allocation concealment: Selection bias (biased allocation to interventions) due to inadequate concealment of allocations prior to assignment.
7. | Blinding of participants and personnel: Performance bias due to knowledge of the allocated interventions by participants during the study.
8. | Blinding of outcome assessor (detection bias): Detection bias due to knowledge of the allocated interventions by outcome assessors.
9. | Incomplete outcome data (attrition bias): Attrition bias due to amount, nature or handling of incomplete outcome data.
10. | Selective Reporting (reporting bias): Reporting bias due to selective outcome reporting.
11. | Intention-to-treat-analysis: Bias due to incomplete reporting and analysis according to group allocation.
12. | If observational study, comparator group was sufficiently similar (and selected patients were all included or a random sample were included).
13. | If observational study, Adjustment for confounders.; a. Crude analysis (unadjusted comparison between ADP and no ADP) [High RoB]; b. Regression adjustment or patient-matching (accounting for at least age, sex, and symptom duration OR a risk score) [Low RoB]; c. Regression adjustment or patient-matching (not accounting at least one of for age, sex, symptom duration, or risk score) [Moderate RoB]; d. Propensity score analysis (or equivalent) [Low RoB]

Author, Year, PMID, Design | Free of Discrepancies | Eligibility Clear | Intervention Clear | Outcomes Adequately Defined | Blinding | | Incomplete Outcome Data | Selective Reporting | RCT | | | NRCS | | Overall RoB
Author, Year, PMID, Design | Free of Discrepancies | Eligibility Clear | Intervention Clear | Outcomes Adequately Defined | Participants and Personnel | Outcome Assessor | Incomplete Outcome Data | Selective Reporting | Random Sequence Generation | Allocation Concealment | ITT | Comparator Group Similar | Confounder Adjustment | Overall RoB
Dietary Interventions
Aliti, 2013, 23689381, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (high concern) | Yes (low concern) | No (low concern) | No (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | N/A | N/A | Low RoB (RCT)
Fabricio, 2019, 31221280, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (high concern) | Yes (low concern) | Yes (high concern)^a^ | No (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | N/A | N/A | High RoB (RCT)
D’Almeida, 2018, 29793053, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (high concern) | Yes (low concern) | No (low concern) | No (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | N/A | N/A | Low RoB (RCT)
Velloso, 1991, 1824218, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (high concern) | Yes (low concern) | Unclear | Unclear | No (high concern)^b^ | No (high concern)^b^ | Unclear | N/A | N/A | High RoB (RCT)
Inuzuka, 2016, NRCS^c^ | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (high concern) | N/A | Unclear | Unclear | Unclear | N/A | N/A | N/A | Yes (low concern) | Yes (low concern) | Moderate RoB (NRCS)
Saline Solution Interventions
Issa, 2013, 22243938, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low concern) | No (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | N/A | N/A | Low RoB (RCT)
Paterna, 2005, 15963399, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low concern) | No (low concern) | No (high concern)^d^ | No (high concern)^d^ | Yes (low concern) | N/A | N/A | High RoB (RCT)
Wan, 2017, 28701670, RCT | No (high concern)^e^ | Yes (low concern) | Yes (low concern) | No (high concern)^f^ | No (high concern) | No (high concern) | No (low concern) | No (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | N/A | N/A | High RoB (RCT)
Mahjoob, 2021, 34903983, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Unclear | Yes (low concern) | No (low concern) | No (low concern) | Yes (low concern) | Unclear | Yes (low concern) | N/A | N/A | Moderate RoB (RCT)
Tuttolomondo, 2011, 20346637, NRCS | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Unclear | Yes (low concern) | No (low concern) | No (low concern) | N/A | N/A | N/A | Yes (low concern) | No (high concern)^g^ | High RoB (NRCS)
Licata, 2003, 12660669, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (high concern) | Yes (low concern) | No (low concern) | No (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | N/A | N/A | Low RoB (RCT)
Paterna, 2000, 10938493, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (high concern) | Yes (low concern) | Unclear | No (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | N/A | N/A | Moderate RoB (RCT)
Paterna, 2011, 21701268, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (high concern) | Yes (low concern) | No (low concern) | No (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | N/A | N/A | Low RoB (RCT)
Parrinello, 2012, 22980301, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low concern) | No (low concern) | Yes (low concern) | Unclear | Yes (low concern) | N/A | N/A | Low RoB (RCT)
Yayla, 2015, 26135463, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (high concern)^h^ | Yes (low concern) | Yes (low concern) | No (low concern) | No (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | N/A | N/A | Low RoB (RCT)
Parrinello, 2011, 21440872, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low concern) | No (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | N/A | N/A | Low RoB (RCT)
Tuttolomondo, 2021, 34288546, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (high concern) | Yes (low concern) | No (low concern) | No (low concern) | Yes (low concern) | Unclear | Yes (low concern) | N/A | N/A | Moderate RoB (RCT)
Okuhara, 2014, 24462960, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Unclear | Yes (low concern) | No (low concern) | No (low concern) | Yes (low concern) | Unclear | Yes (low concern) | N/A | N/A | Low RoB (RCT)
Roul, NRCS^c^ | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (high concern) | Unclear | Yes (low concern) | Unclear | Unclear | N/A | N/A | N/A | No (high concern) | No (high concern) | High RoB (NRCS)
Montgomery, 2023, 37044281, RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low concern) | No (low concern) | Yes (low concern) | Unclear | Yes (low concern) | N/A | N/A | Low RoB (RCT)

Notes.

a 30% of participants had missing outcome data;

b Randomization based on odd or even of medical record number;

c Conference abstract with limited methodological details;

d assignment of patient was decided by an independent physician;

e Sample sizes and outcome events in the table are different than in text;

f Outcomes not clearly defined in the methods section;

g Match treatment and comparison group by age and sex and then conducted unadjusted comparisons;

h For outcomes reported once patients reach compensated state; unclear when this occurred.

Abbreviations. ITT=intention to treat; NRCS=nonrandomized comparative study; RCT=randomized controlled trial.