# APPENDIX B EXCLUDED STUDIES

1 Abshire M, Xu J, Baptiste D, . Nutritional interventions in heart failure: a systematic review of the literature. Journal of Cardiac Failure. 2015;21(12):989–999. Systematic Review.26525961
2 Biao F, Huang L. GW27-e1005 Liberal versus restricted fluid administration in heart failure patients: a meta-analysis of 6 randomized trials. Journal of the American College of Cardiology. 2016;68(16_Supplement):C149–C149. doi:doi:10.1016/j.jacc.2016.07.561. Systematic Review.
3 Biegus J, Zymlinski R, Siwolowski P, . Controlled decongestion by Reprieve therapy in acute heart failure: results of the TARGET-1 and TARGET-2 studies. European Journal of Heart Failure. 2019;21(9):1079–1087. Not sodium intake.31127666
4 Bikdeli B, Strait KM, Dharmarajan K, . Intravenous fluids in acute decompensated heart failure. JACC: Heart Failure. 2015;3(2):127–133. Not sodium intake.25660836
5 Bocchi E. Hypertonic saline solution in heart failure. 2008. ClinicalTrials identifier: NCT00555685. https://clinicaltrials.gov/study/NCT00555685. No additional results reported.
6 Castro-Gutiérrez V, Rada G. Should sodium intake be restricted in chronic heart failure? Medwave. 2016;16(Suppl5). Other; not hospitalized only/This is not primary study but literature review for SRs.
7 Chimparlee N. Effects of salt and fluid restriction on dyspnea in patients with acute decompensated heart failure. 2020. ICTRP identifier: TCTR20200508002. https://trialsearch.who.int/Trial2.aspx?TrialID=TCTR20200508002. No additional results reported.
8 Colin-Ramirez E, Sepehrvand N, Rathwell S, . Sodium restriction in patients with heart failure: A systematic review and meta-analysis of randomized clinical trials. Circulation: Heart Failure. 2023;16(1):e009879. Systematic Review.36373551
9 Covic A, Copur S, Tapoi L, . Efficiency of hypertonic saline in the management of decompensated heart failure: a systematic review and meta-analysis of clinical studies. American Journal of Cardiovascular Drugs. 2021;21:331–347. Systematic Review.33210263
10 Crane C, Hertel A, Hobza C, Menard JR. Does hypertonic saline infusion with furosemide improve outcomes for patients with acute CHF exacerbation? Evidence-Based Practice. 2018;21(2):E5–E6. Other; help desk answer.
11 d’Almeida KSM, Trojahn MM, Barilli SLS, . Preliminary results of a randomized clinical trial on the effect of fluid and dietary sodium restriction in the management of patients with heart failure and preserved ejection fraction. Journal of Cardiac Failure. 2016;22(8):S63. No additional results reported.
12 da Silva E. Effect of dietary sodium restriction in the management of patients with heart failure and diastolic dysfunction. 2013. ClinicalTrials.gov identifier: NCT01896908. https://clinicaltrials.gov/show/NCT01896908. No additional results reported.
13 d’Almeida KS, Rabelo-Silva ER, Souza GC, . Effect of fluid and dietary sodium restriction in the management of patients with heart failure and preserved ejection fraction: study protocol for a randomized controlled trial. Trials. 2014;15:1–6. No additional results reported.24382030
14 De Vecchis R, Baldi C, Cioppa C, Giasi A, Fusco A. Effects of limiting fluid intake on clinical and laboratory outcomes in patients with heart failure. Herz. 2016;41(1):63. Systematic Review.26292805
15 De Vecchis R, Esposito C, Ariano C, Cantatrione S. Hypertonic saline plus iv furosemide improve renal safety profile and clinical outcomes in acute decompensated heart failure. Herz. 2015;40(3):423. Systematic Review.24682291
16 De Vecchis R, Paccone A, DiMaio M. Effects of a restricted water intake on various clinical and laboratory outcomes in patients with heart failure: a meta-analysis of randomized controlled trials. Minerva Cardioangiologica. Retracted.
17 DiNicolantonio JJ, Di Pasquale P, Taylor RS, Hackam DG. Low sodium versus normal sodium diets in systolic heart failure: systematic review and meta-analysis. Heart. 2012. Systematic Review.
18 DiNicolantonio JJ, Pasquale PD, Taylor RS, Hackam DG. Low sodium versus normal sodium diets in systolic heart failure: Systematic review and meta-analysis. Heart. Retracted.
19 Engelmeier R. Safety and efficacy of low dose hypertonic saline solution and high dose furosemide for congestive heart failure (REaCH). 2009. ClinicalTrials.gov identifier: NCT01028170. https://clinicaltrials.gov/show/NCT01028170. No additional results reported.
20 Engelmeier RS, Le TT, Kamalay SE, . Randomized trial of high dose furosemide-hypertonic saline in acute decompensated heart failure with advanced renal disease. Journal of the American College of Cardiology. 2012;59(13S):E958–E958. Not sodium intake.
21 Fabrício CG, Gentil JR, Amato CA, Marques F, Schwartzmann PV, Simões MV. Prospective, randomized and blinded clinical study testing two levels of dietary sodium intake in patients with acute decompensated heart failure. Journal of Cardiac Failure. 2016;22(8):S55. No additional results reported.
22 Fasullo S, Basile I, Sarullo F, . Sodium management in acute and chronic phases in patients with New York Heart Association class III (class C) heart failure. Short- and long-term findings. Journal article; Conference proceeding. Giornale Italiano di Cardiologia. 2011;12(5):7S. doi:10.1714/641.7476. No additional results reported.
23 Gandhi S, Mosleh W, Myers RB. Hypertonic saline with furosemide for the treatment of acute congestive heart failure: A systematic review and meta-analysis. International Journal of Cardiology. 2014;173(2):139–145. Systematic Review.24679680
24 García-García A, Alvarez-Sala-Walther LA, Lee H-Y, Sierra C, Pascual-Figal D, Camafort M. Is there sufficient evidence to justify changes in dietary habits in heart failure patients? A systematic review. The Korean Journal of Internal Medicine. 2022;37(1):37. Systematic review.34482681
25 Gaspare, P. Troponin I release after high diuretic doses (Tra-HSS-Fur).2011. ClinicalTrials.gov identifier: NCT01419132. https://clinicaltrials.gov/study/NCT01419132. No additional results reported.
26 Guglin M. Low sodium vs. regular diet in patients admitted for heart failure (SALT). 2016. Clinicaltrials.gov identifier: NCT02689635. https://clinicaltrials.gov/show/NCT02689635. No additional results reported.
27 He L, Sun L, Yang Y, . Clinical experience of supplying sodium chloride for the treatment of patients with severe heart failure. Zhonghua xin xue Guan Bing za zhi. 2012;40(9):766–769. Not sodium intake.23141090
28 Ingrassia O. Sodium management in acute and chronic heart failure (SMAC-HF). 2000. ClinicalTrials.gov identifier: NCT01156337. https://ClinicalTrials.gov/show/NCT01156337. No additional results reported.
29 Inuzuka Y, Kishimori T, Inoue T, . Sodium restriction in Japanese patients hospitalized with acute decompensated heart failure. Journal of Cardiac Failure. 2015;21(10):S183. No additional results reported.
30 Issa V, Ayub-Ferreira S, Bacal F, . Prevention of renal dysfunction with hypertonic saline solution in patients with decompensated heart failure: a prospective, double blind, randomized, placebo-controlled trial. European Heart Health. 2011:162–163. No additional results reported.
31 Issa VS, Ayub-Ferreira S, Bacal F, . Hypertonic saline solution for prevention of renal dysfunction in patients with decompensated heart failure (HYSS-HF STUDY): A double-blind, randomized controlled trial. Journal of the American College of Cardiology. 2011;57(14S):E218–E218. No additional results reported.
32 Issa VS, Bacal F, Mangini S, . Hypertonic saline solution for renal failure prevention in patients with decompensated heart failure. Arquivos Brasileiros de Cardiologia. 2007;89:251–255. No additional results reported.17992382
33 Issa VS, Bacal F, Mangini S, . Hypertonic saline solution for renal failure prevention in patients with decompensated heart failure. Arquivos Brasileiros de Cardiologia. 2007;89:251–255. Other; pre-post (N=9).17992382
34 Issa VS, Ayub-Ferreira S, Bacal F, . Hypertonic saline solution for prevention of renal dysfunction in patients with decompensated heart failure-prospective, double blind, randomized, placebo-controlled trial. European Heart Health. No additional results reported.
35 Krim SR, Campbell PT, Desai S, . Management of patients admitted with acute decompensated heart failure. Ochsner Journal. 2015;15(3):284–289. Other; Literature review.26413005
36 Lee Y-W, Huang L-H, Ku C-H. Use of dietary sodium intervention effect on neurohormonal and fluid overload in heart failure patients: Review of select research based literature. Applied Nursing Research. 2018;42:17–21. Systematic Review.30029710
37 Li Z, Wang Z, Liu N, Li H. Effect of hypertonic saline solution combined with furosemide on acute heart failure: A meta-analysis. Computational and Mathematical Methods in Medicine. 2022: 5728967. Systematic Review.
38 Liu C, Peng Z, Gao X, . Simultaneous use of hypertonic saline and IV furosemide for fluid overload: A systematic review and meta-analysis. Critical Care Medicine. 2021;49(11):e1163–e1175. Systematic Review.34166286
39 Mahtani KR, Heneghan C, Onakpoya I, . Reduced salt intake for heart failure: a systematic review. JAMA Internal Medicine. 2018;178(12):1693–1700. Systematic Review.30398532
40 Nalos M. 0.5M Na Lactate solution in acute heart failure (AHF) (SOLACE1). 2009. ClinicalTrials identifier: NCT01981655. https://clinicaltrials.gov/study/NCT01981655. Not sodium intake.
41 Nouira S. Impact of hypertonic saline solution on acute decompensated heart failure (HSS). 2018. ClinicalTrials.gov identifier: NCT05298098. https://clinicaltrials.gov/show/NCT05298098. No additional results reported.
42 Okuhara Y. Evaluation of neurohumoral factors and water clearance for treating acute decompensated heart failure with salt. 2017. ICTRP identifier: JPRN-UMIN000029129. https://trialsearch.who.int/Trial2.aspx?TrialID=JPRN-UMIN000029129. No additional results reported.
43 Patel N, Patel M, Elzanaty A, . Efficacy and safety of hypertonic saline solution with furosemide in patients with acute decompensated heart failure: A systematic review and meta-analysis. Journal of the American College of Cardiology. 2021;77(18_Supplement_1):611–611. Systematic Review.
44 Paterna S, Di Gaudio F, La Rocca V, . Hypertonic saline in conjunction with high-dose furosemide improves dose–response curves in worsening refractory congestive heart failure. Advances in Therapy. 2015;32:971–982. Not sodium intake.26521190
45 Reilly CM, Anderson KM, Baas L, . American Association of Heart Failure Nurses Best Practices paper: Literature synthesis and guideline review for dietary sodium restriction. Heart & Lung: The Journal of Cardiopulmonary and Acute Care. 2015;44(4):289–298. Systematic Review.
46 Shaughnessy A. Is furosemide and hypertonic saline more effective than furosemide alone for severe heart failure? Evidence Based Practice. No additional results reported.
47 Silva-Neto, L. Fluid and salt restriction in decompensated heart failure patients. 2009. ClinicalTrials identifier: NCT01133236. https://clinicaltrials.gov/study/NCT01133236. No additional results reported.
48 Simão DO, da Costa RJ, Verneque BJF, do Amaral JF, Chagas GM, Duarte CK. Sodium and/or fluid restriction and nutritional parameters of adult patients with heart failure: A systematic review and meta-analysis of randomized controlled trial. Clinical Nutrition ESPEN. 2021;45:33–44. Systematic Review.34620336
49 Simões M. Dietary sodium intake in acute heart failure (SODIC). 2014. ClinicalTrials.gov identifier: NCT03722069. https://clinicaltrials.gov/study/NCT03722069. No additional results reported.
50 Sousa MM, Gouveia BLA, Almeida TCF, Freire MEM, Melo FABP, Oliveira SHS. Evidence related to sodium restriction in patients with heart failure. Revista Brasileira de Enfermagem. 2020;73. Outpatient CHF.
51 Stein C, Helal L, Migliavaca CB, . Are the recommendation of sodium and fluid restriction in heart failure patients changing over the past years? A systematic review and meta-analysis. Clinical Nutrition ESPEN. 2022;49:129–137. Systematic Review.35623804
52 Tang, WH. Oral Sodium to Preserve Renal EfficiencY in Acute Heart Failure (OSPREY-AHF). 2020. ClinicalTrials.gov identifier: NCT04334668. https://clinicaltrials.gov/study/NCT04334668. No additional results reported.
53 Torres GS, Posadas C, Tena I, Boyer J, Enríquez C. Use of a normal sodium diet in the diuretic treatment of refractory cardiac insufficiency. Archivos del Instituto de Cardiologia de Mexico. 1982;52(6):507–515. Not sodium intake.7159133
54 Vijayan A. Concentrated saline infusions and increased dietary sodium with diuretics for heart failure with kidney dysfunction. 2007. ClinicalTrials.gov identifier: NCT00575484. https://clinicaltrials.gov/show/NCT00575484. No additional results reported.
55 Wu S, Alikhil M, Forsyth R, Allen B. Impact of potentially unwarranted intravenous antibiotics targeting pulmonary infections in acute decompensated heart failure. Journal of Pharmacy Technology. 2021;37(6):298–303. Not sodium intake.
56 Yang J. Tolvaptan for treatment of decompensated heart failure patients with diuretic resistance and hyponatremia. Academic Journal of Second Military Medical University. 2015:1133–1137. Not sodium intake.
57 Yayla C, Akyel A, Canpolat U, . Comparison of three different diuretic treatment strategies in acute decompensated heart failure patients. European Heart Journal. 2017;38. No additional results reported.
58 Zepeda P, Rain C, Sepúlveda P. What are the effects of hypertonic saline plus furosemide in acute heart failure. Medwave. 2015;15(Suppl 2):e6233. Systematic Review.26335942
59 Zhu C, Cheng M, Su Y, Ma T, Lei X, Hou Y. Effect of dietary sodium restriction on the quality of life of patients with heart failure: A systematic review of randomized controlled trials. Journal of Cardiovascular Nursing. 2022;37(6):570–580. Systematic Review.34954741
60 Ezekowitz JA, Colin-Ramirez E, Ross H, . Reduction of dietary sodium to less than 100 mmol in heart failure (SODIUM-HF): an international, open-label, randomised, controlled trial [published correction appears in Lancet. 2022 Oct 8;400(10359):1194]. Lancet. 2022;399(10333):1391–1400. doi:10.1016/S0140-6736(22)00369-5 35381194