# APPENDIX A SEARCH STRATEGIES

## MEDLINE

(((“Heart Failure”[Mesh] or ((heart failure[tiab] or cardiac failure[tiab] or myocardial failure[tiab] or CHF[tiab]) AND (hospital* OR inpatient OR “Acute Disease”[Mesh] or acute[tiab] or decompensated[tiab])) OR heart decompensation[tiab]) AND (“Saline Solution, Hypertonic”[Mesh] OR Hypertonic Saline OR Hypertonic sodium chloride OR HSS OR salt hypertonic OR Sodium tablets OR “Saline Solution”[Mesh] OR Intravenous saline OR Normal saline OR Hypotonic saline OR Saline solution OR Lactate* ringer’s OR “Ringer’s Lactate”[Mesh] OR “Diet, Sodium-Restricted”[Mesh] or sodium-restrict* or salt-restrict* or sodium-free or salt-free or low-salt or low-sodium or reduced-salt or reduced-sodium or ((sodium[tiab] or salt[tiab]) AND (restrict*[tiab] or reduc*[tiab] or low[tiab] or free[tiab])))) NOT (“address”[pt] OR “autobiography”[pt] OR “bibliography”[pt] OR “biography”[pt] OR “case reports”[pt] OR “comment”[pt] OR “congress”[pt] OR “dictionary”[pt] OR “directory”[pt] OR “festschrift”[pt] OR “government publication”[pt] OR “historical article”[pt] OR “interview”[pt] OR “lecture”[pt] OR “legal case”[pt] OR “legislation”[pt] OR “news”[pt] OR “newspaper article”[pt] OR “patient education handout”[pt] OR “periodical index”[pt] OR “comment”[ti] OR “Editorial”[Publication Type] OR “ephemera”[pt] OR “in vitro techniques”[mh] OR “introductory journal article”[pt] OR (“Animals”[Mesh] NOT “Humans”[Mesh]) OR (child[Mesh] NOT adult[Mesh]) OR rats[tw] OR rat[tw] OR cow[tw] OR cows[tw] OR chicken*[tw] OR horse[tw] OR horses[tw] OR mice[tw] OR mouse[tw] OR bovine[tw] OR sheep[tw] OR ovine[tw] OR murinae[tw] OR cats[tw] OR cat[tw] OR dog[tw] OR dogs[tw] OR rodent[tw])) AND (“Cohort Studies”[Mesh] OR cohort OR “Clinical Trial” [Publication Type] OR (follow-up OR followup) OR longitudinal OR “Placebos”[Mesh] OR placebo* OR “Research Design”[Mesh] OR “Evaluation Study” [Publication Type] OR “Comparative Study” [Publication Type] OR ((comparative OR Intervention) AND study) OR pretest* OR posttest* OR prepost* OR “before and after” OR interrupted time* OR time serie* OR intervention* OR ((quasi-experiment* OR quasiexperiment* OR quasi OR experimental) AND (method OR study OR trial OR design*)) OR “real world” OR “real-world” OR “Case-Control Studies”[Mesh] OR (case AND control) OR “Random Allocation”[Mesh] OR “Clinical Trial” [Publication Type] OR “Double-Blind Method”[Mesh] OR “Single-Blind Method”[Mesh] OR random* OR “Placebos”[Mesh] OR placebo OR ((clinical OR controlled) AND trial*) OR ((singl* OR doubl* OR trebl* OR tripl*) AND (blind* OR mask*)) OR rct OR crossover OR cross-over OR cross-over OR “treatment switching” OR “Treatment Switching”[Mesh] OR RCT OR “Randomized Controlled Trial” [Publication Type] OR systematic[sb] OR meta-analysis[pt] OR meta-analysis as topic[mh] OR meta-analysis[mh] OR meta analy* OR metanaly* OR metaanaly* OR met analy* OR (systematic AND (review* OR overview*)) OR “Review Literature as Topic”[Mesh] OR cochrane[tiab] OR embase[tiab] OR (psychlit[tiab] or psyclit[tiab]) OR (psychinfo[tiab] or psycinfo[tiab]) OR (cinahl[tiab] or cinhal[tiab] OR “cumulative index to nursing and allied health”) OR science citation index[tiab] OR ibids[tiab] OR “international bibliographic information on dietary supplements” OR cancerlit[tiab] OR reference list*[tiab] OR bibliograph*[tiab] OR hand-search*[tiab] OR relevant journals[tiab] OR manual search*[tiab] OR ((selection OR inclusion OR exclusion) AND criteria[tiab]) OR data extraction[tiab] OR relevant journals OR “Systematic Review” [Publication Type] OR “Comparative Effectiveness Research”[Mesh] or “Comparative Effectiveness”)

## EMBASE

No. | Query | Results
#64 | #45 AND #55 AND #62 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim | 5643
#63 | #45 AND #55 AND #62 | 13088
#62 | #56 OR #59 OR #60 OR #61 | 627326
#61 | ‘ringer lactate solution’ | 9234
#60 | ((((((((hypertonic AND saline OR hypertonic) AND sodium AND chloride OR hss OR salt) AND hypertonic OR sodium) AND tablets OR intravenous) AND saline OR normal) AND saline OR hypotonic) AND saline OR saline) AND solution OR lactate*) AND ringer* | 12542
#59 | ‘sodium chloride’ | 238797
#58 | #45 AND #55 AND #56 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim | 4882
#57 | #45 AND #55 AND #56 | 11117
#56 | #51 OR #52 OR #53 OR #54 | 472391
#55 | #46 OR #47 OR #48 OR #49 OR #50 | 10320989
#54 | (sodium OR salt) AND (restrict* OR reduc* OR low OR free) | 472391
#53 | ‘sodium free’ OR ‘salt free’ OR ‘low salt’ OR ‘low sodium’ OR ‘reduced salt’ OR ‘reduced sodium’ | 14002
#52 | ‘salt restrict’ | 2
#51 | ‘sodium restriction’ | 11815
#50 | heart AND decompensation | 7940
#49 | decompensated | 32589
#48 | acute AND disease | 1098740
#47 | inpatient | 191126
#46 | ‘hospital’ | 9716334
#45 | #41 OR #42 OR #43 OR #44 | 713122
#44 | chf | 30735
#43 | myocardial AND failure | 136191
#42 | cardiac AND failure | 315468
#41 | (‘heart’/exp OR heart) AND (‘failure’/exp OR failure) | 686908

## COCHRANE

#1 | MeSH descriptor: [Heart Failure] explode all trees | 12328
#2 | heart failure or cardiac failure or myocardial failure or CHF | 48961
#3 | #1 OR #2 | 48982
#4 | hospital* OR inpatient OR decompensated OR heart decompensation | 407267
#5 | MeSH descriptor: [Acute Disease] explode all trees | 10838
#6 | #4 OR #5 | 413481
#7 | sodium-restrict* or salt-restrict* or sodium-free or salt-free or low-salt or low-sodium or reduced-salt or reduced-sodium | 2215
#8 | MeSH descriptor: [Diet, Sodium-Restricted] explode all trees | 701
#9 | (sodium or salt) AND (restrict* or reduc* or low or free) | 24630
#10 | MeSH descriptor: [Saline Solution, Hypertonic] explode all trees | 584
#11 | MeSH descriptor: [Saline Solution] explode all trees | 284
#12 | MeSH descriptor: [Ringer’s Lactate] explode all trees | 281
#13 | Hypertonic Saline OR Hypertonic sodium chloride OR HSS OR salt hypertonic OR Sodium tablets OR Intravenous saline OR Normal saline OR Hypotonic saline OR Saline solution OR Lactate* ringer* | 32690
#14 | #7 OR #8 OR #9 OR #10 OR #11 OR #12 OR #13 | 53612
#15 | #3 AND #6 AND #14 | 2096

## CINAHL

((heart failure or cardiac failure or myocardial failure or CHF) AND (hospital OR inpatient or acute or decompensat*)) AND (Hypertonic Saline OR Hypertonic sodium chloride OR HSS OR salt hypertonic OR Sodium tablets OR Intravenous saline OR Normal saline OR Hypotonic saline OR Saline solution OR Lactate* ringer’s OR sodium-restrict* or salt-restrict* or sodium-free or salt-free or low-salt or low-sodium or reduced-salt or reduced-sodium OR ((sodium or salt) AND (restrict* or reduc* or low or free)))

## CLINICALTRIALS.GOV

Condition: ((heart failure OR cardiac failure OR myocardial failure OR CHF) AND (acute OR decompensat*)) AND

Other terms: (Saline OR Hypertonic sodium chloride OR HSS OR salt OR Sodium OR Lactate ringer)