# ABBREVIATIONS TABLE

Abbreviation: Definition
ACC: American College of Cardiology
ADHF: Acute decompensated heart failure
BNP: Brain (or B-type) natriuretic peptide
BUN: Blood urea nitrogen
CI: Confidence interval
eGFR: Estimated glomerular filtration rate
ESC: European Society of Cardiology
ESP: Evidence Synthesis Program
GRADE: Grading of Recommendations Assessment, Development and Evaluation
HF: Heart failure
HSS: Hypertonic saline solution
ICU: Intensive care unit
IQR: Interquartile range
IV: Intravenous
KQ: Key Questions
LVEDD: Left ventricle end-diastolic diameter
LVEF: Left ventricular ejection fraction
MD: Mean difference
NMD: Net mean difference
NR: Not reported
NRCS: Nonrandomized comparative study
NS: Not significant
NT-proBNP: N-terminal pro-brain (or B-type) natriuretic peptide
NYHA: New York Heart Association
PRA: Plasma renin activity
RCT: Randomized controlled trials
RD: Risk difference
RoB: Risk of bias
RR: Relative risk
SD: Standard deviation
TDS-HF: Thirst Distress Scale for Heart Failure
VAS: Visual analogue scale