# REFERENCES

1 Ju MR, Karalis JD, Chansard M, . Variation of Hepatocellular Carcinoma Treatment Patterns and Survival Across Geographic Regions in a Veteran Population. Ann Surg Oncol. Dec 2022;29(13):8413–8420. doi:10.1245/s10434-022-12390-7 36018517
2 American Cancer Society. Key statistics about liver cancer. Accessed June 27, 2023. https://www.cancer.org/cancer/types/liver-cancer/about/what-is-key-statistics.html
3 National Cancer Institute. Cancer Stat Facts: Liver and Intrahepatic Bile Duct Cancer. Accessed June 27, 2023. https://seer.cancer.gov/statfacts/html/livibd.html
4 Sung H, Ferlay J, Siegel RL, . Global Cancer Statistics 2020: GLOBOCAN Estimates of Incidence and Mortality Worldwide for 36 Cancers in 185 Countries. CA: a cancer journal for clinicians. 2021;71(3):209–249. doi:10.3322/caac.21660 33538338
5 Lee YT, Wang JJ, Luu M, . The Mortality and Overall Survival Trends of Primary Liver Cancer in the United States. J Natl Cancer Inst. Nov 2 2021;113(11):1531–1541. doi:10.1093/jnci/djab079 34010422
6 Lee Y-T, Wang JJ, Luu M, . The Mortality and Overall Survival Trends of Primary Liver Cancer in the United States. Journal of the National Cancer Institute. 2021;113(11):1531–1541. doi:10.1093/jnci/djab079 34010422
7 National Cancer Institute. Liver (Hepatocellular) Cancer Screening (PDQ®)–Health Professional Version. Updated May 2, 2023. Accessed July 21, 2023. https://www.cancer.gov/types/liver/hp/liver-screening-pdq#_76
8 Singal AG, Zhang E, Narasimman M, . HCC surveillance improves early detection, curative treatment receipt, and survival in patients with cirrhosis: A meta-analysis. Journal of Hepatology. 2022;77(1):128–139. doi:10.1016/j.jhep.2022.01.023 35139400
9 Aly A, Ronnebaum S, Patel D, Doleh Y, Benavente F. Epidemiologic, humanistic and economic burden of hepatocellular carcinoma in the USA: a systematic literature review. Hepat Oncol. Jul 21 2020;7(3):HEP27. doi:10.2217/hep-2020-0024 32774837
10 Beste LA, Green P, Berry K, Belperio P, Ioannou GN. Hepatitis C-Related Hepatocellular Carcinoma Incidence in the Veterans Health Administration After Introduction of Direct-Acting Antivirals. JAMA. Sep 8 2020;324(10):1003–1005. doi:10.1001/jama.2020.10121 32897335
11 Philips CA, Rajesh S, Nair DC, Ahamed R, Abduljaleel JK, Augustine P. Hepatocellular Carcinoma in 2021: An Exhaustive Update. Cureus. 2021;13(11):e19274. doi:10.7759/cureus.19274 34754704
12 Ioannou GN, Green P, Lowy E, Mun EJ, Berry K. Differences in hepatocellular carcinoma risk, predictors and trends over time according to etiology of cirrhosis. PLoS One. 2018;13(9):e0204412. doi:10.1371/journal.pone.0204412 30260995
13 Kansagara D, Papak J, Pasha AS, . Screening for Hepatocellular Cancer in Chronic Liver Disease: A Systematic Review. 2014. VA Evidence-based Synthesis Program Reports.
14 Singal AG, Zhang E, Narasimman M, . HCC surveillance improves early detection, curative treatment receipt, and survival in patients with cirrhosis: A meta-analysis. J Hepatol. Jul 2022;77(1):128–139. doi:10.1016/j.jhep.2022.01.023 35139400
15 Sterne JAC, Savovic J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. Aug 28 2019;366:14898. doi:10.1136/bmj.l4898
16 Sterne JA, Hernan MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. Oct 12 2016;355:i4919. doi:10.1136/bmj.i4919 27733354
17 Balshem H, Helfand M, Schunemann HJ, . GRADE guidelines: 3. Rating the quality of evidence. J Clin Epidemiol. Apr 2011;64(4):401–6. doi:10.1016/j.jclinepi.2010.07.015 21208779
18 Chen THH, Chen CJ, Yen MF, . Ultrasound screening and risk factors for death from hepatocellular carcinoma in a high risk group in Taiwan. International journal of cancer. 2002;98(2):257–261.11857416
19 Wang J-H, Chang K-C, Kee K-M, . Hepatocellular carcinoma surveillance at 4-vs. 12-month intervals for patients with chronic viral hepatitis: a randomized study in community. Official journal of the American College of Gastroenterology ACG. 2013;108(3):416–424.
20 Zhang BH, Yang BH, Tang ZY. Randomized controlled trial of screening for hepatocellular carcinoma. J Cancer Res Clin Oncol. Jul 2004;130(7):417–22. doi:10.1007/s00432-004-0552-0 15042359
21 Chen J, Parkin D, Chen Q, . Screening for liver cancer: results of a randomised controlled trial in Qidong, China. Journal of medical screening. 2003;10(4):204–209.14738659
22 Pocha C, Dieperink E, McMaken KA, Knott A, Thuras P, Ho SB. Surveillance for hepatocellular cancer with ultrasonography vs. computed tomography - a randomised study. Aliment Pharmacol Ther. Aug 2013;38(3):303–12. doi:10.1111/apt.12370 23750991
23 Trinchet JC, Chaffaut C, Bourcier V, . Ultrasonographic surveillance of hepatocellular carcinoma in cirrhosis: a randomized trial comparing 3-and 6-month periodicities. Hepatology. 2011;54(6):1987–1997.22144108
24 Moon AM, Weiss NS, Beste LA, . No Association Between Screening for Hepatocellular Carcinoma and Reduced Cancer-Related Mortality in Patients With Cirrhosis. Gastroenterology. Oct 2018;155(4):1128–1139 e6. doi:10.1053/j.gastro.2018.06.079 29981779
25 Su F, Weiss NS, Beste LA, . Screening is associated with a lower risk of hepatocellular carcinoma-related mortality in patients with chronic hepatitis B. Journal of Hepatology. 2021;74(4):850–859. doi:10.1016/j.jhep.2020.11.023 33245934
26 Kim JH, Kang SH, Lee M, . Improved Detection of Hepatocellular Carcinoma by Dynamic CT in Cirrhotic Patients With Chronic Hepatitis B: A Multi-Center Study. Journal of gastroenterology and hepatology. 2020;doi:10.1111/jgh.15046
27 An J, Kim HI, Chang S, Shim JH. Continued value of the serum alpha-fetoprotein test in surveilling at-risk populations for hepatocellular carcinoma. PLoS ONE. 2020;15(8 August):e0238078. doi:10.1371/journal.pone.0238078 32845895
28 Bae H, Lee SA, Choi JW, Hwang SH, Park S, Park MS. Effectiveness of hepatocellular carcinoma surveillance and an optimal surveillance interval: Nationwide cohort of Korea. Yonsei Medical Journal. 2021;62(8):758–766. doi:10.3349/ymj.2021.62.8.758 34296554
29 Kim H, Nam J, Lee JH, . Intensity of surveillance for hepatocellular carcinoma determines survival in patients at risk in a hepatitis B-endemic area. Alimentary pharmacology & therapeutics. 2018;47(11):1490–1501.29611209
30 Mittal S, Kanwal F, Ying J, . Effectiveness of surveillance for hepatocellular carcinoma in clinical practice: a United States cohort. Journal of hepatology. 2016;65(6):1148–1154.27476765
31 Pelizzaro F, Peserico G, D’Elia M, . Surveillance for hepatocellular carcinoma with a 3-months interval in “extremely high-risk” patients does not further improve survival. Dig Liver Dis. Jul 2022;54(7):927–936. doi:10.1016/j.dld.2021.08.025 34580038
32 Piñero F, Rubinstein F, Marciano S, . Surveillance for hepatocellular carcinoma: does the place where ultrasound is performed impact its effectiveness? Digestive Diseases and Sciences. 2019;64(3):718–728.30511199
33 Tanaka H, Nouso K, Kobashi H, . Surveillance of hepatocellular carcinoma in patients with hepatitis C virus infection may improve patient survival. Liver International. 2006;26(5):543–551.16761998
34 Thein H-H, Campitelli MA, Yeung LT, Zaheen A, Yoshida EM, Earle CC. Improved survival in patients with viral hepatitis-induced hepatocellular carcinoma undergoing recommended abdominal ultrasound surveillance in Ontario: a population-based retrospective cohort study. PLoS One. 2015;10(9):e0138907.26398404
35 Tong MJ, Rosinski AA, Huynh CT, Raman SS, Lu DS. Long-term survival after surveillance and treatment in patients with chronic viral hepatitis and hepatocellular carcinoma. Hepatology communications. 2017;1(7):595–608.29404481
36 Trevisani F, Cantarini MC, Labate AM, . Surveillance for hepatocellular carcinoma in elderly Italian patients with cirrhosis: effects on cancer staging and patient survival. Official journal of the American College of Gastroenterology| ACG. 2004;99(8):1470–1476.
37 Wu CY, Hsu YC, Ho HJ, Chen YJ, Lee TY, Lin JT. Association between ultrasonography screening and mortality in patients with hepatocellular carcinoma: a nationwide cohort study. Gut. Apr 2016;65(4):693–701. doi:10.1136/gutjnl-2014-308786 25670811
38 Tzartzeva K, Obi J, Rich NE, . Surveillance Imaging and Alpha Fetoprotein for Early Detection of Hepatocellular Carcinoma in Patients With Cirrhosis: A Meta-analysis. Gastroenterology. May 2018;154(6):1706–1718 e1. doi:10.1053/j.gastro.2018.01.064 29425931
39 Singal AG, Conjeevaram HS, Volk ML, . Effectiveness of hepatocellular carcinoma surveillance in patients with cirrhosis. Cancer epidemiology, biomarkers & prevention : a publication of the American Association for Cancer Research, cosponsored by the American Society of Preventive Oncology. 2012;21(5):793–9. Comment in: Expert Rev Gastroenterol Hepatol. 2012 Aug;6(4):441–4 PMID: 22928896 [https://www.ncbi.nlm.nih.gov/pubmed/22928896]. doi:10.1158/1055-9965.EPI-11-1005
40 Lok AS, Sterling RK, Everhart JE, . Des-gamma-carboxy prothrombin and alphafetoprotein as biomarkers for the early detection of hepatocellular carcinoma. Gastroenterology. 2010;138(2):493–502. doi:10.1053/j.gastro.2009.10.031 19852963
41 National Center for Health Statistics. Chronic liver disease and cirrhosis death rates among persons aged 25 and over, by sex and age: United States, 2006–2016. Accessed August 30, 2023. https://www.cdc.gov/nchs/hus.htm
42 Yao Z, Dai C, Yang J, . Time-trends in liver cancer incidence and mortality rates in the U.S. from 1975 to 2017: a study based on the Surveillance, Epidemiology, and End Results database. Journal of gastrointestinal oncology. 2023;14(1):312–324. doi:10.21037/jgo-23-25 36915450
43 U.S. Preventive Services Task Force. Cervical Cancer: Screening. Accessed August 30, 2023. https://www.uspreventiveservicestaskforce.org/uspstf/recommendation/cervical-cancer-screening
44 U.S. Preventive Services Task Force. Ovarian Cancer: Screening. Accessed August 30, 2023. https://www.uspreventiveservicestaskforce.org/uspstf/recommendation/ovarian-cancer-screening
45 Weiss NS, Etzioni R. Estimating the influence of rescreening interval on the benefits associated with cancer screening: approaches and limitations. Epidemiology (Cambridge, Mass). 2002;13(6):713–7.12410014
46 Weiss NS, Dhillon PK, Etzioni R. Case-Control Studies of the Efficacy of Cancer Screening: Overcoming Bias From Nonrandom Patterns of Screening. Epidemiology. 2004;15(4)
47 Doria-Rose VP, Kamineni A, Barrett MJ, Ko CW, Weiss NS. Case-Control Studies of the Efficacy of Screening Tests That Seek to Prevent Cancer Incidence: Results of an Approach That Utilizes Administrative Claims Data That Do Not Provide Information Regarding Test Indication. American Journal of Epidemiology. 2019;188(4):703–708. doi:10.1093/aje/kwy274 30698635
48 Singal AG, Llovet JM, Yarchoan M, . AASLD practice guidance on prevention, diagnosis, and treatment of hepatocellular carcinoma. Hepatology (Baltimore, Md). 2023;Publish Ahead of Printdoi:10.1097/HEP.0000000000000466
49 American Association for the Study of Liver Diseases. Practice Guidelines Accessed October 16, 2023. https://www.aasld.org/practice-guidelines
50 Qaseem A, Forland F, Macbeth F, Ollenschlager G, Phillips S, Wees PJvd. Guidelines International Network: toward international standards for clinical practice guidelines. Annals of internal medicine. 2012;156(7):525–31. doi:10.7326/0003-4819-156-7-201204030-00009 22473437
51 Institute of Medicine Committee on Standards for Developing Trustworthy Clinical Practice G. Clinical Practice Guidelines We Can Trust. Washington DC: National Academies Press (US); 2011.
52 AGREE Enterprise. Appraisal of Guidelines for Research and Evaluation (AGREE) Instrument. Accessed August 30, 2023. https://www.agreetrust.org/
53 Asrani SK, Ghabril MS, Kuo A, . Quality measures in HCC care by the Practice Metrics Committee of the American Association for the Study of Liver Diseases. Hepatology. 2022;75(5)
54 Zucker SD, Fried MW. Parsing the guidelines on guidelines: Balancing sensibility and conflict of interest. Hepatology. 2018;68(3)
55 Sally MK, Bland JM. Analysis of a trial randomised in clusters. BMJ. 1998;316(7124):54. doi:10.1136/bmj.316.7124.54 9451271
56 Harris RP, Sheridan SL, Lewis CL, . The Harms of Screening: A Proposed Taxonomy and Application to Lung Cancer Screening. JAMA Internal Medicine. 2014;174(2):286. doi:10.1001/jamainternmed.2013.12745 24322527
57 National Cancer Institute. Liver (Hepatocellular) Cancer Screening (PDQ®)–Health Professional Version. Accessed August 30, 2023. https://www.cancer.gov/types/liver/hp/liver-screening-pdq
58 Kansagara D, Papak J, Pasha AS, . Screening for hepatocellular carcinoma in chronic liver disease: a systematic review. Ann Intern Med. Aug 19 2014;161(4):261–9. doi:10.7326/M14-0558 24934699
59 Lederle FA, Pocha C. Screening for Liver Cancer: The Rush to Judgment. Annals of Internal Medicine. 2012/03/06 2012;156(5):387–389. doi:10.7326/0003-4819-156-5-201203060-00012 22393134
60 Lee TH, Brennan TA. Direct-to-Consumer Marketing of High-Technology Screening Tests. New England Journal of Medicine. 2002/02/14 2002;346(7):529–531. doi:10.1056/NEJM200202143460715 11844859
61 VA Cooperative Studies Program. PREventing liver cancer Mortality through Imaging with Ultrasound vs. MRI (PREMIUM). Accessed August 30, 2023. https://www.vacsp.research.va.gov/CSP_2023/CSP_2023.asp
62 Garcia-Albeniz X, Hsu J, Hernan MA. The value of explicitly emulating a target trial when using real world evidence: an application to colorectal cancer screening. Eur J Epidemiol. Jun 2017;32(6):495–500. doi:10.1007/s10654-017-0287-2 28748498
63 Aby E, Phan J, Truong E, Grotts J, Saab S. Inadequate Hepatocellular Carcinoma Screening in Patients With Nonalcoholic Steatohepatitis Cirrhosis. J Clin Gastroenterol. Feb 2019;53(2):142–146. doi:10.1097/MCG.0000000000001075 29912761
64 Alencar RSDSM, Oliveira CP, Chagas AL, . Hepatocellular carcinoma (HCC) in patients with Non-Alcoholic Fatty Liver Disease (NAFLD): screening, treatment and survival analysis in a Brazilian series. Clinics. 2022;77:100097. doi:10.1016/j.clinsp.2022.100097 36088887
65 Bolondi L, Sofia S, Siringo S, . Surveillance programme of cirrhotic patients for early diagnosis and treatment of hepatocellular carcinoma: a cost effectiveness analysis. Gut. 2001;48(2):251–259.11156649
66 Chaiteerakij R, Chattieng P, Choi J, Pinchareon N, Thanapirom K, Geratikornsupuk N. Surveillance for hepatocellular carcinoma reduces mortality: an inverse probability of treatment weighted analysis. Annals of hepatology. 2017;16(3):421–429.28425412
67 Chen VL, Singal AG, Tapper EB, Parikh ND. Hepatocellular carcinoma surveillance, early detection, and survival in a privately-insured US cohort. Liver international : official journal of the International Association for the Study of the Liver. 2020;doi:10.1111/liv.14379
68 Chinnaratha MA, Campbell K, Mathias R, McCormick RJ, Woodman RJ, Wigg AJ. Improved Survival of Hepatocellular Carcinoma Patients Diagnosed with a Dedicated Screening Programme—a Propensity Score Adjusted Analysis. Journal of Gastrointestinal Cancer. 2019;50(4):888–893.30345486
69 Choi DT, Kum H-C, Park S, . Hepatocellular carcinoma screening is associated with increased survival of patients with cirrhosis. Clinical Gastroenterology and Hepatology. 2019;17(5):976–987. e4.30616961
70 Costentin CE, Layese R, Bourcier V, . Compliance With Hepatocellular Carcinoma Surveillance Guidelines Associated With Increased Lead-Time Adjusted Survival of Patients With Compensated Viral Cirrhosis: A Multi-Center Cohort Study. Gastroenterology. Aug 2018;155(2):431–442 e10. doi:10.1053/j.gastro.2018.04.027 29729258
71 Cucchetti A, Trevisani F, Pecorelli A, . Estimation of lead-time bias and its impact on the outcome of surveillance for the early diagnosis of hepatocellular carcinoma. Journal of Hepatology. 2014;61(2):333–341.24717522
72 Davila JA, Weston A, Smalley W, El-Serag HB. Utilization of screening for hepatocellular carcinoma in the United States. Journal of clinical gastroenterology. 2007;41(8):777–782.17700427
73 Debes JD, Chan AJ, Balderramo D, . Hepatocellular carcinoma in South America: Evaluation of risk factors, demographics and therapy. Liver International. 2018;38(1):136–143.28640517
74 Edenvik P, Davidsdottir L, Oksanen A, Isaksson B, Hultcrantz R, Stål P. Application of hepatocellular carcinoma surveillance in a European setting. What can we learn from clinical practice? Liver International. 2015;35(7):1862–1871.25524812
75 El-Serag HB, Kramer JR, Chen GJ, Duan Z, Richardson PA, Davila JA. Effectiveness of AFP and ultrasound tests on hepatocellular carcinoma mortality in HCV-infected patients in the USA. Gut. Jul 2011;60(7):992–7. doi:10.1136/gut.2010.230508 21257990
76 Eskesen AN, Bjøro K, Aandahl EM, Line PD, Melum E. Low use of surveillance and early diagnosis of hepatocellular carcinoma in Norway—a population-based cohort study. Cancer epidemiology. 2014;38(6):741–747.25454262
77 Giannini EG, Pieri G, Labanca S, . Characteristics and survival of patients with primary biliary cholangitis and hepatocellular carcinoma. Digestive and Liver Disease. 2022;54(9):1215–1221. doi:10.1016/j.dld.2022.03.002 35354543
78 Giannini E, Arzani L, Borro P, . Does surveillance for hepatocellular carcinoma in HCV cirrhotic patients improve treatment outcome mainly due to better clinical status at diagnosis? Hepato-gastroenterology. 2000;47(35):1395–1398.11100360
79 Haq MI, Drake TM, Goh TL, . Effect of hepatocellular carcinoma surveillance programmes on overall survival in a mixed cirrhotic uk population: A prospective, longitudinal cohort study. Journal of Clinical Medicine. 2021;10(13):2770. doi:10.3390/jcm10132770 34202593
80 Hong TP, Gow PJ, Fink M, . Surveillance improves survival of patients with hepatocellular carcinoma: a prospective population-based study. Medical Journal of Australia. 2018;209(8):348–354.30309301
81 Huang Y, Wallace MC, Adams LA, . Rate of Nonsurveillance and Advanced Hepatocellular Carcinoma at Diagnosis in Chronic Liver Disease. J Clin Gastroenterol. Jul 2018;52(6):551–556. doi:10.1097/MCG.0000000000000916 28858944
82 Hwang JA, Kang TW, Min JH, . Association between intensity of imaging surveillance and clinical outcomes in patients with hepatocellular carcinoma. European Journal of Radiology. 2022;151:110328. doi:10.1016/j.ejrad.2022.110328 35489206
83 Im S, Jang ES, Lee JH, . Surveillance rate and its impact on survival of hepatocellular carcinoma patients in South Korea: a cohort study. Cancer research and treatment: official journal of Korean Cancer Association. 2019;51(4):1357–1369.
84 Jasirwan COM, Hasan I, Sulaiman AS, . Risk factors of mortality in the patients with hepatocellular carcinoma: A multicenter study in Indonesia. Current Problems in Cancer. 2020;44(1):100480. doi:10.1016/j.currproblcancer.2019.05.003 31130257
85 Karim MA, Singal AG, Kum HC, . Clinical Characteristics and Outcomes of Nonalcoholic Fatty Liver Disease-Associated Hepatocellular Carcinoma in the United States. Clinical Gastroenterology and Hepatology. 2022;doi:10.1016/j.cgh.2022.03.010
86 Kemp W, Pianko S, Nguyen S, Bailey MJ, Roberts SK. Survival in hepatocellular carcinoma: impact of screening and etiology of liver disease. Journal of gastroenterology and hepatology. 2005;20(6):873–881.15946134
87 Kuo SC, Lin CN, Lin YJ, Chen WY, Hwang JS, Wang JD. Optimal Intervals of Ultrasonography Screening for Early Diagnosis of Hepatocellular Carcinoma in Taiwan. JAMA Network Open. 2021;4(6):e2114680. doi:10.1001/jamanetworkopen.2021.14680 34165580
88 Kuo Y-H, Lu S-N, Chen C-L, . Hepatocellular carcinoma surveillance and appropriate treatment options improve survival for patients with liver cirrhosis. European Journal of Cancer. 2010;46(4):744–751.20060710
89 Kwon JW, Tchoe HJ, Lee J, Suh JK, Lee JH, Shin S. The impact of national surveillance for liver cancer: Results from real-world setting in Korea. Gut and Liver. 2020;14(1):108–116. doi:10.5009/GNL18522 30974929
90 Lang S, Martin A, Kasper P, . Hepatocellular carcinoma surveillance with liver imaging is not associated with improved survival. Scandinavian Journal of Gastroenterology. 2020;55(2):222–227. doi:10.1080/00365521.2020.1718747 31990240
91 Leykum LK, El–Serag HB, Cornell J, Papadopoulos KP. Screening for hepatocellular carcinoma among veterans with hepatitis C on disease stage, treatment received, and survival. Clinical Gastroenterology and Hepatology. 2007;5(4):508–512.17382601
92 Merchante N, Figueruela B, Rodríguez-Fernández M, . Low performance of ultrasound surveillance for the diagnosis of hepatocellular carcinoma in HIV-infected patients. AIDS. 2019;33(2):269–278.30325782
93 Nusbaum JD, Smirniotopoulos J, Wright HC, . The effect of hepatocellular carcinoma surveillance in an urban population with liver cirrhosis. Journal of clinical gastroenterology. 2015;49(10):e91–e95.25751372
94 Oeda S, Iwane S, Takasaki M, . Optimal follow-up of patients with viral hepatitis improves the detection of early-stage hepatocellular carcinoma and the prognosis of survival. Internal Medicine. 2016;55(19):2749–2758.27725532
95 Papageorge MV, de Geus SWL, Woods AP, . Surveillance Patterns for Hepatocellular Carcinoma among Screening-Eligible Patients in the Medicare Population. Annals of Surgical Oncology. 2022;29(13):8424–8431. doi:10.1245/s10434-022-12360-z 36057903
96 Pascual S, Irurzun J, Zapater P, . Usefulness of surveillance programmes for early diagnosis of hepatocellular carcinoma in clinical practice. Liver International. 2008;28(5):682–689.18433394
97 Pelizzaro F, Vitale A, Sartori A, . Surveillance as determinant of long-term survival in nontransplanted hepatocellular carcinoma patients. Cancers. 2021;13(4):1–16. doi:10.3390/cancers13040897
98 de Lope CR, Reig M, Matilla A, . Clinical characteristics of hepatocellular carcinoma in Spain. Comparison with the 2008–2009 period and analysis of the causes of diagnosis out of screening programs. Analysis of 686 cases in 73 centers. Medicina Clínica (English Edition). 2017;149(2):61–71.
99 Schauer C, Mules T, Van Rijnsoever M, Gane E. Increasing burden of advanced hepatocellular carcinoma in New Zealand - The need for better surveillance. New Zealand Medical Journal. 2020;133(1515):25–34.32438374
100 Schauer C, van Rijnsoever M, Gane E. Surveillance factors change outcomes in patients with hepatocellular carcinoma due to chronic hepatitis C virus infection in New Zealand. Journal of viral hepatitis. 2019;26(12):1372–1376.31323163
101 Shindo K, Maekawa S, Komatsu N, . Semiannual imaging surveillance is associated with better survival in patients with non-B, non-C hepatocellular carcinoma. Mediators of Inflammation. 2015;2015
102 Singal AG, Patibandla S, Obi J, . Benefits and Harms of Hepatocellular Carcinoma Surveillance in a Prospective Cohort of Patients with Cirrhosis. Clinical gastroenterology and hepatology : the official clinical practice journal of the American Gastroenterological Association. 2020;doi:10.1016/j.cgh.2020.09.014
103 Singal AG, Mittal S, Yerokun OA, . Hepatocellular carcinoma screening associated with early tumor detection and improved survival among patients with cirrhosis in the US. The American journal of medicine. 2017;130(9):1099–1106. e1.28213044
104 Sohn W, Kang D, Kang M, Guallar E, Cho J, Paik Y-H. Impact of nationwide hepatocellular carcinoma surveillance on the prognosis in patients with chronic liver disease. Clinical and molecular hepatology. 2022;28(4):851–863. Comment in: Clin Mol Hepatol. 2022 Oct;28(4):810–813 PMID: 36064304 [https://www.ncbi.nlm.nih.gov/pubmed/36064304]. doi:10.3350/cmh.2022.0037 36263667
105 Taura N, Hamasaki K, Nakao K, . Clinical benefits of hepatocellular carcinoma surveillance: a single-center, hospital-based study. Oncology reports. 2005;14(4):999–1003.16142364
106 Tong MJ, Sun H-E, Hsien C, Lu DS. Surveillance for hepatocellular carcinoma improves survival in Asian-American patients with hepatitis B: results from a community-based clinic. Digestive diseases and sciences. 2010;55(3):826–835.19960258
107 Toyoda H, Kumada T, Tada T, . Impact of hepatocellular carcinoma aetiology and liver function on the benefit of surveillance: A novel approach for the adjustment of lead-time bias. Liver International. 2018;38(12):2260–2268.29981527
108 Tran SA, Le A, Zhao C, . Rate of hepatocellular carcinoma surveillance remains low for a large, real-life cohort of patients with hepatitis C cirrhosis. BMJ open gastroenterology. 2018;5(1):e000192.
109 Trevisani F, De Notariis S, Rapaccini G, . Semiannual and annual surveillance of cirrhotic patients for hepatocellular carcinoma: effects on cancer stage and patient survival (Italian experience). The American journal of gastroenterology. 2002;97(3):734–744.11922571
110 van Meer S, Robert A, Coenraad MJ, . Surveillance for hepatocellular carcinoma is associated with increased survival: results from a large cohort in the Netherlands. Journal of hepatology. 2015;63(5):1156–1163.26100498
111 Vaz J, Stromberg U, Midlov P, Eriksson B, Buchebner D, Hagstrom H. Unrecognized liver cirrhosis is common and associated with worse survival in hepatocellular carcinoma: A nationwide cohort study of 3473 patients. Journal of Internal Medicine. 2023;293(2):184–199. doi:10.1111/joim.13570 36166276
112 Wong GLH, Wong VWS, Tan GM, . Surveillance programme for hepatocellular carcinoma improves the survival of patients with chronic viral hepatitis. Liver International. 2008;28(1):79–87.17900247
113 Yamago H, Hiraoka A, Murakami T, . Ultrasonography surveillance improves prognosis of patients with hepatocellular carcinoma. Molecular and Clinical Oncology. 2019;11(3):325–330.31384461
114 Yeh J-H, Hung C-H, Wang J-H, Kuo Y-H, Tai W-C, Lu S-N. Hepatocellular carcinoma detected by regular surveillance: Does timely confirmation of diagnosis matter? Digestive and Liver Disease. 2016;48(6):661–666.26992848
115 Yu EW-R, Chie W-C, Chen TH-H. Does screening or surveillance for primary hepatocellular carcinoma with ultrasonography improve the prognosis of patients? The Cancer Journal. 2004;10(5):317–325.15530261