# ACKNOWLEDGMENTS

The authors are grateful to external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Timothy Morgan, MD
  Deputy Director
  National GI & Hepatology Program

- Jason Dominitz, MD
  National Director
  VHA Gastroenterology

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Angela L. Denietolis, MD
  Executive Director
  VACO Office of Primary Care

- Michael Kelley, MD
  Executive Director
  National Oncology Program

- Sophia Califano, MD
  Deputy Chief Consultant for Preventive Medicine
  VA National Center for Health Promotion and Disease Prevention

- Devan Kansagara, MD
  Physician (internal medicine)
  VA Portland Healthcare System

- George Ioannou, MD, MS
  Physician (gastroenterology)
  VA Puget Sound Health Care System

This report was prepared by the Evidence Synthesis Program Center located at the Minneapolis VA Health Care System, directed by Timothy J. Wilt, MD, MPH and Wei Duan-Porter, MD, PhD and funded by the Department of Veterans Affairs, Veterans Health Administration, Health Services Research and Development.

The findings and conclusions in this document are those of the author(s) who are responsible for its contents and do not necessarily represent the views of the Department of Veterans Affairs or the United States government. Therefore, no statement in this article should be construed as an official position of the Department of Veterans Affairs. The final research questions, methodology, and/or conclusions may not necessarily represent the views of contributing operational and content experts. No investigators have affiliations or financial involvement (eg, employment, consultancies, honoraria, stock ownership or options, expert testimony, grants or patents received or pending, or royalties) that conflict with material presented in the report.