# DISCUSSION

Our systematic review found that the evidence was very uncertain regarding the effectiveness and harms of screening for hepatocellular carcinoma in adults at increased risk. Uncertainty is mostly due to methodological limitations in the published literature. While we identified 74 eligible studies (including 5 RCTs), all but 15 were assessed as being high or critical risk of bias. We found very limited data from studies with a standard design typically used to determine screening effectiveness (cohort, case-control, RCT). Instead, the vast majority of studies analyzed individuals who already had an HCC diagnosis (HCC cohort), thus preventing reliable assessment of HCC screening benefits and harms in the target “at-risk” population.

When limited to studies judged not at high or critical risk of bias, only 7 studies enrolled exclusively or predominately individuals with cirrhosis, the relevant target screening population in the USA (90% of all HCC cases occur among those with cirrhosis). Only 3 of these studies were conducted in the USA, 1 reporting all-cause mortality and 2 reporting HCC mortality. For the 2 studies reporting HCC mortality, 1 low RoB case-control study in Veterans found no association of ultrasound plus AFP screening with HCC mortality compared with no screening. A small RCT in Veterans (with some risk of bias concerns) found no statistically significant reductions in HCC mortality among individuals screened with ultrasound plus AFP every 6 months versus CT every 12 months plus AFP every 6 months.

Screening test accuracy and epidemiologic data do not provide supportive evidence of HCC screening benefits and RCT findings are inconclusive. Based on a meta-analysis, screening with ultrasound and AFP has poor diagnostic accuracy for early-stage disease with sensitivity and specificity of the combination of modalities of 63% and 84%, respectively.^38^ When limited to studies conducted in the USA, diagnostic accuracy is much lower (31.7% and 35.9%, respectively).^39,40^ Epidemiologic results also suggest that screening has resulted in increased detection without mortality declines; a pattern consistent with overdiagnosis and detection and treatment programs with, at best, limited effectiveness. For example, from 2006-2016, age-adjusted cirrhosis incidence remained fairly stable (12.1 per 100,000 to 14.3 per 100,000 in males and 5.8 to 7.5 per 100,000 in women).^41^ However, agestandardized HCC incidence increased more than 3-fold from 2.6 HCC cases per 100,000 person-years in 1975 to 8.7 per 100,000 person-years in 2017.^42^ Trends in HCC incidence have been accompanied by a stage shift, ie, an increased percentage of HCC cases with local disease. There has been no concurrent increase of curative-aim treatments nor a decrease in HCC mortality. Instead, more than a 2-fold increase in HCC-attributable death has occurred (2.8 HCC deaths per 100,000 person-years in 1975 to 6.6 per 100,000 person-years in 2017). Shifting patterns of liver disease and cirrhosis etiology over this time may partially account for HCC incidence and mortality findings.

Simply asked, are epidemiologic findings that fail to find a reversal in HCC mortality due to poor screening test performance, wrong screening tests or intervals, wrong choice of screening population, changes in risk population, and/or shifts in underlying etiology? Or is it possible that some screening strategies work in some individuals and have overall net benefit? The evidence does not provide sufficient answers. However, conclusive evidence for cancer screening has rarely been derived from epidemiologic or observational studies. A notable exception is Pap testing to reduce cervical cancer incidence and mortality.^43^ In this situation, cervical cancer incidence and mortality dropped dramatically following widespread implementation of Pap testing. These findings led to recommendations for screening.^43^ However, in almost all other instances, development of high-quality cancer screening recommendations required evidence of effectiveness from RCTs due to limitations in establishing causal effects from observational data. For instance, early enthusiasm for ovarian cancer screening with transvaginal ultrasound and CA-125 testing was based on nonrandomized trials purportedly demonstrating screening effectiveness based on stage shift, greater use of curative therapies, and improved survival for screen-detected disease (similar to HCC screening).^44^ However, later RCTs demonstrated harms of screening without benefits. Guidelines now recommend against ovarian cancer screening.^44^

There are several challenges for the assessment of screening effectiveness and harms using cohort studies limited only to those with an HCC diagnosis. Many have been noted previously (including in the 2014 ESP report^13^), yet misinterpretation of published evidence and conduct of studies with previously noted limitations persists. A major issue is the combination of lead-time bias (when a diagnostic approach merely identifies the disease earlier thus increasing perceived survival time without significant modification of the disease course) and length-time bias (when screening detects slower progressing cancer which has a better prognosis, including longer survival). Despite attempts in some studies to control for these biases, solutions are limited and based on assumptions about tumor growth and spectrum of disease. While sensitivity analyses can test the robustness of results under different assumptions, they do not resolve all uncertainty. Another major bias concerns patient and coexisting disease cofounders known to affect both receipt of screening and survival such as comorbidities, liver disease severity, or etiology (selection bias). Finally, decision making surrounding classification of intervention groups and outcomes was commonly omitted. A priori decision making and investigation of data missingness, selection biases, and misclassification would provide greater clarity regarding data source limitations.

We found only 5 cohort studies in the target population, and all had serious or critical risk of bias. Case-control studies are a useful alternative approach when used with methodology to control potential bias.^45–47^ The 2 case-control studies had limitations, including small sample size. However, the design is still preferable to the more common HCC cohort studies since they include control subjects from the target population. Both case-control studies were conducted at VHA medical centers but provided contrasting results, albeit in different at-risk groups. The first study, in individuals with HBV, found that a history of being screened with ultrasound +/- AFP was associated with a reduction in HCC mortality versus no prior screening. The second study, among individuals with cirrhosis, found no association of HCC mortality with prior receipt of screening with ultrasound plus AFP.^24^

Our findings update 2 prior systematic reviews. In 2014, Kansagara et al^13^ concluded that evidence was uncertain regarding the effects of screening for HCC in adults with increased risk. The noted issues related to HCC cohort studies were common to both our report and the previous report. For example, Kansagara et al found that only 5 of the studies included in their review adjusted for lead time. Furthermore, they noted that sensitivity analysis for some studies showed no benefit under certain assumptions of doubling time. Our review differs from Kansagara et al in that their list of required adjustment for confounders only included age, sex, and liver disease severity. The cohort study and the case-control studies in the current report are not included in the earlier report.

A systematic review by Singal et al^14^ of published literature and meeting abstracts from January 2014–July 2020 informed a guidance statement by the AASLD. Authors concluded that HCC screening (semiannual screening) was associated with improved early detection, curative treatment receipt, and survival in patients with cirrhosis, although there was heterogeneity in pooled estimates. As in the review by Kansagara, Singal noted that HCC screening was associated with improved early-stage detection and curative treatment receipt but that few studies assessed screening-related harms.

Methodologic limitations exist in this review. For example, the review did not clearly differentiate increased-risk cohort studies from HCC cohort studies. Combining results for these studies is problematic because it assumes that the impact of screening on all-cause mortality in populations with increased risk can be determined from an HCC cohort. Authors included studies that do not fully adjust for lead, length, and indication biases. Unadjusted analyses are not useful for determining causal effects of screening. Only 12 studies reported hazard ratios adjusted for lead time and these 12 studies were pooled. As noted earlier, results often varied by lead time values used both within and between studies, while none of these choices has been validated. Singal did not provide consideration of length bias and other confounding does not appear to have been assessed. Overall risk of bias domains were not provided. Harms of subsequent treatment were not considered. Reports provided no measure of overdiagnosis or overtreatment particularly relevant in screen-detected tumors among individuals with high competing mortality risk. Finally, there was no overall assessment of certainty of evidence.

The AASLD recently issued guidance regarding screening for HCC.^48^ AASLD guidance statements are intended to help clinicians understand and implement the most recent evidence based on comprehensive review and analysis of the literature.^49^ AASLD recommends the following: HCC screening with semiannual ultrasound plus AFP in at-risk individuals, including those with cirrhosis from any etiology, individuals with non-cirrhotic chronic HBV infection from endemic countries or with a family history of HCC (Level 2: Strong recommendations); interventions such as best practice alerts or outreach programs to increase HCC screening adherence given the underuse of screening in clinical practice (Level 2: Strong recommendation); diagnosis based on noninvasive imaging criteria and/or pathology (Level 1: Strong recommendation). AASLD does not recommend routine use of CT or MRI based imaging and tumor biomarkers outside of AFP (Level 5: Weak recommendation).

Strengths of the AASLD guidance statements include clear actionable information and accompanying strength of recommendations, stated use of methods to rate level of evidence, acknowledgement of evidence limitations including poor diagnostic accuracy of screening methods, recommendations against screening groups at very low risk (ie, < 0.2% per year; those with Hepatitis C or NASH without cirrhosis), focusing screening to “at risk” individuals who would be HCC treatment candidates, and noting that in some individuals HCC diagnosis may be made noninvasively, thus reducing harms of liver biopsies.

However, based on a validated quality metric checklist for assessing clinical guidelines and guidance statements (AGREE), we identified several factors in the AASLD guidance development that do not adhere to established standards for high-quality clinical guidelines.^50–52^ AASLD guidance authors stated that they used a literature review that was comprehensive and unbiased but did not mandate systematic reviews to facilitate more rapid publication. However, there is no accompanying guidance document protocol, description of search strategies, or study eligibility criteria. Thus, there is no information to determine if the review was comprehensive or unbiased. The guidance committee chair authored the accompanying screening evidence report; several limitations of that systematic review are noted above. Guidance statements are based on expert consensus yet still derive evidence levels and recommendations. They are also used to develop quality measures in HCC by the Practice Metrics Committee of the AASLD.^53^ The recently published measures reference AASLD guidance statements and closely align with their conclusions. Thus, AASLD guidance statements and guidelines seem to have similar implications for practice metrics. Most guidance panel members, including the chair, had stated conflicts of interest, including serving as advisors or consultants to pharmaceutical or biotechnology industry or owning stock, which appears inconsistent with AASLD policies.^54^ Additionally, no primary care clinicians or public representatives were included.

The stated highest quality data for AASLD recommending HCC screening is a single cluster randomized trial of screening with ultrasound plus AFP every 6 months in adults with hepatitis B conducted in Shanghai, China, where the prevalence of HCC is higher than in the USA.^20^ The study reported that death from HCC occurred less frequently in the screening group; rate ratio 0.63, 95% CI [0.41 to 0.98]. Absolute HCC mortality reduction was small (48 per 100,000 person years). We rated this study as high risk of bias. Limitations included: results varied in different publications, patients in the control group were not made aware of the study or actively followed. There was no information about randomization technique and very little information on baseline characteristics; potential differences in baseline characteristics are particularly relevant in cluster-randomized studies when control groups are not aware of study participation and when all-cause mortality is not reported. Intention-to-treat analyses were not used, outcome assessment was not blinded, and generalizability to populations without hepatitis B or those with lower HCC risk is uncertain. Statistical analyses did not adjust for clustering. “Ignoring the clustering results in confidence intervals which are too narrow and P values which are too small; hence it is likely to produce spuriously significant differences.”^55^

The recommendation for screening individuals with cirrhosis, the population comprising nearly 90% of individuals who develop HCC, was made despite the lack of RCT evidence, and acknowledgement that a case-control study among USA adults (judged as the only low RoB study in adults with cirrhosis) found no association of ultrasound plus AFP screening with HCC mortality. AASLD recommends semiannual screening for individuals with an estimated annual incidence of ≥0.2 per year, thus subjecting a large proportion of individuals to long-term intensive screening. AASLD notes some “potential limitations” in the “cohort” studies (more appropriately described as HCC cohorts rather than cohorts of “at-risk” adults) but does not acknowledge all individuals in HCC cohorts had HCC. Such study designs target the wrong population, cannot answer the questions regarding screening in “at-risk” adults, and thus do not provide information on the benefits and harms of screening. Some harms of screening were considered (though harms information was sparse) but harms and burden of treatment were not. Given that AASLD states that up to 30% of screen-detected tumors are indolent, substantial overdiagnosis and overtreatment is present with notable treatment-related harms without improved outcomes. Even if screening and treatment are demonstrated to reduce HCC mortality, the harms and costs of treatments, which include surgical resection, ablation, or liver transplantation, require careful assessments to determine overall net clinical benefit, including effect on overall mortality.^56^ In the case of liver transplantation, scarce resources are used due to limited donor availability. Listed cost-effectiveness estimates base conclusions on highly uncertain effect estimates and do not include all harms. Finally, evidence does not support screening semiannually or including AFP with ultrasound. Such a strategy is more intensive than other recommended cancer screening programs and increases costs as well as patient, clinician, and health system burden.

In contrast to AASLD conclusions, the National Cancer Institute states that “based on fair evidence, screening of persons at elevated risk does not result in a decrease in mortality from hepatocellular cancer” and “based on fair evidence, screening would result in rare but serious harms”.^57^ The United States Preventive Services Task Force, the American Cancer Society, as well as primary care medical societies including the American College of Physicians and American Academy of Family Physicians make no recommendations on HCC screening. Given limitations in evidence regarding benefits, harms, and costs, it is challenging to conclude that unproven screening benefits outweigh known drawbacks.

Limitations

While the primary limitations to our findings are those inherent to the existing evidence, our review was limited to English language publications. There may be relevant studies published in non-English language. However, discussion with our nominating partners and Technical Expert Panel members did not lead to identification of important studies not included in our report. Furthermore, the primary focus of this report is screening individuals at increased risk in the USA. Potential differences in patients, disease etiology, screening performance, and treatment approaches from non-English language countries probably have lower applicability to USA settings. Thus, limiting our inclusion to English language is unlikely to change findings.

Other limitations are primarily due to the existing evidence. The use of the HCC diagnosed population does not permit reliable assessment of evidence related to the questions precluding assessment of individuals undergoing screening not diagnosed with HCC. We were unable to capture harms or cost data associated with screening, as individuals with increased risk are not included in these studies.

## FUTURE RESEARCH

Nearly 10 years ago, Kansagara and colleagues identified evidence gaps and provided research suggestions.^58^ These gaps are long standing, have been noted by others, and remain today. For example, Lederle and Pocha as well as Atkins et al, noted uncertainty as to whether HCC screening among individuals at increased risk reduces all-cause or HCC mortality as well as the comparative effectiveness of screening strategies including intervals, imaging modalities, additive value of AFP to imaging tests, and in which at-risk populations screening may be effective.^59^ Lee and Brennan^60^ point out that rather than implementation of wide-spread HCC screening in at-risk adults, “a good case can be made that professional ethics prohibits providing unproven diagnostic screening tests, even if there is substantial demand from patients.” They noted uncertainty about the natural history of HCC, especially smaller lesions suspicious for HCC detected by imaging as well as harms of overdiagnosis and overtreatment. Understanding the cost, burden, and financial toxicity of screening and downstream evaluation and treatment as well as the cost effectiveness of screening programs is required. Our review demonstrated that some of the highlighted research gaps persist. In particular, randomized trials of screening versus no screening are needed in the target populations. Rigorous studies are needed to address choice and implementation of screening strategies. Screening requires adequate performance, feasibility, and limited harms. These issues can be addressed with study designs appropriate to the question, with emphasis on inclusion of the at-risk population and, where feasible, randomization.

The VA-CSP #2023: PREventing liver cancer Mortality through Imaging with Ultrasound versus MRI (PREMIUM Study) is an important large, randomized trial evaluating the comparative effectiveness of HCC screening by ultrasound + AFP every 6 months versus abbreviated MRI (aMRI) + AFP every 6 months among patients with cirrhosis who have a high risk of HCC based on an estimated annual HCC risk >2.5%. The primary outcome is HCC-related mortality, with overall survival as a secondary outcome. Study sample size and follow-up are intended to detect reductions in HCC mortality judged as clinically meaningful when including screening and treatment harms as well as health system and patient burdens and costs (ie, 30% relative reduction).^61^

Study principal investigators focus enrollment on individuals with cirrhosis at highest HCC risk yet with limited co-morbidities and note weaknesses in existing evidence and the need for screening RCTs with better strategies than currently used. While screening with ultrasound +/- AFP is recommended by some organizations, they note that it has unacceptably low sensitivity and specificity for early-stage HCC and no demonstrable effectiveness in reducing HCC-related mortality.

This trial cannot assess the fundamental unanswered question of whether any screening is effective compared with no screening. PREMIUM will also not assess whether less intensive ultrasound screening (eg, ultrasound every 12 months +/- AFP) results in similar mortality with lower screening burden and costs than more intensive strategies. A 3-arm study that included no screening was not proposed due to feasibility. If aMRI is found not more effective than ultrasound + AFP, attempts to estimate whether ultrasound + AFP reduces mortality versus no screening will be challenging.

The PREMIUM design has been considered analogous to the NCI’s National Lung Screening Trial in which plain chest radiography was compared to low-dose computed tomography without a no screening arm. However, prior to NLST findings of computed tomography effectiveness versus chest x-ray, there was not a widely recommended or implemented lung cancer screening program, unlike the current situation with HCC. Thus, a null NLST finding would not have resulted in implementation of widespread CXR screening. Furthermore, because the annual HCC incidence for the large majority of individuals in whom screening is recommended by AASLD is more than 10-fold lower than those eligible for enrollment in PREMIUM (0.2% versus 2.5%), any HCC mortality reduction in this lower risk population will be much smaller than could be detected in PREMIUM. Thus, incorporating harms, costs, and burden is especially relevant in developing screening recommendations in this large population of lower risk individuals and emphasizes the importance of conducting RCTs of screening versus no screening in individuals with HCC incidence <2.5%.

Observational research may also be able to address evidence gaps. A useful research framework is target trial emulation. The focus is on a hypothetical trial designed to answer the question. The trial PICOT is used to define the observation study and analysis. If the target population is those at high risk of HCC, then this population must be included. Target trial emulation of colon cancer screening is described in Garcia-Albeniz et al.^62^ This framework provides a tool for analysis of observational data that addresses biases specific to cancer screening. The comparison group to the exposed group must be similar, and thus would include those eligible to be screened who were not screened when first eligible. This strategy avoids the time-dependent confounding due to screening history.

The current review highlights continued uncertainty. Future work should focus on filling evidence gaps reinforcing clinical equipoise around our key questions and suggest research to address these, including whether screening is effective; the harms, burden and costs of screening and associated evaluations and treatments; choice of screening method, intervals, and populations considered at increased HCC risk; and, if of net benefit, efficient and effective implementation strategies.

## CONCLUSIONS

Evidence is very uncertain whether screening for HCC in individuals at increased risk reduces all-cause or HCC mortality. Evidence is also very uncertain as to the comparative effectiveness of varying screening strategies including screening intervals, imaging modalities, additive value of AFP to imaging tests, and in what populations screening may be effective. Harms data were limited regarding psychological distress, liver biopsy complications, renal insufficiency, overdiagnosis, and financial burden. However, all screening strategies have diagnostic- and treatment-induced harms, patient and clinician burden, and costs. Randomized trials evaluating screening versus no screening as well as different screening strategies are needed. More rigorous observational studies and use of target trial emulation as a framework for design could aid in designing observational studies to provide greater certainty. Until methodologically higher quality studies are available, the current state of the evidence seriously challenges HCC screening implementation and patient-clinician decision-making.