# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Appendix.

## OVERVIEW OF INCLUDED STUDIES

We identified 171 potentially relevant articles after deduplication and title and abstract screening. Of these, 74 primary studies met eligibility criteria: 5 RCTs and 69 observational studies (5 cohort, 2 case-control, 62 HCC cohort). Of the 5 RCTs, 2 were rated some concerns RoB, while the other 3 were rated high RoB. Of the 5 cohort studies, 1 was rated serious RoB, and the other 4 were rated critical RoB. Of the 62 HCC cohort studies, 11 were rated serious RoB, and the remaining 51 were rated critical RoB. Of note, we designated studies that only included in their analyses individuals who already had HCC as “HCC Cohort” to describe these separately from traditional cohorts or casecontrol studies or randomized controlled trials evaluating “high-risk individuals.” Characteristics of all eligible studies are shown in Table 1.

Individuals with cirrhosis made up 80% or more of the study sample in 7 studies rated as at low risk of bias, having some concerns, or at serious risk of bias. Only 3 of these studies were conducted in the USA and all enrolled Veterans at VA medical centers (1 RCT, 1 case-control study, and 1 HCC cohort study). Additionally, while 5 studies reported all-cause mortality, only 1 was conducted in the USA (in a non-VA setting). None of the 5 studies reporting overall survival and only 2 of the 5 studies reporting HCC-specific mortality were conducted in North America (both in USA Veterans; 1 RCT and 1 case-control study). Among the 3 studies conducted in North America not rated as high or critical RoB, 1 RCT evaluated ultrasound +/- AFP every 6 months versus CT every 12 months plus AFP every 6 months, 1 case-control study compared ultrasound plus AFP within 4 years of a HCC diagnosis versus no screening, and 1 HCC cohort study evaluated screening with any imaging modality (ultrasound, MRI, or CT) +/- AFP versus no screening.

Table 1 Characteristics of Included Studies

| | # Studies by Risk of Bias^*^ | | | Total
Characteristics | | Low | Some Concerns^†^ or Serious | High^†^ or Critical^‡^ | Total
Study Design
Randomized Controlled Trial | | - | 2^†^ | 3^†^ | 5
Case-Control | | 2 | - | - | 2
Cohort | | - | 1 | 4 | 5
HCC Cohort | | - | 11 | 51 | 62
Etiology Characteristics
Cirrhosis Requirement | | 1 | 4 | 13 | 18
Large Proportion (≥80%) Cirrhosis | | - | 2 | - | 2
Population Characteristics
Veteran Only | | 2 | 1 | 3 | 6
Country
North America | | 2 | 4 | 14 | 20
Asia | | - | 6 | 20 | 26
Europe | | - | 3 | 16 | 19
South America | | - | 1 | 2 | 3
Australia/New Zealand | | - | - | 6 | 6
Outcomes Reported
All-Cause Mortality | | - | 10 | 13 | 23
Overall Survival | | - | 9 | 52 | 61
HCC-Specific Mortality | | 2 | 4 | 6 | 12
HCC Stage at diagnosis | | - | 5 | 32 | 86
Sensitivity/Specificity | | - | 1 | 1 | 2
Percent Curative | | - | 7 | 39 | 46
Financial Burden | | - | 2 | - | 2
Adherence | | - | - | - | 0
Overdiagnosis | | - | - | - | 0
Diagnosis with Biopsy | | 2 | 3 | - | 5
Psychological Distress | | - | - | - | 0
Liver Transplant | | 2 | 6 | 19 | 27
Data Sources
EMR | | 2 | 4 | - | 6
Chart Review | | 1 | 3 | - | 4
Non-USA Administrative | | - | 3 | - | 3
Non-USA Registry | | - | 4 | - | 4
Comparison
Screening vs None | Any Imaging +/- AFP vs None | - | 1 | - | 1
Screening vs None | US (6 mo) vs None | - | 1 | - | 1
Screening vs None | US + AFP (6-12 mo) vs None | - | 2 | - | 2
Screening vs None | US + AFP (4 years before diagnosis) vs None | 1 | - | - | 1
Screening vs None | US + AFP (6-12 mo) vs incidentally detected (none) vs symptomatically detected (none) | - | 1 | - | 1
Screening vs None | US +/- AFP vs None | 1 | | - | 1
Multiple Screening Intervals vs None | US (6 mo) vs US (other intervals) vs None | - | 2 | - | 2
Multiple Screening Intervals vs None | US + AFP vs US (other intervals) vs None | - | 1 | - | 1
Multiple Screening Intervals vs None | US +/- AFP (routine) vs US +/- AFP (irregular) vs None | - | 1 | - | 1
Screening Intervals | US (3 mo) vs US (6 mo) | - | 2 | - | 2
US vs Other Modalities | US vs US + CT | - | 1 | - | 1
US vs Other Modalities | US positive & AFP negative vs both US & AFP positive vs US negative & AFP positive | - | 1 | - | 1
US vs Other Modalities | US + AFP vs CT + AFP | - | 1 | - | 1

Notes.

* Risk of bias was assessed using ROBINS-I for observational studies, and RoB2 for RCTs.

† ”Some concerns” and “high” used for RCTs only.

‡ Data on data sources, study start year, and comparison was not collected for studies judged to be high or critical risk of bias.

Abbreviations. AFP=alpha-fetoprotein; CT=computed tomography; EMR=electronic medical records; HCC=hepatocellular carcinoma; mo=month; US=ultrasound.

## RANDOMIZED CONTROLLED TRIALS

We identified 5 RCTs, 3 of which were assessed as high RoB.^18–20^ None were adequately designed or executed to address the effectiveness or comparative effectiveness and harms of screening especially among individuals with cirrhosis. All 3 trials (including the only 2 RCTs evaluating screening versus no screening) were assessed as high risk of bias in the domain “bias due to deviations from intended interventions,” with particular concern around adherence to the intervention and the impact this would have on the outcome. The high risk of bias trials enrolled patients mainly with hepatitis B and without cirrhosis. Results may not be applicable to a USA setting or those with cirrhosis. Other domains of concern varied across studies, and included the process of randomization, missing data, and selection of the reported results. The analytic approaches used in these trials were also concerning, including not accounting for clustering^19–21^ and in some instances not applying an intention-to-treat methodology or blinding of outcome assessment.^19,21^ The remaining 2 trials were assessed to be some concerns (Appendix), and are discussed below and included in certainty of evidence tables.^22,23^ Summary characteristics for all RCTs are shown in Table 2, and detailed trial characteristics and results for RCTs rated some concerns RoB can be found in the Appendix.

Table 2 Characteristics of All Eligible RCTs

Study Country | Sample Size Follow-Up | Population | Intervention Characteristics | Comparator | Outcomes Assessed
Some Concerns Risk of Bias
Pocha, 2013^22^; USA^*^ | N = 163; 31-35 months | 100% cirrhosis | Ultrasound +/- AFP every 6 months | CT +/- AFP every 12 months (AFP every 6 months) | HCC-specific mortality, stage at HCC diagnosis, % receiving transplant, % diagnosed with biopsy, false +/-, financial burden
Trinchet, 2011^23^; France/Belgium | N = 1278; 5-years | 100% cirrhosis | Ultrasound every 3 months | Ultrasound every 6 months | All-cause mortality, overall survival, HCC-specific mortality, % receiving transplant
High Risk of Bias
Chen, 2003^21^; China | N = 5581 | Hepatitis B | AFP (+ultrasound if AFP >200 μg/l or >100 μg/l more than twice) | No screening | All-cause mortality, overall survival, stage at HCC diagnosis, sensitivity/specificity
Wang, 2013^19^; Taiwan | N = 744 | Hepatitis B and C | Ultrasound every 4 months | Ultrasound every 12 months | Overall survival, stage at HCC diagnosis, % receiving curative treatment, % receiving transplant
Zhang, 2004^20^; China | N = 18816 | Hepatitis B or history of chronic hepatitis | Ultrasound +/- AFP every 6 months | No screening | Overall survival, HCCspecific mortality, stage at HCC diagnosis, % receiving curative treatment

Notes.

* Conducted in VHA.

Abbreviations. AFP=alpha-fetoprotein; CT=computed tomography; HCC=hepatocellular carcinoma; US=ultrasound.

### Ultrasound at 3 Months versus Ultrasound at 6 Months

Trinchet et al investigated screening for HCC via ultrasound every 3 months compared to screening via ultrasound every 6 months.^23^ The trial was conducted in France and Belgium among individuals with cirrhosis (N = 1278) and reported outcomes at 5-year follow-up. Compared with screening every 6 months, ultrasound screening at 3 months did not result in any significant differences in all-cause mortality, HCC-specific mortality, or overall survival. Results suggest there may be no benefits of more frequent screening with ultrasound (every 3 months) compared with less frequent screening with ultrasound (every 6 months) (low COE, Table 3).

There was also no significant difference in the number of patients receiving liver transplants between the 2 groups (17/640; 2.4% vs 13/638; 2.0%; p = NR).

### Ultrasound at 6 Months versus CT at 12 Months

A trial by Pocha et al investigated screening for HCC via ultrasound plus AFP every 6 months compared to screening via CT every 12 months (with AFP every 6 months).^22^ The trial was small (N = 163) and conducted in the USA in a Veteran population with cirrhosis. Mean follow-up ranged from 31-35 months (CT arm and ultrasound arm, respectively). Compared with screening via CT at 12 months, ultrasound screening at 6 months did not result in any significant differences in HCC-specific mortality. The evidence is very uncertain on the effect of ultrasound screening every 6 months compared with CT screening every 12 months on HCC-specific mortality (very low COE, Table 3).

Compared with screening via CT at 12 months, ultrasound screening at 6 months did not result in any significant differences in number of patients receiving liver transplant (4/83; 4.8% vs 2/80; 2.5%; p-value not reported), the number of patients receiving biopsy for diagnosis, BCLC stage at HCC diagnosis, or false positive or negative imaging.

Study authors reported the sensitivity and specificity of ultrasound for detection of HCC was 71.4% and 97.5%, respectively, with a positive predictive value of 83.3% and a negative predictive value of 95.1%. For CT, sensitivity and specificity were 66.7% and 94.4%, respectively, with a positive predictive value of 50.0% and negative predictive value or 97.1%.

Study authors used VHA and Medicare 2013 cost estimates to calculate the total cost to detect 1 HCC with ultrasound. Costs ranged from $12,069 in the VA to $17,041 in non-VA settings. The estimated cost with CT ranged from $18,768 (VA) to $57,383 (non-VA). No overall cost effectiveness assessing incremental cost effectiveness ratios for quality-adjusted life years was conducted.

Table 3 Certainty of Evidence Ratings for Randomized Controlled Trials Rated Some Concerns Risk of Bias

Outcome Follow-Up No. of Participants (Studies) | Relative Effect (95% CI) | Anticipated Absolute Effects (95% CI) | | | Certainty | Comments
Ultrasound Screening Every 3 Months Compared to Every 6 Months in Adults at Increased Risk for HCC
| | Screening Every 6 Months | Screening Every 3 Months | Difference
All-Cause Mortality; Follow-Up: mean 5 years; N = 1278; (1 RCT)^23^ | RR 0.88 ^†^; (0.7, 1.2) | 12.1% | 11.3% (8.4, 15.2) | 1.5% fewer (4.5 fewer to 2.3 more) | ⨁⨁◯◯; Low^a,b^ | There may be little to no difference in all-cause mortality when US screening every 3 months compared with US screening every 6 months.
HCC-Specific Mortality; Follow-Up: mean 5 years; N = 1278; (1 RCT)^23^ | RR 1.41 ^†^; (0.7, 2.9) | 2.0% | 2.9% (1.4, 6.0) | 0.8% more (0.7 fewer to 3.9 more) | ⨁⨁◯◯; Low^a,b^ | There may be little to no difference in HCC-specific mortality when US screening every 3 months compared with US screening every 6 months.
Overall Survival at 5 years; N = 1278; (1 RCT)^23^ | 84.9% survival at 5 years in the 3-month screening group, compared to 85.8% survival in the 6-month screening group (p = 0.38). | | | | ⨁⨁◯◯; Low^a,b^ | There may be little to no difference in overall survival when US screening every 3 months compared with US screening every 6 months.
Ultrasound Screening Every 6 Months Compared to CT Screening Every 12 Months in Adults at Increased Risk for HCC
| | CT Screening Every 12 Months | US Screening Every 6 Months | Difference
HCC-Specific Mortality; Follow-Up: 31-35 months; N = 163; (1 RCT)^22^ | RR 0.71 ^†^; (0.2, 2.1) | 8.8% | 6.2% (2, 18.7) | 2.5% fewer (6.7 fewer to 10 more) | ⨁◯◯◯; Very low^a,c^ | The evidence is very uncertain on the effect of US screening every 6 months compared with CT screening every 12 months on HCC-specific mortality.

Notes. The risk in the intervention group (and its 95% confidence interval) is based on the assumed risk in the comparison group and the relative effect of the intervention (and its 95% CI).

† Calculated by review team.

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect. Explanations:

a Downgraded 1 level for risk of bias (rated some concerns overall)

b Downgraded 1 level for imprecision (wide confidence interval)

c Downgraded 2 levels for imprecision (wide confidence intervals and optimal information size criterion not met)

Abbreviations. CI=confidence interval; CT=computed tomography; HCC=hepatocellular carcinoma; no.=number; RCT=randomized controlled trial; RR=risk ratio.

## CASE-CONTROL STUDIES

We identified 2 case-control studies, both assessed as low risk of bias (Appendix) and conducted in the VHA.^24,25^ Summary characteristics for both studies are shown in Table 4 below, and detailed study characteristics and results can be found in the Appendix.

### Ultrasound With or Without AFP versus No Ultrasound

Both case-control studies investigated HCC screening defined as at least 1 ultrasound in the 4 year period prior to index date.^24,25^ Both studies were of a matched case-control design and were conducted in a VA population. In the first study, Moon et al,^24^ defined cases as individuals with cirrhosis who died of HCC, whereas Su et al^25^ defined cases as individuals with hepatitis B who died of HCC. Controls were defined as patients with cirrhosis (Moon et al) or hepatitis B (Su et al) who did not die of HCC. As the population of interest for each study was different, there were slight differences in matching criteria, as follows: in the Moon et al study cases and controls were matched on: 1) year of diagnosis, 2) race and ethnicity, 3) age, 4) sex, 5) primary etiology of cirrhosis, 6) MELD score at time of cirrhosis diagnosis, and 7) VA facility in which the diagnosis of cirrhosis was made. Individuals in Su et al were matched on 1) hepatitis B diagnosis date, 2) age, 3) sex, 4) race/ethnicity, 5) cirrhosis, 6) antiviral therapy exposure, 7) hepatitis B antigen status, and 8) viral load.

For HCC-specific mortality, Moon reported an odds ratio (OR) of 0.87 (95% CI [0.44, 1.72]) for ultrasound plus AFP compared with no screening among individuals with cirrhosis.^24^ In contrast, for HCC-specific mortality, Su et al reported an OR of 0.21 (95% CI [0.09, 0.50]) in favor of ultrasound screening with or without AFP versus no screening among a population of individuals with hepatitis B.^25^ We downgraded for imprecision, study limitations, and inconsistency in effects across these 2 studies and their included cases/controls (cirrhosis/hepatitis B). We concluded that the overall evidence is very uncertain on the effect of ultrasound screening plus AFP compared with no screening on HCC-specific mortality among adults at increased risk for HCC (very low COE, Table 5).^24,25^

Both Moon and Su provided a count of the number of cases that were diagnosed via histology, 69 (29%) and 79 (46.7%), respectively, and those that received a transplant, 0 and 2 (1.2%), respectively.

Table 4 Characteristics of All Eligible Case-Control Studies

Study; Country; Risk of Bias | Sample Size; Follow-Up | Population | Intervention Characteristics | Comparator | Outcomes Assessed
Moon, 2018^24^; USA (VHA); Low | N = 476; 4 years | 100% Cirrhosis | Ultrasound + AFP at least once in past 4 years | No screening | HCC-specific mortality, diagnosis with biopsy, % receiving transplant
Su, 2021^25^; USA; Low | N= 338; 4 years | 100% Hepatitis B | Ultrasound +/- AFP at least once in past 4 years | No screening | HCC-specific mortality, diagnosis with biopsy, % receiving transplant

Abbreviations. AFP=alpha-fetoprotein; HCC=hepatocellular carcinoma.

Table 5 Certainty of Evidence Ratings for Case-Control Studies

Outcomes | No. of Participants (Studies) | No. Cases With Event | No. Controls With Event | Relative Effect (95% CI) | Certainty | Comments
HCC-Specific Mortality Timing of Exposure: 0-4 years before index date | 407 cases 407 controls (2 observational studies)^24,25^ | 168 | 214 | Not pooled | ⨁◯◯◯; Very low^a,b,c^ | The evidence is very uncertain on the effect of screening with ultrasound with or without AFP compared with no screening on HCC-specific mortality in adults at increased risk for HCC.

Notes. GRADE Working Group grades of evidence.

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded 1 level for study limitations (concerns about population chosen by study authors for control group)

b Downgraded 1 level for inconsistency (one study in individuals with increased risk (cirrhosis) found no benefit while another study of individuals with increased risk (hepatitis B) showed benefit)

c Downgraded 1 level for imprecision (optimal information size criterion not met)

d Downgraded 2 levels for imprecision (wide confidence intervals and optimal information size criterion not met)

Abbreviations. AFP=alpha-fetoprotein; CI=confidence interval; HCC=hepatocellular carcinoma; no.=number; OR=odds ratio.

## COHORT STUDIES

We identified 1 cohort study among individuals at increased risk. The study was assessed as serious risk of bias (Appendix).^26^ Summary characteristics for the study are shown in Table 6 below, and study characteristics and results can be found in the Appendix.

### Ultrasound versus Ultrasound Alternated With CT

This study investigated ultrasound every 6 months after a diagnosis of cirrhosis versus ultrasound alternating with dynamic computed tomography (CT) every 6 months, with the expectation that CT exams should be performed at least 2 times every 2 years on a regular basis, after diagnosis of cirrhosis to screen for very-early-stage HCC.^26^ The study retrospectively captured 1,235 patients over a median follow up time of 4.5 years with hepatitis B-related cirrhosis from 4 hospitals in South Korea. Authors reported 10-year overall mortality was significantly lower in those with alternating ultrasound and CT versus those with ultrasound alone (hazard ratio [HR] = 0.42, 95% CI [0.24, 0.73]) after adjusting for age, gender, diabetic status, hepatitis B status, HBV serum DNA levels, serum aspartate aminotransferase, alanine aminotransferase, albumin, total bilirubin, creatinine, prothrombin time, platelet count, Child-Pugh score, model for end-stage liver disease score, fibrosis index, platelets, and gender-hepatitis B scores. The evidence is very uncertain on the effect of ultrasound screening at 6 months on overall mortality compared to alternating ultrasound and CT screening every 6 months (very low COE). The authors reported an overall survival of patients undergoing ultrasound alternating with CT at 96.5% versus 93.3% (p = 0.03) for those receiving ultrasound alone. The evidence is very uncertain on the effect of ultrasound screening at 6 months on overall survival compared to alternating ultrasound and CT screening at 6 months (very low COE).

Table 6 Characteristics of Cohort Studies (Rated Serious RoB)

Study; Country; Risk of Bias | Sample Size; Follow-Up | Population | Intervention Characteristics | Comparator | Outcomes Assessed
Kim, 2020^26^; Korea; Serious | N=992; 4.5 years (median) | 100% cirrhosis | Ultrasound every 6 months | Ultrasound alternating with CT every 6 months | All-cause mortality; Overall survival

Abbreviations. CT=computed tomography.

Table 7 Certainty of Evidence Ratings for Cohort Studies

Outcomes | Follow-Up (Studies) | Reported Results | Certainty | Comments
Ultrasound Screening at 6 Months Compared With Ultrasound Alternating With CT Screening At 6 Months in a Population Diagnosed With HCC
All-Cause Mortality | 10 years (1 observational study)^26^ | US alternating with CT had significant association with all-cause mortality compared to US exam alone (HR = 0.42, 95% CI [0.24, 0.73], p = 0.002) | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of US screening at 6 months on all-cause mortality compared with alternating US and CT screening at 6 months.
Overall Survival | 10 years (1 observational study)^26^ | 10-year overall survival among those undergoing US alternating with CT at 96.5% which was significantly higher than 93.3% among those with US exam alone. | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of US screening at 6 months on overall survival compared with alternating US and CT screening at 6 months.

Notes. GRADE Working Group grades of evidence.

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Downgraded 2 levels for study limitations (various concerns related to confounding, selection bias, and misclassification of interventions)

b Downgraded for imprecision (optimal information size criterion not met)

Abbreviations. CI=confidence interval; CT=computed tomography; HCC=hepatocellular carcinoma; HR=hazard ratio; US=ultrasound.

## HCC COHORT STUDIES

We identified 62 HCC cohort studies, 51 of which were assessed as critical RoB. The remaining 11 studies were deemed as serious RoB (Appendix). We present summary characteristics in Table 8 below and detailed study characteristics in the Appendix. However, as noted, all HCC cohort studies were rated as either critical or serious RoB. Additionally, all HCC cohorts were solely comprised of individuals with HCC and cannot validly assess HCC screening effectiveness and harms.

Table 8 Characteristics of HCC Cohort Studies (Serious RoB)

Study; Country; Risk of Bias | Sample Size; Follow-Up | Population | Intervention Characteristics | Comparator | Outcomes Assessed
An, 2020^27^; Korea; Serious | N = 1776; 5 years | 100% cirrhosis 81.9% HBV | Ultrasound + AFP biannually | HCC detected by 1 of 3 test results: US positive but AFP negative; both US & AFP positive; US negative but AFP positive | All-cause mortality; Overall survival; HCC-specific mortality; HCC stage at diagnosis; Diagnosis with biopsy; %Curative treatment; %Transplant
Bae, 2021^28^; Korea; Serious | N = 64674; 5 years | 63.4% cirrhosis 53.8% HBV | Ultrasound + AFP at least every 6 months | US + AFP intervals every 7-12m, every 13-24m, every 25-36m, No screening | All-cause mortality; %Curative
Kim, 2018^29^; Korea; Serious | N = 1402; 5 years | 78.3% cirrhosis 82.7% HBV | Ultrasound +/AFP at least every 8 months for at least 2 years prior to diagnosis | No screening, Irregular screening | All-cause mortality; Overall survival; HCC stage at diagnosis; %Curative treatment
Mittal, 2016^30^; USA^*^; Serious | N = 887; NR | 100% cirrhosis | US/MRI/CT +/AFP ≥1 test in 2 years prior to diagnosis | No screening | All-cause mortality; HCC stage at diagnosis; %Transplant
Pelizzaro, 2022^31^; Italy; Serious | N = 1107; 3.1 years (median) | 100% cirrhosis | Ultrasound every 3±1 months | Ultrasound every 6±1 months | All-cause mortality; Overall survival; HCC-specific mortality; %Curative; %Transplant; Financial burden
Piñero, 2019^32^; Argentina; Serious | N = 553; 5 years | Cirrhosis NR | Ultrasound every 6 months for at least 1 year | No screening | All-cause mortality; HCC stage at diagnosis
Tanaka, 2006^33^; Japan; Serious | N = 384; 5 years | 80% cirrhosis | Ultrasound + AFP every 6 months | No screening | Overall survival
Thein, 2015^34^; Canada; Serious | N = 1483; 5 years | Viral hepatitis with or without cirrhosis | Ultrasound ≥1 tests annually | No screening, Inconsistent screening | All-cause mortality; Overall survival; %Curative
Tong, 2017^35^; USA; Serious | N = 333; 5 years | 77% cirrhosis 51.5% HBV | Ultrasound + AFP every 6-12 months | No screening | Overall survival; %Transplant; %Curative
Trevisani, 2004^36^; Italy; Serious | N = 363; 17 months | Cirrhosis NR 9.5% HBV | Ultrasound + AFP every 6-12 months | No screening | Overall survival
Wu, 2016^37^; Taiwan; Serious | N = 52823; 5 years | 52.4% cirrhosis 28.32% HBV | Ultrasound every 1-6 months | Ultrasound every 7-12m, every 13-24m, every 2536m, No screening | All-cause mortality; Diagnosis with biopsy; %Curative treatment

Notes.

* Conducted in VHA.

Abbreviations. AFP=alpha-fetoprotein; CT=computed tomography; HBV=hepatitis B virus; HCC=hepatocellular carcinoma; m=months; MRI=magnetic resonance imaging; US=ultrasound.

### Any Imaging versus No Screening

Nine HCC cohort studies investigated outcomes of screening using imaging (+/- AFP) compared to no imaging undertaken before HCC diagnosis. The screening modality utilized in each study is captured in Table 8. Two studies compared routine screening to no screening and irregular screening.^29,34^ A third study compared routine screening to 2 non-screening arms: HCC detected symptomatically and HCC detected incidentally.^36^ Two studies compared the effects of routine screening (1-6 months) to other screening intervals (7-12 months/13-24 months/25-36 months) in addition to comparisons with no screening.^28,37^

The HCC cohort studies varied geographically: 4 studies were conducted in Asia (Taiwan,^37^ Japan,^33^ South Korea,^28,29^), 3 in North America (Canada,^34^ USA^30,35^), 1 in South America (Argentina^32^), and 1 in Europe (Italy^36^). Studies relied upon patient data retrieved from various sources. Studies used a variety of data sources to draw the population. Three studies used administrative claims databases;^28,34,37^ 2 used EMR data,^30,35^ and 2 used data from chart review.^33,36^ Two studies used data from national (non-USA) registries, 1 with EMR^32^ while the other supplemented with chart review.^29^

Studies varied widely in sample size (ranging from 333 to 64,674), liver disease etiologies (cirrhosis, hepatitis B, hepatitis C, alcohol-related disease), and follow-up (17 months to 8 years) (Table 8).

Six studies reported all-cause mortality rates when comparing screening with no screening.^28–30,32,34,37^ Authors reported hazard ratios that ranged from 0.51 to 0.79. Four of the studies reporting an all-cause mortality outcome also included arms which compared the effects of routine versus irregular screening schedules.^28,29,34,37^ These results and information relating to lead-time adjustment are shown in the Appendix. We downgraded the evidence due to study limitations and indirectness and assessed the evidence as very uncertain on the effect of screening on all-cause mortality (very low COE).

Five studies evaluated the effects of imaging versus no screening on overall survival.^29,33–36^ Results for this outcome were not consistently reported, although authors reported significantly longer survival for those under screening using imaging when compared to those not under screening. We assessed, downgrading for study limitations and indirectness, that the evidence is very uncertain regarding the effect of screening on all-cause survival (very low COE). Two of these studies also compared routine screening to irregular screening schedules.^29,34^ These results are shown in the Appendix.

Three studies reported BCLC HCC stage at diagnosis as an outcome.^29,30,32^ Kim et al reported a higher proportion of patients receiving early stage diagnosis (BCLC 0-A-B) in the routine screening group (ultrasound +/- AFP, ≤8 months) compared with no screening (69.3% vs 40.3%).^29^ Piñero et al only reported the proportion diagnosed in early stage, 93.3% among patients undergoing ultrasound imaging at 6 month intervals.^32^ In a study investigating patients who had at least 1 imaging test (ultrasound/MRI/CT +/- AFP) performed in the 2 years prior to diagnosis, Mittal et al reported that early stage HCC was seen in 50% in patients compared to 33.7% in a non-screening group.^30^

Four studies reported the proportion of patients who received curative treatment in screening versus non-screening arms. Studies showed that routine screening was associated with increased receipt of curative treatment upon HCC diagnosis compared to non-screening arms. Tong et al investigated the effect of screening using ultrasound plus AFP and reported 60.1% of patients receiving curative treatment versus 26.6% of patients in the non-screening arm.^35^ Kim et al reported that 51.9% versus 19.7%, patients received curative treatment compared to non-screening and Bae et al reported 52.2% versus 23.3%. With respect to patients receiving ultrasound alone, Wu et al^37^ reported 29.4% received curative treatment compared to 19.7% in a mixed hepatitis B/C population, and Thein et al^34^ reported 59.3% in the routine imaging group received curative treatment compared to 43.1% in the nonscreening group.

Two studies reported the number of patients receiving liver transplant as an outcome. Mittal et al reported that a similar proportion of patients undergoing regular screening (imaging +/- AFP) received liver transplant (3.6%) compared to a non-screening group (3.8%).^30^ Tong et al reported that in a population that included a substantial proportion of HBV patients (>50%), individuals undergoing routine imaging (ultrasound plus AFP) were more likely to receive liver transplant (21.7%) than those in a non-screening group (5.7%).^35^

### Ultrasound Every 3 Months versus Ultrasound Every 6 Months

A single study, Pelizzaro et al, investigated the effects of ultrasound imaging at 3±1month intervals (N = 109) compared to 6±1 month intervals (N = 998).^31^ This study took place in Italy and acquired patient data from a national registry. The population was comprised primarily of patients with hepatitis C (79%) liver disease etiology; all had cirrhosis.

Authors reported 5-year all-cause mortality of 69/109 (63.3%) in the 3-month group and 373/668 (55.8%) in the 6-month group (risk ratio [RR] = 1.02, 95% CI [0.88, 1.32]). With respect to HCCspecific mortality, the authors reported mortality in the 3-month group of 66.7% and 57.4% in the 6-month group. The authors reported a 5-year overall survival of 40.7% in the 3-month group and 47.2% in the 6-month group (HR = 0.87, 95% CI [0.67, 1.13]). Due to study limitations, imprecision, and indirectness of the study population, we assessed the evidence as very uncertain on the effect of screening at 3 months compared with 6 months on overall and HCC-specific mortality and overall survival (very low COE). These results and information relating to lead-time adjustment are shown in the Appendix.

Pelizzaro et al reported the proportion of patients receiving curative treatment: 69.7% and 68.2% in the 3- and 6-month arms, respectively (OR = 0.93, 95% CI [0.60, 1.45]). The authors also reported the proportion of patients receiving liver transplant, with 10.1% versus 0.5% in the 3- and 6-month arms, respectively.^31^ The authors reported financial burden of screening, with an average total cost per patient of €2905 in the 3-month arm compared to €1823 in the 6-month arm.^31^

### Ultrasound Plus AFP Every 6 Months With Outcomes Stratified by Ultrasound/AFP Test Results

#### Ultrasound and AFP Positive versus Ultrasound Positive but AFP Negative

One HCC cohort, An et al, investigated the effects of biannual ultrasound with AFP every 6 months.^27^ This study was conducted in South Korea with a population total of 1,776 patients. Data for the study population were accessed from the South Korean national registry and included a large majority of patients with cirrhosis (87.7%) and liver disease due to HBV (81.9%).^27^ Median follow-up (IQR) was 3.1 years (1.6-5.1).

The authors evaluated HCC cases and categorized them according to the results of ultrasound and AFP screening prior to HCC confirmation: 1) both Ultrasound and AFP positive: suspected malignant lesion on ultrasound and a high serum AFP test [≥20 ng/mL]); 2) ultrasound positive but AFP negative: suspected malignant lesion on ultrasound with a normal AFP result; 3) ultrasound negative but AFP positive. The reported HR for 5-year all-cause mortality for individuals with HCC detected by ultrasound and having a normal AFP versus those detected with both an ultrasound and AFP abnormality was 0.57 (95% CI [0.47, 0.69]). For overall survival, authors reported a survival of 69.9% in the ultrasound-positive alone group compared to 55.5% in the ultrasound- and AFP-positive group. For HCC-specific mortality, the HR for ultrasound positive versus ultrasound and AFP positive was 0.50 (95% CI [0.40, 0.63]).^27^ Due to serious study limitations and indirectness of the study population, we assessed that the evidence is very uncertain regarding the effect of screening based on both a positive ultrasound and AFP result versus ultrasound positive but AFP normal on overall and HCC-specific mortality (very low COE). Detailed results and information relating to lead-time adjustment are shown in the Appendix.

An et al reported HCC stage at diagnosis (BCLC), proportion of patients receiving curative treatment, and proportion receiving liver transplant. In the ultrasound-positive but AFP-normal group, 93.1% of patients were diagnosed with early stage HCC (BCLC 0-A-B) compared to 86% in the both ultrasound- and AFP-positive group.^27^ In the ultrasound-positive but AFP-normal group, 63.1% of patients were able to receive curative treatment compared with 56.4% of those in the both ultrasound- and AFP-positive group; 2.3% of patients in the ultrasound-positive and AFP-normal group versus 2.0% in the both ultrasound- and AFP-positive group received a liver transplant.^27^

#### Ultrasound and AFP Positive versus Ultrasound Negative but AFP Positive

An et al also evaluated the differences between the groups detected by AFP but ultrasound negative or HCC detected based on abnormal findings from both ultrasound and AFP. Over a maximum follow-up of 5.1 years, the mortality for AFP positive but ultrasound negative was 88/298 (29.5%) compared to both ultrasound and AFP positive (98/500 [39.6%]). The authors reported an HR of 0.74 (95% CI [0.57, 0.95]). HCC-specific mortality was 20.1% in the AFP-positive and ultrasound-negative group compared to 29.6% in the ultrasound- and AFP-positive group (HR = 0.67, 95% CI [0.50, 0.90]). Authors reported a survival of 55.5% in the ultrasound- and AFP-positive group compared to 64.8% survival in the AFP-positive but ultrasound-negative group.^27^ Due to severe study limitations and indirectness of the study population, we assessed that the evidence is very uncertain on the effect of screening based on both ultrasound- and AFP-positive results versus AFP positive but ultrasound negative on overall survival and overall and HCC-specific mortality (very low COE).

An et al reported differences with respect to HCC stage at diagnosis, proportion of patients receiving curative treatment, and proportion receiving liver transplant in the ultrasound- plus AFP-positive group compared to the AFP-positive but ultrasound-negative group. The authors reported that 86% of patients in the ultrasound- plus AFP-positive group and 89.6% in the AFP-positive but ultrasound-negative group were diagnosed with early-stage HCC (BCLC 0-A-B). Among those in the ultrasound-plus AFP-positive group, 56.4% received curative treatment compared with 60.1% in the AFP-positive but ultrasound-negative group, with 2% of patients in the ultrasound- plus AFP-positive group and 5% in the AFP-positive group receiving liver transplant.^27^

Table 9 Certainty of Evidence Ratings for HCC Cohort Studies

Outcomes | Follow-Up (Studies) | Reported Results | Certainty | Comments
Any Imaging (+/- AFP, Prior to HCC Diagnosis) Compared to No Screening (Prior to HCC Diagnosis) in a Population Diagnosed With HCC
All-Cause Mortality | 5-8 years; (6 observational studies)^28–30,32,34,37^ | HRs that ranged from 0.51 to 0.79. | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of screening with any imaging modality on all-cause mortality.
Overall Survival | 5-years; (5 observational studies); ^29^ ^,^ ^33^ ^–^ ^36^ | Multiple point estimates that generally suggest overall survival is significantly longer in those under screening when compared with those not under screening. | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of screening with any imaging modality on overall survival.
Ultrasound Screening at 3 Months Compared to Ultrasound Screening at 6 Months in a Population Diagnosed With HCC
All-Cause Mortality | Median 50 months; (1 observational study)^31^ | 69/109 (63.3%) in 3-mo group and 373/668 (55.8%) in 6-mo group (HR 0.93 [0.65 to 1.32]). | ⨁◯◯◯; Very low^a,b,c^ | The evidence is very uncertain on the effect of US screening every 3 months compared with US screening every 6 months on all-cause mortality.
Overall Survival | 5-year (1 observational study)^31^ | 40.7% in 3-mo group and 47.2% in 6-mo group (HR = 0.87, 95% CI [0.67, 1.13], p = 0.43). | ⨁◯◯◯; Very low^a,b,c^ | The evidence is very uncertain on the effect of US screening every 3 months compared with US screening every 6 months on overall survival.
HCC-Specific Mortality | 5-year; (1 observational study)^31^ | 66.7% in 3-mo group and 57.4% in 6-mo group attributed to HCC progression. | ⨁◯◯◯; Very low^a,b,c^ | The evidence is very uncertain on the effect of US screening every 3 months compared with US screening every 6 months on HCC-specific mortality.
Screening Biannually With US & AFP: Outcomes Stratified by US And AFP Results: (Prior to HCC) in a HCC Population: US Positive
All-Cause Mortality | 5-year; (1 observational study)^27^ | HR = 0.53 (95% CI [0.43, 0.64]). | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain regarding all-cause mortality for HCC detected based on biannual ultrasound positive compared with HCC detected with both ultrasound and AFP positive.
Overall Survival | 5-year; (1 observational study)^27^ | 69.9% in ultrasound group and 55.5% in ultrasound + AFP group. | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on overall survival for HCC detected based on ultrasound positive but AFP negative compared with HCC detected by both ultrasound and AFP positive.
HCC-Specific Mortality | 5-year; (1 observational study)^27^ | HR = 0.46 (95% CI [0.37, 0.58]). | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on HCC-specific mortality for HCC detected based on ultrasound positive but AFP negative compared with HCC detected based on both ultrasound and AFP positive.
Screening Biannually With US & AFP: Outcomes Stratified by US and AFP Results: (Prior to HCC) in a HCC Population: AFP Positive
All-Cause Mortality | 5-year; (1 observational study)^27^ | HR = 0.74 (95% CI [0.57, 0.95]). | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect on all-cause mortality for HCC detected based on both ultrasound and AFP positive compared to AFP positive but US negative.
Overall Survival | 5-year; (1 observational study)^27^ | 55.5% in ultrasound + AFP group and 64.8% in AFP group. | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect on overall survival for HCC detected based on ultrasound and AFP positive compared with AFP positive but US negative.
HCC-Specific Mortality | 5-year; (1 observational study)^27^ | HR = 0.67 (95% CI [0.50, 0.90]). | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect on HCC-specific mortality for HCC detected based on both ultrasound and AFP positive compared to AFP positive but US negative.

Notes. Calculated by review authors.

GRADE Working Group grades of evidence.

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Downgraded 2 levels for study limitations (various concerns related to confounding, selection bias and misclassification of interventions).

b Downgraded 1 level for indirectness (HCC population only, missing portion of at-risk population).

c Downgraded for imprecision (wide confidence intervals).

Abbreviations. AFP=alpha-fetoprotein; CI=confidence interval; HCC=hepatocellular carcinoma; HR=hazard ratio; mo=month; RR=risk ratio.