# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42023406164 (https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42023406164)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in the Appendix.

## ANALYTIC FRAMEWORK

The analytic framework shown in Figure 2 provides a conceptual overview of the key questions, populations, interventions, and outcomes. The population of interest is individuals at increased risk of HCC based on a current or past history of liver disease (including cirrhosis), viral infection, or alcoholic and metabolic liver disease. We were broad in our inclusion of a definition of “increased risk,” typically using author-defined populations of those undergoing screening and any included control group. Eligible outcomes judged as critical for decision-making included all-cause mortality, overall survival, HCC-specific mortality, and screening related harms (false +/-, psychological distress, liver biopsy complications, renal insufficiency, overdiagnosis, and financial burden). We also assessed stage of disease at detection and the percentage of individuals receiving potentially curative treatment, including surgical resection, ablative therapy, or liver transplantation. We did not consider intermediate outcomes associated with the intervention (eg, diagnostic accuracy or treatment-related harms), as they were outside the scope of the review question. We also evaluated whether screening benefits and/or risks varied by patient or disease characteristics (eg, patient demographics, comorbidities, disease etiology and severity) or screening protocol (eg, imaging modality or schedule).

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key question was the focus of this review: What are the benefits and harms of HCC screening among adults at increased risk? We were also interested in whether benefits and harms of HCC screening varied by the following factors:

- Patient or co-existing medical characteristics (eg, age, sex, race/ethnicity; comorbidities)
- Presence of cirrhosis
- Liver disease etiology (hepatitis, B, C, alcohol, metabolic liver disease), severity, or HCC risk
- Screening intervals (eg, semiannual, annual, biennial) or abdominal imaging technique
- Screening modality with or without AFP (ultrasound, MRI, CT)

Figure 2 Analytic Framework

Notes. *Pending ultrasound, MRI or CT may be undertaken as an additional triage/diagnostic test.

Abbreviations. AFP=alpha-fetoprotein; CKD=chronic kidney disease; CT=computed tomography; DM=diabetes melitus; HCC=hepatocellular carcinoma; MRI=magnetic resonance imaging.

Study eligibility criteria are shown in the table below.

| Eligibility Criteria
Population | Adults (≥18 years of age) at increased risk of HCC (broadly those with cirrhosis or current or past liver disease that may put them at increased HCC risk and as included by authors)
Intervention | Abdominal imaging (ultrasound, CT, or MRI (full or abbreviated)) with or without alpha-fetoprotein blood test for HCC screening (ie, not a diagnostic or monitoring test for a patient with known or suspected HCC)
Comparator | No HCC screening or compared to another abdominal imaging technique, eg, ultrasound vs CT or MRI (full or abbreviated) with or without alpha-fetoprotein blood test; HCC screening in patient and liver disease subgroups, at different intervals
Outcomes | All-cause mortality, overall survival, HCC-specific mortality, HCC-specific survival, receipt of curative intent treatment for HCC, HCC stage at diagnosis, screening-related harms (eg, liver biopsies, false positive and negative tests, financial burden associated with screening adherence, opportunity costs, psychological distress at incorrect diagnosis, overdiagnosis)
Study Design | RCT, comparative experimental or observational studies
Setting | Non-hospice

## SEARCHING AND SCREENING

Two previous reviews assessing the effectiveness of screening for HCC in chronic liver disease, Kansagara et al^13^ and Singal et al,^14^ were conducted in 2014 and 2022. We utilized and updated the published search strategy by Singal et al, searching in Embase and MEDLINE from July 1, 2020, through January 24, 2023. The publications included in those two reviews were added to the list of citations identified through the search (see the Appendix for complete search strategies). Additional citations were identified from hand-searching reference lists and consultation with content experts and our technical expert panel. English-language titles, abstracts, and full-text articles were independently reviewed by 2 investigators, and disagreements were resolved by consensus.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Effect information and population, intervention, and comparator characteristics were abstracted from all included studies. The internal validity (risk of bias [RoB]) of each included study was rated using the Cochrane Risk of Bias Tool 2.0 (RoB-2)^15^ for RCTs and the Risk of Bias in non-Randomized Studies-of Interventions (ROBINS-I)^16^ tool for observational studies. As required by the ROBINS-I tool, a list of confounders that must have been addressed by study authors was developed a priori to conducting assessments. We required observational studies to have included the following variables in their models: age, comorbidities, lead time, liver disease severity, and liver disease etiology. Studies that did not address these confounding variables were judged as having critical risk of bias and were not assessed further or included in detailed data abstraction or synthesis. All data abstraction and internal validity ratings were completed by 1 reviewer and verified by another; disagreements were resolved by consensus or discussion with a third reviewer (see the Appendix for risk of bias ratings).

## SYNTHESIS

Prior to analysis, we examined the clinical and methodological characteristics of the included studies to determine if appropriate for pooling. These included: screening modality (including screening intervals), HCC etiology and risk in both screening and control cohorts (within and across studies), comparison condition (eg, no screening or an alternate screening protocol), outcomes assessed in each group, patient demographics and comorbidities, and study design and country of origin. Although we planned to pool study results when feasible (see registered protocol for full details), we found that methodological and clinical variation among included studies precluded meta-analysis. Instead, we narratively synthesized available evidence by studies, populations, and interventions for each outcome.

We anticipated including mostly large observational studies and that even after adjustment for confounders, clinical variability and statistical heterogeneity would remain high. Indeed, after identifying eligible studies, we found that study methodology corresponded closely to risk of bias ratings and to the comparability of populations, interventions, and methodologies. Therefore, we organized results first by study design; within each study design section, outcomes are presented by screening method comparisons. Study authors categorized screening approaches in a variety of ways, so we grouped reported outcomes by screening strategies we judged to be most similar.

Our search included observational studies; thus, in addition to separating RCTs from observational studies we also stratified observational studies by design. Case-control and cohort studies yield different effect measures. We further separated cohort studies (which include the population at risk of HCC) from HCC cohort studies (which included only those diagnosed with HCC) because of the difference in target populations and potential biases. The difference in target population means that outcome measures (eg, all-cause mortality) in cohort studies and HCC cohort studies are not comparable. HCC studies are also further subject to lead-time bias (screening will artificially increase duration of follow-up and survival due to earlier diagnosis) and length-time bias (screening may select those with better prognosis). The table below summarizes the final grouping by study design.

Label | Study Design
RCT | Randomized controlled trial: interventions (screening or control) were randomly assigned at individual or group level.
Case-Control | A population of cases (those with outcome of interest, eg, HCC mortality) and matched controls (those who did not have the outcome) were assessed for exposure to intervention.
Cohort | A population of individuals at risk for HCC were followed longitudinally over time and both exposure to intervention (screening vs control) and subsequent outcomes were assessed from this longitudinal data (often retrospective from EHR data).
HCC Cohort | Similar to a cohort study, but study selection limited to those with intermediate outcome, in this case a diagnosis of HCC. It is not possible to extrapolate outcomes in this subgroup to population at risk.

### Strength of Evidence

We used the Grading of Recommendations, Assessment, Development, and Evaluation (GRADE) methodology to rate overall certainty of evidence for critical outcomes as high, moderate, low, or very low.^17^ We engaged organizational partners and a panel of clinical experts to determine outcomes critical for decision making. We also sought their input to guide decisions about comparability of populations, screening modalities, and comparisons to permit study result grouping. We did not attempt to derive minimally important thresholds, and thus our judgments on certainty of evidence rely on statistical rather than potential clinical significance.