# BACKGROUND

Hepatocellular carcinoma (HCC) is the sixth most common cancer and the second leading cause of cancer-related death worldwide.^1^ An estimated 41,210 Americans will be diagnosed with liver cancer in 2023 (approximately 9.5 per 100,000), with 29,380 expected to die from the disease.^2^ Results of the Surveillance, Epidemiology, and End Results Program (SEER) show that age-adjusted rates of liver and intrahepatic bile duct cancer in the USA more than doubled between 1992 and 2012 (4.6 to 9.3 per 100,000) before leveling off over the last decade (see Figure 1).^3^ Mortality from the disease has followed a similar trajectory (from 3.9 per 100,000 in 1992 to 6.7 per 100,000 in 2016). Liver cancer accounts for approximately 2% of all new cancer cases in the USA.^3^

HCC is the most common form of primary liver cancer and makes up approximately 75% of all liver and bile duct cancers.^4^ HCC incidence and mortality vary by age, race or ethnicity, and sex. HCC occurs most frequently and is most deadly among males, Asian and Pacific Islanders, and older adults.^5^ Mortality has increased within these high risk groups with the exception of Asian and Pacific Islanders.^6^ Shifting patterns of liver disease and cirrhosis etiology over this time may also account for HCC incidence and mortality findings.

The goal of any screening program is to reduce all-cause and disease-specific morbidity and mortality with acceptable harms, burden, and costs. Screening is recommended by several specialty societies (eg, American Association for the Study of Liver Diseases [AASLD], European Association for the Study of the Liver [EASL]), typically through abdominal ultrasound imaging with alpha-fetoprotein (AFP) every 6 months. However, the National Cancer Institute’s Physician Data Query concluded that based on fair evidence, screening of persons at elevated risk does not result in a decrease in mortality from HCC and would result in rare but serious side effects.^7^ Neither the United States Preventive Services Task Force nor primary care medical societies have issued HCC screening guidelines in “increased-risk individuals.”

Figure 1 Liver and Intrahepatic Bile Duct Cancers

Excerpted from: https://seer.cancer.gov/statfacts/html/livibd.html

The percentage of all liver cancers detected as localized disease has increased; moving from 49.4% in 2000 to 62.1% diagnosed at a localized stage in 2016.^5^ This stage shift, while potentially promising, may simply reflect increased early-stage incidence and detection without a corresponding decline in late-stage incidence or mortality reduction. Thus, stage shift is not sufficient to demonstrate evidence of screening effectiveness. Even with increased detection of localized disease, the proportion of patients receiving potentially curative treatment remained at less than one-third (27%).^5^ A recent systematic review summarized the epidemiology, costs, and burden of HCC.^8^ Incidence was higher in Medicare and Veterans Health Administration (VA) patients, (22.3 and 45 per 100,000 person-years, respectively), compared to the general USA population (9.5 per 100,000), though these data are not age or comorbidity adjusted.^9^ Authors found that HCC incidence, costs, and health burden to patients, caregivers, and the health care system were high. Furthermore, due to costs and limited survival benefits, some patients may elect to forgo treatment, thus underlining the importance of more effective detection and treatment options.

HCC incidence among Veterans receiving care in the VA peaked in 2015 with 31 per 100,000 and then declined slightly to 22 per 100,000 patients in 2018.^10^ While the incidence of hepatitis C-related HCC among VA patients has declined from 2015 to 2018, the incidence of non-hepatitis C-related HCC has increased. Effective, safe, and affordable early HCC identification and treatment options are important. The 3-year payer costs in the VA related to cirrhosis are estimated to be $154,688 with $69,010 for HCC treatment.^9^ Early identification of liver cancers may reduce cancer-related and all-cause mortality by providing an opportunity for potentially curative therapies like surgical resection, ablative therapy, or liver transplantation.

Individuals with cirrhosis, hepatitis B virus, and hepatitis C virus are at increased risk of HCC. Hepatitis C treatment and vaccination for hepatitis B have reduced the contribution these diseases have to the total number of HCC cases.^11^ In contrast, metabolic dysfunction-associated steatotic liver disease (MASLD; formerly known as nonalcoholic fatty liver disease) and alcohol-associated liver disease (ALD) have increased and are becoming the most common risk factors for HCC in the USA.^11,12^ Other risk factors for HCC include age, male sex, and Hispanic ethnicity.^12^ Of concern for the USA population, both diabetes and body mass index (BMI) are associated with HCC in individuals with cirrhosis.^12^

In addition to the question of whether HCC screening should be conducted, there are several questions about how to best implement HCC screening if screening is effective. They include: 1) the optimal imaging technique (ultrasound, magnetic resonance imaging [MRI], or computed tomography [CT]), 2) whether AFP should be included, 3) how often to screen (eg, 3, 6, or 12 months), and 4) whether the benefits and harms of screening vary by patient or liver disease characteristics.

In 2014, the ESP conducted a systematic review on HCC screening in chronic liver disease.^13^ Authors concluded that screening tests can identify early-stage HCC but found that evidence was uncertain about survival benefits of systematic screening compared with clinical diagnosis. The current review was requested by the VA National Gastroenterology and Hepatology Program (NGHP) and aimed to identify and critically appraise currently available evidence on the effects, comparative effects, and harms of HCC screening versus no screening and different screening strategies in populations at increased risk. We also assessed whether benefits and harms varied by patient or co-existing medical characteristics, presence of cirrhosis, liver disease etiology, screening intervals, or screening modality with or without AFP. Findings will be used to inform clinical guidelines, VA directives, and implementation strategies related to HCC screening across the VA.