# Appendix

## SEARCH STRATEGIES

Search Date: January 24, 2022 | | Search Statement
MEDLINE; July 1, 2020 – January 24, 2022 | 1 | (liver ca* or hepatocellular ca* or hepatoma).tw.
MEDLINE; July 1, 2020 – January 24, 2022 | 2 | (screen* or surveillance).tw.
MEDLINE; July 1, 2020 – January 24, 2022 | 3 | 1 and 2
MEDLINE; July 1, 2020 – January 24, 2022 | 4 | limit 4 to yr=“2020 - 2022”
Embase; July 1, 2020 – January 24, 2022 | 1 | (liver ca* or hepatocellular ca* or hepatoma).tw.
Embase; July 1, 2020 – January 24, 2022 | 2 | (screen* or surveillance).tw.
Embase; July 1, 2020 – January 24, 2022 | 3 | 1 and 2
Embase; July 1, 2020 – January 24, 2022 | 4 | limit 4 to yr=“2020 - 2022”

## STUDIES EXCLUDED DURING FULL-TEXT SCREENING

1 Chen VL, Yeh M-L, Yang JD, . Effects of Cirrhosis and Diagnosis Scenario in Metabolic-Associated Fatty Liver Disease-Related Hepatocellular Carcinoma. Hepatology communications. 2021;5(1):122–132. Ineligible Comparator33437906
2 Curran C, Priest M, Datta S, Forrest EH, Stanley AJ, Barclay ST. Hepatocellular Carcinoma Risk Scores Predict Patients Under Surveillance at Low Risk of Benefit and High Risk of Harm. Digestive Diseases and Sciences. 2022; Ineligible Comparator
3 De Toni EN, Schlesinger-Raab A, Fuchs M, . Age independent survival benefit for patients with hepatocellular carcinoma (HCC) without metastases at diagnosis: A population-based study. Gut. 2020;69(1):168–176. Ineligible Comparator30878947
4 Kurniawan J, Gani RA, Hasan I, . The Improvement in 1-Year Survival Rate of Patients with Hepatocellular Carcinoma BCLC Stage A and B after the Implementation of Comprehensive Management. Journal of Gastrointestinal Cancer. 2020;51(3):829–835. Ineligible Comparator31502104
5 Lahmidani N, Hamdoun FZ, Lahlali M, . Prognostic Impact of Alpha Fetoprotein at Diagnosis on Overall Survival of Single Small Hepatocellular Carcinomas. The Gulf journal of oncology. 2020;1(33):64–67. Ineligible Comparator32476652
6 Lee J, Park SB, Byun S, Kim HI. Impact of ultrasonographic blind spots for early-stage hepatocellular carcinoma during surveillance. PLoS ONE. 2022;17(9 September):e0274747. Ineligible Comparator36112645
7 Rattanasupar A, Chartleeraha S, Akarapatima K, Chang A. Factors that Affect the Surveillance and Late-Stage Detection of a Newly Diagnosed Hepatocellular Carcinoma. Asian Pacific journal of cancer prevention : APJCP. 2021;22(10):3293–3298. Ineligible Comparator34711006
8 Sigurdsson B, Sigurdardottir R, Arnardottir MB, Lund SH, Jonasson JG, Bjornsson ES. A nationwide study on hepatocellular carcinoma. Cancer Epidemiology. 2020;69:101835. Ineligible Comparator33068877
9 Ali AH, Tabibian JH, Nasser-Ghodsi N, . Surveillance for hepatobiliary cancers in patients with primary sclerosing cholangitis. Hepatology. Jun 2018;67(6):2338–2351. Ineligible Population29244227
10 Wu Y, Shen L, Qi H, . Surveillance Strategy for Patients With BCLC Stage B Hepatocellular Carcinoma After Achieving Complete Remission: Data From the Real World. Frontiers in Oncology. 2020;10:574804. Ineligible Population33117712
11 Attree C, Wallace M, Jeffrey G, . Hepatocellular cancer surveillance in cirrhotic patients with fatty liver disease. Journal of Gastroenterology and Hepatology. 2022;37(Supplement 1):75–76. Gastroenterological Society of Australia, GESA and Australian Gastroenterology Week, AGW 2022. Sydney, NSW Australia. Ineligible Publication Type34409657
12 Bui HT, Wong K, Tran DK, Balasubramanian S. Impact of an HCC surveillance program on surveillance rates, early detection of HCC and outcomes in a community-based hepatology practice-real world experience. Hepatology. 2020;72(1 SUPPL):394A. 71st Annual Meeting of the American Association for the Study of Liver Diseases, AASLD. Boston, MA United States. Ineligible Publication Type
13 Carrieri V, Bray A, Argentieri G, Mazelli G, Lena LD, Paterno V. Liver cirrhosis in the elderly: Clinical and ecographic correlations. European Geriatric Medicine. 2020;11(SUPPL 1):S250. 16th International E-Congress of the European Geriatric Medicine Society. Athens Greece. Ineligible Publication Type
14 Chalasani NP, Porter K, Book AJ, . THE MULTI-TARGET HEPATOCELLULAR CARCINOMA BLOOD TEST PROVIDES HIGH SENSITIVITY FOR DETECTING EARLY-STAGE HEPATOCELLULAR CARCINOMA ACROSS IMPORTANT PATIENT SUBGROUPS. Gastroenterology. 2022;162(7 Supplement):S-1130. DDW 2022. San Diego United States. Ineligible Publication Type
15 Chen E, Holmes J, Howell J, . A growing problem: Non-alcoholic fatty liver diseaserelated hepatocellular carcinoma is increasing and associated with low rates of surveillance participation and poor overall survival. Journal of Gastroenterology and Hepatology (Australia). 2020;35(SUPPL 1):75–76. Gastroenterological Society of Australia, GESA and Australian Gastroenterology Week, AGW 2020. Virtual. Ineligible Publication Type
16 Cho YY, Kim HJ. Surveillance of hepatocelluar carcinoma in Korea after National reimbursement. Hepatology International. 2022;16(Supplement 1):S432. 31st Conference of the Asian Pacific Association for the Study of the Liver, APASL 2022. Seoul South Korea. Ineligible Publication Type
17 Chong N, Schoenberger H, Fetzer DT, . Preceding Ultrasound Visualization Predicts Quality Of Future Surveillance In Patients With Cirrhosis. Gastroenterology. 2021;160(6 Supplement):S-485. DDW 2021. Virtual, Online. Ineligible Publication Type
18 Consul N. Hepatocellular Carcinoma Surveillance with Abbreviated MRI Strategies. Radiology Imaging cancer. 2021;3(1):e219002. Ineligible Publication Type33778767
19 El Sabagh A, Mohamed I, Zain Aloor F, . OUTCOMES OF DIFFERENT RADIOLOGICAL MODALITIES FOR HCC SURVEILLANCE OF HIGH RISK CIRRHOTIC PATIENTS. Hepatology. 2022;76(Supplement 1):S1414–S1415. Annual Meeting of the American Association for the Study of Liver Diseases, AASLD 2022. Virtual. Ineligible Publication Type
20 Fetzer DT. Beyond the AJR: Shorter Ultrasound Screening Intervals for Hepatocellular Carcinoma Improve Patient Outcomes. American Journal of Roentgenology. 2022;218(4):761. Ineligible Publication Type35576533
21 Flores JE, Morgan J, Pietris K, Tse E. Fatty liver disease not associated with decreased proportion of early hepatocellular carcinoma detected on ultrasound. Journal of Gastroenterology and Hepatology (Australia). 2020;35(SUPPL 1):42. Gastroenterological Society of Australia, GESA and Australian Gastroenterology Week, AGW 2020. Virtual. Ineligible Publication Type
22 Flores JE, Morgan J, Pietris K, Tse E. Factors contributing to the diagnosis of curable hepatocellular carcinoma. Journal of Gastroenterology and Hepatology (Australia). 2020;35(SUPPL 1):41–42. Gastroenterological Society of Australia, GESA and Australian Gastroenterology Week, AGW 2020. Virtual. Ineligible Publication Type
23 Gala K, Eisa M, Safadi S, . Incidentally Diagnosed Hepatocellular Carcinoma: Root Cause Analysis and Characteristics. American Journal of Gastroenterology. 2020;115(SUPPL):S506–S507. 2020 Annual Scientific Meeting of the American College of Gastroenterology, ACG 2020. Nashville, TN United States. Ineligible Publication Type
24 Gillessen J, Reuken P, Hunyady PM, . Failure of ultrasound-based surveillance for hepatocellular carcinoma in patients at risk is frequent and associated with detection at later tumor stages, noncurative treatment options and reduced survival. results from a german multi-center retrospective cohort study. United European Gastroenterology Journal. 2021;9(SUPPL 8):713. 29th United European Gastroenterology Week. Virtual. Ineligible Publication Type
25 Gonzalez-Sanchez H, Castano-Garcia A, Celada-Sendino M, . CHARACTERISTICS AND SURVIVAL OF PATIENTS WITH HEPATOCELLULAR CARCINOMA IN NATURAL HISTORY IN A WESTERN COUNTRY. United European Gastroenterology Journal. 2022;10(Supplement 8):939. 30th United European Gastroenterology Week, UEG Week 2022. Virtual. Ineligible Publication Type
26 Gounder P, Pak KJY, Sahota A, . Receipt of timely hepatocellular carcinoma (hcc) screening among kaiser permanente southern california (kpsc) members with chronic hepatitis b virus (hbv) infection who developed hcc - Los angeles, california, 2008-2019. Hepatology. 2021;74(SUPPL 1):462A–463A. 72nd Annual Meeting of the American Association for the Study of Liver Diseases, AASLD 2021. Virtual. Ineligible Publication Type
27 Halim A, Olsen M, Youd P. Hepatocellular carcinoma surveillance at a district general hospital in the UK-can the surveillance interval be increased during the COVID-19 pandemic? United European Gastroenterology Journal. 2020;8(8 SUPPL):126. 28th United European Gastroenterology Week, UEG. Virtual. Ineligible Publication Type
28 Hassan I. OUTCOMES OF NON-ALCOHOLIC STEATOHEPATITIS-RELATED HEPATOCELLULAR CARCINOMA : A 20-YEAR EXPERIENCE FROM A NATIONAL PROGRAMME. Gastroenterology. 2020;158(6 Supplement 1):S-1400. Digestive Disease Week (DDW) 2020. Chicago United States. Ineligible Publication Type
29 Ibrahim H, Hassan F, Edward G. Outcomes of non-alcoholic steatohepatitis (NASH)-related hepatocellular carcinoma (HCC) at New Zealand liver transplant unit (NZLTU) over last 2 decades. Hepatology International. 2020;14(Supplement 1):S260. 29th Annual Conference of Asian Pacific Association for the Study of the Liver. Bali Indonesia. Ineligible Publication Type
30 Iyer KG, Flores JE, Macisaac M, . Surveillance uptake remains a key challenge to timely detection of early-stage hepatocellular carcinoma in Australia: A single-site, retrospective cohort study of hepatocellular carcinoma diagnosis in Melbourne. Journal of Gastroenterology and Hepatology. 2022;37(Supplement 1):73. Gastroenterological Society of Australia, GESA and Australian Gastroenterology Week, AGW 2022. Sydney, NSW Australia. Ineligible Publication Type
31 Jang H, Kim MA, Oh H, . Comparison of the effects of ultrasound alone and ultrasound, CT, and MRI combination on surveillance in high-risk patients with hepatocellular carcinoma. Hepatology International. 2020;14(Supplement 1):S286. 29th Annual Conference of Asian Pacific Association for the Study of the Liver. Bali Indonesia. Ineligible Publication Type
32 Kang S, Kim JW. Utility of CT/MR surveillance in LI-RADS Visualization Scoreassessed Liver cirrhosis patients. Hepatology International. 2022;16(Supplement 1):S99–S100. 31st Conference of the Asian Pacific Association for the Study of the Liver, APASL 2022. Seoul South Korea. Ineligible Publication Type
33 Karim M, Singal AG, Kum HC, . SURVEILLANCE WITH CT OR MRI IS ASSOCIATED WITH IMPROVED SURVIVAL COMPARED TO ULTRASOUND IN PATIENTS WITH HEPATOCELLULAR CARCINOMA. Gastroenterology. 2022;162(7 Supplement):S-1160. DDW 2022. San Diego United States. Ineligible Publication Type
34 Kessing R. Hepatocellular carcinoma screening: Risk patients are more likely to be examined. Tumor Diagnostik und Therapie. 2021;42(8):554. HCC-Screening: Risikopatienten/-innen werden eher untersucht. Ineligible Publication Type
35 Khan AA, Hadi Y, Kupec J. ASSESSING THE RISK: INCIDENCE OF ACUTE KIDNEY INJURY AFTER CT AND MRI FOR EVALUATION OF LESIONS IDENTIFIED ON HCC SURVEILLANCE. Gastroenterology. 2020;158(6 Supplement 1):S-1454. Digestive Disease Week (DDW) 2020. Chicago United States. Ineligible Publication Type
36 Khan V, Jiang D, Panneerselvam K, . Missed opportunities for hepatocellular carcinoma (HCC) screening and surveillance amongst veterans subsequently diagnosed with HCC. Hepatology. 2020;72(1 SUPPL):646A. 71st Annual Meeting of the American Association for the Study of Liver Diseases, AASLD. Boston, MA United States. Ineligible Publication Type
37 Kim JY, Lim J, Yu DM, Kang HJ, Shim JH. Hepatic high-grade dysplastic nodules are crucial precancerous lesions and potential indications for ablation in cirrhotic patients. Hepatology. 2021;74(SUPPL 1):644A–645A. 72nd Annual Meeting of the American Association for the Study of Liver Diseases, AASLD 2021. Virtual. Ineligible Publication Type
38 Kim SY, Lim YS. Towards a New Horizon for Individualized Surveillance Tools in Hepatocellular Carcinoma. Clinical gastroenterology and hepatology : the official clinical practice journal of the American Gastroenterological Association. 2021; Ineligible Publication Type
39 Krishna AS, Narayanasamy KNS. Clinical impact of screening for HCC in CLD patients: A south Indian teritiary centre persepective. Hepatology International. 2022;16(Supplement 1):S429. 31st Conference of the Asian Pacific Association for the Study of the Liver, APASL 2022. Seoul South Korea. Ineligible Publication Type
40 Lepour M, De Terwangne C, Henrion J, Descamps OS, De Vos M. The surveillance for hepatocellular carcinoma, it’s fine. to diagnose the cirrhosis, it’s better. Acta Clinica Belgica. 2022;77(Supplement 2):21. 26th Annual Congress of the Belgian Society of Internal Medicine. La Hulpe Belgium. Ineligible Publication Type
41 Liou WL, Tan T, Chen K, George Goh BB, Jason Chang PE, Tan CK. Gender differences in hepatocellular carcinoma : is it all due to adherence to surveillance? A study of 1, 716 patients over 3 decades. Journal of Hepatology. 2022;77(Supplement 1):S919–S920. The International Liver Congress. London United Kingdom. Ineligible Publication Type
42 Mezzacappa C, Kaplan DE, Mahmud N, Serper M, Taddei TH. SCREENING FOR HEPATOCELLULAR CARCINOMA AND OVERALL SURVIVAL IN A COHORT OF VETERANS WITH CIRRHOSIS: A SNAPSHOT OF THE POST-DAA ERA. Hepatology. 2022;76(Supplement 1):S1379–S1380. Annual Meeting of the American Association for the Study of Liver Diseases, AASLD 2022. Virtual. Ineligible Publication Type
43 Mubarak A, Kakadia A, Hirapara B, . Liver lesions identified by mri versus ultrasound in patients diagnosed with liver cirrhosis. Hepatology. 2021;74(SUPPL 1):700A. 72nd Annual Meeting of the American Association for the Study of Liver Diseases, AASLD 2021. Virtual. Ineligible Publication Type
44 Navadurong H, Laohasurayotin K, Yorwittaya K, . PERFORMANCE OF ABBREVIATED MAGNETIC RESONANCE IMAGING VERSUS ULTRASONOGRAPHY AS AN IMAGING TOOL FOR HEPATOCELLULAR CARCINOMA SURVEILLANCE. Gut. 2022;71(Supplement 2):A85. International Digestive Disease Forum, IDDF. Hong Kong Hong Kong. Ineligible Publication Type
45 Olson MC, Venkatesh SK. Hepatocellular carcinoma screening at transplant centers: Counterpoint-CT and MRI are the way to go. American Journal of Roentgenology. 2020;216(3):581–582. Ineligible Publication Type
46 Papageorge MV, De Geus SW, Woods AP, . Surveillance Patterns and Survival in Hepatocellular Carcinoma: A Seer-medicare Analysis. Annals of Surgical Oncology. 2022;29(SUPPL 2):S391. Society of Surgical Oncology SSO 2022 - International Conference on Surgical Cancer Care. Dallas, TX United States. Ineligible Publication Type
47 Parikh ND, Tayob N, Al-Jarrah T, . Barriers to hcc surveillance in a multicenter us cohort. Hepatology. 2021;74(SUPPL 1):617A. 72nd Annual Meeting of the American Association for the Study of Liver Diseases, AASLD 2021. Virtual. Ineligible Publication Type
48 Rai B, Albertian R, Solano L, . Lack of liver disease awareness: Important contributor to late stage hepatocellular carcinoma. Hepatology. 2020;72(1 SUPPL):644A–645A. 71st Annual Meeting of the American Association for the Study of Liver Diseases, AASLD. Boston, MA United States. Ineligible Publication Type
49 Rodriguez-Fernandez M, Merchante N, Rodriguez-Arrondo F, . Changes in liver cancer survival in HIV infection after management optimization. Topics in Antiviral Medicine. 2020;28(1):199. Conference on Retroviruses and Opportunistic Infections, CROI 2020. Boston, MA United States. Ineligible Publication Type
50 Sedki M, Horton B, Avins A, Corley DA, Chai KP, Ready JB. Chronic hepatitis b management through a dedicated surveillance program in an integrated-care setting. Hepatology. 2021;74(SUPPL 1):44A–45A. 72nd Annual Meeting of the American Association for the Study of Liver Diseases, AASLD 2021. Virtual. Ineligible Publication Type
51 Spiers J, Li W, Alazawi W. FACTORS ASSOCIATED WITH HCC STAGE AT PRESENTATION AND SURVIVAL IN AN ETHNICALLY DIVERSE UK POPULATION. Gut. 2022;71(Supplement 1):A85. Annual Meeting of the British Society of Gastroenterology, BSG 2022. Birmingham United Kingdom. Ineligible Publication Type
52 Tirumanisetty P, Deda X, Budh D, . Role of isolated alpha feto protein elevation in hepatocellular cancer screening. Is it time for new cut off? American Journal of Gastroenterology. 2021;116(SUPPL):S577. Annual Scientific Meeting of the American College of Gastroenterology, ACG 2021. Las Vegas, NV United States. Ineligible Publication Type
53 Toyoda H, Kanneganti M, Melendez-Torres J, . IMPACT OF SURVEILLANCE PRACTICE ON SURVIVAL AMONG PATIENTS DEVELOPING HCC AFTER DAA-INDUCED SVR: AN INTERNATIONAL STUDY. Hepatology. 2022;76(Supplement 1):S1405–S1406. Annual Meeting of the American Association for the Study of Liver Diseases, AASLD 2022. Virtual. Ineligible Publication Type
54 Waller K, Chang J, Lee A, Ngu M, He E. Impact of surveillance on survival in patients with hepatocellular carcinoma: A single-center retrospective analysis, 2012-2019. Journal of Gastroenterology and Hepatology (Australia). 2020;35(SUPPL 1):102. Gastroenterological Society of Australia, GESA and Australian Gastroenterology Week, AGW 2020. Virtual. Ineligible Publication Type
55 Zambrano ES, Acosta-Lopez S, Bethencourt DD, Garrido MS, Darias RS, Perez Hernandez FA. Adherence to hepatocellular carcinoma screening in patients with hepatitis C cirrhosis treated with direct-acting antivirals against hepatitis C. Journal of Hepatology. 2022;77(Supplement 1):S931. The International Liver Congress. London United Kingdom. Ineligible Publication Type
56 Zangneh HF, Cerocchi O, Khalili K, . Prospective randomized controlled trial of biomarkers for early detection of hepatocellular carcinoma. Journal of Hepatology. 2022;77(Supplement 1):S3. The International Liver Congress. London United Kingdom. Ineligible Publication Type
57 Al-Naamani K, Al-Hashami Z, Al-Siyabi O, . Hepatocellular Carcinoma in Oman: An analysis of 284 cases. Sultan Qaboos University medical journal. 2020;20(3):e316–e322. Ineligible Study Design33110647
58 Tan GJ, Lee CH, Sun Y, Tan CH. Is non-contrast enhanced magnetic resonance imaging cost-effective for screening of hepatocellular carcinoma? Singapore medical journal. 2021; Ineligible Study Design
59 Abara WE, Spradling P, Zhong Y, . Hepatocellular Carcinoma Surveillance in a Cohort of Chronic Hepatitis C Virus-Infected Patients with Cirrhosis. Journal of Gastrointestinal Cancer. 2020;51(2):461–468. No Eligible Outcomes31124041
60 Ahmed NNA, El Gaafary SM, Elia RZ, Abdulhafiz EM. Role of abbreviated MRI protocol for screening of HCC in HCV related cirrhotic patients prior to direct-acting antiviral treatment. Egyptian Journal of Radiology and Nuclear Medicine. 2020;51(1):102. No Eligible Outcomes
61 Al Hasani F, Knoepfli M, Gemperli A, . Factors affecting screening for hepatocellular carcinoma. Annals of hepatology. 2014;13(2):204–210. No Eligible Outcomes24552862
62 Allaire M, El Hajj W, Brichler S, . Prior surveillance and antiviral treatment improve the prognosis of HCC developed in HBV patients in the West. Clinics and research in hepatology and gastroenterology. 2021;45(1):101436. No Eligible Outcomes32418851
63 Atiq O, Tiro J, Yopp AC, . An assessment of benefits and harms of hepatocellular carcinoma surveillance in patients with cirrhosis. Hepatology. Apr 2017;65(4):1196–1205. No Eligible Outcomes27775821
64 Cao M, Li H, Sun D, . Assessment of the compliance, influencing factors, and yielding results of liver cancer screening in a high-risk population: A cross-sectional study. Cancer. 2022;128(20):3653–3662. No Eligible Outcomes35996957
65 Chen Q-F, Dai L, Wu Y, Huang Z, Chen M, Zhao M. Surveillance Strategy for Barcelona Clinic Liver Cancer B Hepatocellular Carcinoma Achieving Complete Response: An Individualized Risk-Based Machine Learning Study. Frontiers in bioengineering and biotechnology. 2021;9:667641. No Eligible Outcomes34540812
66 Choi HH, Rodgers SK, Khurana A, Nelson LW, Kamaya A. Role of Ultrasound for Chronic Liver Disease and Hepatocellular Carcinoma Surveillance. Magnetic Resonance Imaging Clinics of North America. 2021;29(3):279–290. No Eligible Outcomes34243917
67 Davila JA, Henderson L, Kramer JR, . Utilization of surveillance for hepatocellular carcinoma among hepatitis C virus–infected veterans in the United States. Annals of internal medicine. 2011;154(2):85–93. No Eligible Outcomes21242365
68 Demirtas CO, Gunduz F, Tuney D, . Annual contrast-enhanced magnetic resonance imaging is highly effective in the surveillance of hepatocellular carcinoma among cirrhotic patients. European Journal of Gastroenterology and Hepatology. 2020;32(4):517–523. No Eligible Outcomes31524775
69 Dirchwolf M, Marciano S, Ruf AE, . Failure in all steps of hepatocellular carcinoma surveillance process is frequent in daily practice. Annals of Hepatology. 2021;25:100344. No Eligible Outcomes33819695
70 Fazeli S, Covarrubias Y, Bassirian S, . Eliciting Patient Preferences for Hepatocellular Carcinoma Screening: A Choice-Based Conjoint Analysis. Journal of the American College of Radiology. 2022;19(4):502–512. No Eligible Outcomes35248523
71 Frey RS, Boldanova T, Heim M. Ultrasound surveillance for hepatocellular carcinoma: real-life performance in a hepatology outpatient clinic. Swiss Med Wkly. 2015;145:w14200. No Eligible Outcomes26588016
72 Hernandez-Meza G, Violi NV, Said D, . MRI is the most commonly used imaging modality for HCC screening at a tertiary care transplant center. Abdominal Radiology. 2021;46(11):5142–5151. No Eligible Outcomes34283266
73 Huang DQ, Fowler KJ, Liau J, . Comparative efficacy of an optimal exam between ultrasound versus abbreviated MRI for HCC screening in NAFLD cirrhosis: A prospective study. Alimentary Pharmacology and Therapeutics. 2022;55(7):820–827. No Eligible Outcomes35229334
74 Khalili K, Menezes R, Kim TK, . The effectiveness of ultrasound surveillance for hepatocellular carcinoma in a Canadian centre and determinants of its success. Canadian Journal of Gastroenterology and Hepatology. 2015;29(5):267–273. No Eligible Outcomes26076226
75 Khan AA, Hadi YB, Thompson JM, Kupec JT. Acute kidney injury after multiphase imaging for lesions detected on hepatocellular carcinoma surveillance in patients with cirrhosis. BMJ Open Gastroenterology. 2020;7(1):e000394. No Eligible Outcomes
76 Kim JH, Kang SH, Lee M, . Individualized surveillance of chronic hepatitis B patients according to hepatocellular carcinoma risk based on PAGE-B scores. European journal of gastroenterology & hepatology. 2020; No Eligible Outcomes
77 Liu JKJ, Lee CH, Tan CH. Evaluation of non-contrast magnetic resonance imaging as an imaging surveillance tool for hepatocellular carcinoma in at-risk patients. Singapore Medical Journal. 2022;63(4):203–208. No Eligible Outcomes32798363
78 Low ES, Apostolov R, Wong D, . Hepatocellular carcinoma surveillance and quantile regression for determinants of underutilisation in at-risk Australian patients. World Journal of Gastrointestinal Oncology. 2021;13(12):2149–2160. No Eligible Outcomes35070048
79 Majerović M, Jelaković M, Premužić M, . Hepatocellular Carcinoma Surveillance— Experience from Croatian Referral Centre for Chronic Liver Diseases. Journal of Gastrointestinal Cancer. 2019;50(1):48–53. No Eligible Outcomes29127665
80 Marrero JA. Surveillance for Hepatocellular Carcinoma. Clinics in Liver Disease. 2020;24(4):611–621. No Eligible Outcomes33012448
81 Nguyen MH, Roberts LR, Engel-Nitz NM, Bancroft T, Ozbay AB, Singal AG. Gaps in hepatocellular carcinoma surveillance in a United States cohort of insured patients with cirrhosis. Current Medical Research and Opinion. 2022;38(12):2163–2173. No Eligible Outcomes36111416
82 Nguyen MH, Roberts LR, Engel-Nitz NM, Bancroft T, Ozbay AB, Singal AG. Gaps in hepatocellular carcinoma surveillance among insured patients with hepatitis B infection without cirrhosis in the United States. Hepatology communications. 2022;6(12):3443–3456. No Eligible Outcomes36178256
83 Ojeda PI, Hannan LM, Mieloszyk RJ, . Is There a Difference Between LI-RADS 3 to LI-RADS 5 Progression Assessment Using CT Versus MR? A Retrospective, Single-Center, Longitudinal Study of Patients Who Underwent 5082 Radiologic Examinations for Surveillance of Hepatocellular Carcinoma Over a 43-Month Period. Current problems in diagnostic radiology. 2022;51(2):176–180. No Eligible Outcomes33980417
84 Parikh ND, Tayob N, Al-Jarrah T, . Barriers to Surveillance for Hepatocellular Carcinoma in a Multicenter Cohort. JAMA Network Open. 2022;5(7):E2223504. No Eligible Outcomes35867057
85 Park HJ, Jang HY, Kim SY, . Non-enhanced magnetic resonance imaging as a surveillance tool for hepatocellular carcinoma: Comparison with ultrasound. Journal of Hepatology. 2020;72(4):718–724. No Eligible Outcomes31836549
86 Park HJ, Kim SY, Singal AG, . Abbreviated magnetic resonance imaging vs ultrasound for surveillance of hepatocellular carcinoma in high-risk patients. Liver international : official journal of the International Association for the Study of the Liver. 2022;42(9):2080–2092. No Eligible Outcomes34817921
87 Park SH, Kim B, Kim SY, . Abbreviated MRI with optional multiphasic CT as an alternative to full-sequence MRI: LI-RADS validation in a HCC-screening cohort. European Radiology. 2020;30(4):2302–2311. No Eligible Outcomes31858203
88 Singal AG, Reddy S, Radadiya Aka Patel H, . Multicenter Randomized Clinical Trial of a Mailed Outreach Strategy for Hepatocellular Carcinoma Surveillance. Clinical gastroenterology and hepatology : the official clinical practice journal of the American Gastroenterological Association. 2022;20(12):2818–2825.e1. No Eligible Outcomes34902568
89 Singal AG, Tiro JA, Murphy CC, . Patient-Reported Barriers Are Associated With Receipt of Hepatocellular Carcinoma Surveillance in a Multicenter Cohort of Patients With Cirrhosis. Clinical Gastroenterology and Hepatology. 2021;19(5):987–995.e1. No Eligible Outcomes32629122
90 Singal AG, Yopp AC, Gupta S, . Failure rates in the hepatocellular carcinoma surveillance process. Cancer Prev Res (Phila). Sep 2012;5(9):1124–30. No Eligible Outcomes22846843
91 Skladany L, Adamcova Selcanova S, Ciefova J, . Surveillance of hepatocellular carcinoma in Slovakia. Gastroenterologie a Hepatologie. 2020;74(5):380–385. No Eligible Outcomes
92 Skladaný Ľ, Adamcová-Selčanová S, Malec V, . HEPATOCELLULAR CARCINOMA IN CENTRAL SLOVAKIA: TERTIARY REFERRAL CENTRE EXPERIENCE WITH 207 PATIENTS. Gastroenterologie a hepatologie. 2018;72(2):99–107. No Eligible Outcomes
93 Tarao K, Nozaki A, Komatsu H, . Comparison of unenhanced magnetic resonance imaging and ultrasound in detecting very small hepatocellular carcinoma. World journal of hepatology. 2021;13(6):699–708. No Eligible Outcomes34239704
94 Turse E, Aboona M, Charley E, . Factors Associated with Survival of Hepatocellular Carcinoma (HCC) Patients at a Safety Net Hospital in Arizona without On-Site Liver Transplant Program. Journal of Hepatocellular Carcinoma. 2022;9:1–11. No Eligible Outcomes35096683
95 Wei Y, Haifen L, Xiang L, Shutong Z, Yanhao C, Xiang W. Non-contrast magnetic resonance imaging versus the multiphase computed tomography with respect to the Asia-Pacific Clinical Practice Guidelines: A diagnostic performance study for liver cancer. Turkish Journal of Gastroenterology. 2021;32(3):318–326. No Eligible Outcomes
96 Yoon JH, Lee JM, Lee DH, . A Comparison of Biannual Two-Phase Low-Dose Liver CT and US for HCC Surveillance in a Group at High Risk of HCC Development. Liver Cancer. 2020;9(5):503–517. No Eligible Outcomes33083277
97 Zha Z, Wu W, Zhang Q, . Screening, clinical features and prognostic analysis of liver cirrhosis-related hepatocellular carcinoma. Scandinavian Journal of Gastroenterology. 2021;56(8):948–954. No Eligible Outcomes34148534

## UNDERWAY STUDIES

Citation
NCT05486572 Preventing Liver Cancer Mortality Through Imaging With Ultrasound vs. MRI (PREMIUM)
NCT05095714 FAST-MRI for HCC surveillance in patients With High risk of Liver Cancer. (FASTRAK)
NCT00912847 Validity and Cost-Effectiveness of a New Screening Test for Hepatocellular Carcinoma
NCT02551250 Annual MRI Versus Biannual Ultrasound for Surveillance of Hepatocellular Carcinoma in Liver Cirrhosis (MAGNUS-HCC)
NCT00190385 Screening of Hepatocellular Carcinoma in Patients With Compensated Cirrhosis

## RISK OF BIAS ASSESSMENTS

### RANDOMIZED CONTROLLED TRIALS (ROB-2)

Trial Name or Author Year | Bias from randomization process | Bias from deviation from intended interventions (Assignment) | Bias from deviation from intended interventions (Adherence) | Bias from missing outcome data | Bias in measurement of outcome | Bias in selection of reported result | Overall risk of bias (Low, Some concerns, High)
Chen, 2003^21^ | Some concerns | Low | High | Some concerns | Low | Some concerns | High
Pocha, 2013^22^ | Some concerns | Low | Some concerns | Some concerns | Low | Low | Some concerns
Trinchet, 2011^23^ | Low | Low | Some concerns | Low | Low | Low | Some concerns
Wang, 2013^19^ | High | Low | High | Low | Low | Low | High
Zhang, 2004^20^ | Some concerns | Low | High | Low | Low | Some concerns | High

### NONRANDOMIZED COMPARISON STUDIES (ROBINS-I)

Study Name or Author Year | Bias due to confounding^*^,^†^ | Selection bias | Bias in classification of interventions | Bias due to departures from intended interventions (Assignment) | Bias due to departures from intended interventions (Adherence) | Bias due to measurement of outcomes | Bias due to missing data | Bias in the selection of reported results | Overall risk of bias^†^ (Low, Moderate, Serious, Critical, No Information)
Aby, 2019^63^ | Critical | - | - | - | - | - | - | - | Critical
Alencar, 2022^64^ | Critical | - | - | - | - | - | - | - | Critical
An, 2020^27^ | Low | Serious | Moderate | Low | Moderate | Serious | Low | Low | Serious
Bae, 2021^28^ | Serious | Serious | Low | Serious | Moderate | Serious | Low | Low | Serious
Bolondi, 2001^65^ | Critical | - | - | - | - | - | - | - | Critical
Chaiteerakij, 2017^66^ | Critical | - | - | - | - | - | - | - | Critical
Chen, 2002^18^ | Critical | - | - | - | - | - | - | - | Critical
Chen, 2020^67^ | Critical | - | - | - | - | - | - | - | Critical
Chinnaratha, 2019^68^ | Critical | - | - | - | - | - | - | - | Critical
Choi, 2019^69^ | Low | Serious | Moderate | Low | Low | Low | Low | Low | Serious
Costentin, 2018^70^ | Critical | - | - | - | - | - | - | - | Critical
Cucchetti, 2014^71^ | Critical | - | - | - | - | - | - | - | Critical
Davila, 2007^72^ | Critical | - | - | - | - | - | - | - | Critical
Debes, 2018^73^ | Critical | - | - | - | - | - | - | - | Critical
Edenvik, 2015^74^ | Critical | - | - | - | - | - | - | - | Critical
El-Serag, 2011^75^ | Critical | - | - | - | - | - | - | - | Critical
Eskesen, 2014^76^ | Critical | - | - | - | - | - | - | - | Critical
Giannini, 2022^77^ | Critical | - | - | - | - | - | - | - | Critical
Giannini, 2000^78^ | Critical | - | - | - | - | - | - | - | Critical
Haq, 2021^79^ | Critical | - | - | - | - | - | - | - | Critical
Hong, 2018^80^ | Critical | - | - | - | - | - | - | - | Critical
Huang, 2018^81^ | Critical | - | - | - | - | - | - | - | Critical
Hwang, 2022^82^ | Critical | - | - | - | - | - | - | - | Critical
Im, 2019^83^ | Critical | - | - | - | - | - | - | - | Critical
Jasirwan, 2020^84^ | Critical | - | - | - | - | - | - | - | Critical
Karim, 2022^85^ | Critical | - | - | - | - | - | - | - | Critical
Kemp, 2005^86^ | Critical | - | - | - | - | - | - | - | Critical
Kim, 2018^29^ | Low | Serious | Low | Low | Low | Moderate | Low | Low | Serious
Kim, 2020^26^ | Low | Serious | Low | Low | Low | Low | Low | Low | Serious
Kuo, 2021^87^ | Critical | - | - | - | - | - | - | - | Critical
Kuo, 2010^88^ | Critical | - | - | - | - | - | - | - | Critical
Kwon, 2020^89^ | Critical | - | - | - | - | - | - | - | Critical
Lang, 2020^90^ | Critical | - | - | - | - | - | - | - | Critical
Leykum, 2007^91^ | Critical | - | - | - | - | - | - | - | Critical
Merchante, 2019^92^ | Critical | - | - | - | - | - | - | - | Critical
Mittal, 2016^30^ | Low | Serious | Moderate | Low | Low | Moderate | Low | Low | Serious
Moon, 2018^24^ | Low | Low | Low | Low | Low | Low | Low | Low | Low
Nusbaum, 2015^93^ | Critical | - | - | - | - | - | - | - | Critical
Oeda, 2016^94^ | Critical | - | - | - | - | - | - | - | Critical
Papageorge, 2022^95^ | Critical | - | - | - | - | - | - | - | Critical
Pascual, 2008^96^ | Critical | - | - | - | - | - | - | - | Critical
Pelizzaro, 2021^97^ | Critical | - | - | - | - | - | - | - | Critical
Pelizzaro, 2022^31^ | Low | Serious | Moderate | Low | Moderate | Moderate | Low | Low | Serious
Piñero, 2019^32^ | Serious | Serious | Low | Low | Low | Low | Low | Low | Serious
Rodriguez, 2017^98^ | Critical | - | - | - | - | - | - | - | Critical
Schauer, 2020^99^ | Critical | - | - | - | - | - | - | - | Critical
Schauer, 2019^100^ | Critical | - | - | - | - | - | - | - | Critical
Shindo, 2015^101^ | Critical | - | - | - | - | - | - | - | Critical
Singal, 2020^102^ | Critical | - | - | - | - | - | - | - | Critical
Singal, 2017^103^ | Critical | - | - | - | - | - | - | - | Critical
Sohn, 2022^104^ | Critical | - | - | - | - | - | - | - | Critical
Su, 2021^25^ | Low | Low | Low | Low | Low | Low | Low | Low | Low
Tanaka, 2006^33^ | Low | Serious | Low | Low | Low | Low | Low | Low | Serious
Taura, 2005^105^ | Critical | - | - | - | - | - | - | - | Critical
Thein, 2015^34^ | Moderate | Serious | Moderate | Low | Moderate | Moderate | Low | Low | Serious
Tong, 2010^106^ | Critical | - | - | - | - | - | - | - | Critical
Tong, 2017^35^ | Low | Serious | Moderate | Low | Moderate | Low | Low | Low | Serious
Toyoda, 2018^107^ | Critical | - | - | - | - | - | - | - | Critical
Tran, 2018^108^ | Critical | - | - | - | - | - | - | - | Critical
Trevisani, 2004^36^ | Serious | Serious | Moderate | Low | Moderate | Serious | Low | Low | Serious
Trevisani, 2002^109^ | Critical | - | - | - | - | - | - | - | Critical
van Meer, 2015^110^ | Critical | - | - | - | - | - | - | - | Critical
Vaz, 2023^111^ | Critical | - | - | - | - | - | - | - | Critical
Wong, 2008^112^ | Critical | - | - | - | - | - | - | - | Critical
Wu, 2016^37^ | Low | Low | Moderate | Low | Moderate | Low | Low | Low | Serious
Yamago, 2019^113^ | Critical | - | - | - | - | - | - | - | Critical
Yeh, 2016^114^ | Critical | - | - | - | - | - | - | - | Critical
Yu, 2004^115^ | Critical | - | - | - | - | - | - | - | Critical

Notes.

* Publications rated critical in Domain 1 did not undergo full ROBINS-I assessment.

† Low=low, except for concerns about uncontrolled confounding.

## PEER REVIEW COMMENTS AND RESPONSES

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 2 | Yes | Thank you.
2 | 3 | Yes | Thank you.
3 | 4 | Yes | Thank you.
4 | 5 | Yes | Thank you.
5 | 6 | Yes | Thank you.
6 | 7 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
7 | 2 | No | Thank you.
8 | 3 | No | Thank you.
9 | 4 | No | Thank you.
10 | 5 | No | Thank you.
11 | 6 | No | Thank you.
12 | 7 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked?
13 | 2 | No | Thank you.
14 | 3 | No | Thank you.
15 | 4 | No | Thank you.
16 | 5 | No | Thank you.
17 | 6 | No | Thank you.
18 | 7 | No | Thank you.
Additional suggestions or comments can be provided below.
19 | 2 | Well written review that updates the continued lack of sufficient data to make recommendations for HCC screening. Continues to make the argument for more large scale studies like the PREMIUM study to identify best imaging and likely effect for HCC screening. | Thank you.
20 | 3 | This evidence synthesis review examines the efficacy of screening for HCC in adults at increased risk for HCC. This review is comprehensive, detailed with robust methodology. Congratulations to the authors and contributors on this important and impressive work. | Thank you.
21 | 3 | 1) In the discussion, when discussing incidence and mortality rates, would suggest including the Annual report on cancer (which comes out each fall and should be published soon) and SEER website that have updated epidemiological data. The incidence of HCC has plateaued since 2016 and the mortality rates are plateauing as well. | Included in both introduction and discussion
22 | 3 | 2) The point of view of the discussion is perhaps not as neutral as one would expect from an evidence synthesis review, and would encourage more neutral language.; For example:; --> “very” page 42, line 6 and again page 42, line 10; --> “surprisingly” p.43, line 31; --> page 42, line 3- This sentence is purely editorial and does not enhance what should be an objective assessment of the evidence, would suggest removing. “While shifting patterns of liver disease and cirrhosis etiology over this time period may partially account for HCC incidence and mortality findings an equally plausible explanation is that current screening programs may not be effective but are identifying and labeling individuals with HCC without improving receipt of effective therapies.” | Thank you for your thoughtful review, we have updated the discussion with a more neutral voice.; We modified this sentence to read: Shifting patterns of liver disease and cirrhosis etiology over this time may partially account for HCC incidence and mortality findings. However, current screening programs may be ineffective while identifying and labelling individuals with HCC without improving receipt of effective therapies.
23 | 3 | 3) page 44 line 23- The AASLD document is a guidance, and is not a guideline. There are differing criteria for development of these documents two types of documents. Would rewrite this paragraph in this context. The primary source document should be reviewed by this group Singal et al. Hepatology 2023 which clearly describes the differences between the two in the introduction. It is clear that the AASLD guidance is not equivalent to an evidence synthesis review and should not be viewed in the same vein. | We changed this to note that it is a guidance statement and reviewed the source document, as we had previously. Of note, guidance statement authors state that this “document was based on consensus of a multidisciplinary expert panel and provides guidance statements based on formal review and analysis of the literature… the literature review for this document is comprehensive and unbiased, the lack of mandatory systematic reviews facilitated more rapid publication”. The guidance statement provides “levels of evidence” and “strength of recommendations”. Furthermore, the AASLD website places both AASLD guidelines and guidance statement under a single link for practice guidelines. AASLD states: “AASLD develops evidencebased guidelines, practice guidances, and patients guidances to share recommended approaches to diagnostic, therapeutic, and preventive aspects of care.” notes that “Guidance statements help clinicians understand and implement the most recent evidence based on comprehensive review and analysis of the literature”. AASLD has developed quality measures in HCC care based on practice guidelines including AASLD. Final set of quality measures in HCC care include surveillance for HCC with HS every 6 months in all patents with cirrhosis and in Asian individuals with hepatitis B regardless of cirrhosis status. ( Asrani, Sumeet K.*; et al Quality measures in HCC care by the Practice Metrics Committee of the American Association for the Study of Liver Diseases. Hepatology 75(5):p 1289-1299, May 2022. \| DOI: 10.1002/hep.32240) Thus guidance statements have strong practice, policy, and performance implications that appear similar to recommendations made in AASLD guidelines. Finally, AASLD conflict of interest policy documents indicate that writing group panel members and chairs are not permitted to have engaged in consulting or own stock in pharmaceutical or biotechnology firms relevant to the topic. The chair and most panel writing members acknowledged such conflicts.
24 | 3 | Other minor comments-; 1) “Notably” used twice in the same paragraph page 42, line 30 and line36; 2) “Of particular note is temporal confounding (changes in screening availability concurrent with changes in cancer treatment and survival or changes in underlying liver disease etiology)” - p. 43, line 22 awkward sentence structure, consider refining/editing; 3) page 43, line 31, suggest k=5 be placed after “cohort studies” | Thank you, these sentences have been edited to be clearer.
25 | 4 | I appreciate all the work that went in to this review. Now the authors need to devote a similar effort to its communication.; The central finding is that there is no rigorous evidence to support screening high risk patients for HCC. While I don’t doubt this finding, I don’t think the authors have made a strong, clear case to specialist clinicians and VA policymakers. More attention should be given to explaining why the existing evidence is weak and to taking the opportunity to educate the reader. Note, this does not mean that the document needs to be lengthen. Instead, you can avoid the detailed description of the findings that you think are flawed. Relegate those to an appendix.; Here are some suggestions for improvement. | Thank you.
26 | 4 | 1. Give more weight (i.e., details) to the RCTs, less to the observational data; I suspect the authors would agree that observational data on screening are subject to huge biases and can be extraordinarily misleading. Thus, screening is one place where randomized trails are particularly important.; There are only 5 RCTs and you dispense with 3 of them. Why? I get you assess the risk of bias as extraordinarily high, but why? The table says something about adherence, but problems with screening adherence only biases the effect towards the null. I suspect you have identified more fundamental problems. If so, you should describe them. I suggest you do that in the final comment column of Table 3 (which is now used for boilerplate language).; For example, the Zhang study (Zhang BH, Yang BH, Tang ZY. Randomized controlled trial of screening for hepatocellular carcinoma. J Cancer Res Clin Oncol. 2004;130(7):417-422.) randomized 18,000 high risk patients and report a 37% decrease in HCC mortality. Of course, that’s all I can see in the abstract. But were I a proponent, I’d sure want to know why you threw that one out. | We provided greater detail regarding the risk of bias domains that raised our concerns with the identified RCTs in the text. We have provided additional information specifically relevant to the Zhang study in the discussion. To remain consistent throughout the document we chose not to include these details in the characteristics table.
27 | | There are only two case-control studies, but both are from VA. Table 5 is very confusing: each trial is judged as “low certainty”, but when you combine the two together they become “very low certainty”. What’s with that? Why combine the two at all? You are not pooling them. And you don’t do that for the RCTs. What is the risk of bias here? You gotta say more than “concerns about population chosen by study authors for control group”. | We have revised this to provide a single GRADEd statement related to the case-control studies. The decision was based after reviewing this comment and the overarching main question of whether screening is effective in “at risk adults”. Individuals with cirrhosis and Hepatitis B are both subsets of that overall population. We describe the individual studies without a separate GRADE statement thus providing the reader with results information by population group of interest. We elected to provide fairly substantial discussion of these two studies and populations because they are of higher methodological quality and conducted in VA.
28 | | At the other extreme are the HCC cohort studies. You imply these have little value, but are not clear about why. I imagine these are retrospective cohorts of HCC patients, looking backwards in time to determine the exposure: screen-detected vs clinically detected. Of course, that is an awful design. Because the decision of who to screen reflects a choice (made by either the patient or the provider) there is a strong tendency for sicker patients to be in the [underlined: not screened] group. Additionally, there are all the biases related to survival from the time of diagnosis (lead, length and overdx).; A strong section explaining why HCC cohort studies contribute no useful information would obviate the rest of this section: the tables and text could go in the appendix. | Thank you for your careful review, we updated our methods section to provide greater detail regarding the study design and limitations. We have chosen to retain the section describing the HCC cohort evidence. While we have strong reservations and concerns regarding the evidence we believe it is more informative to readers including clinicians, policy makers and researchers to list the studies, highlight reservations with the evidence and remain grounded in systematic review methods while presenting the information. We have incorporated some of these suggestions in our discussion.
29 | 4 | 2. Take the opportunity to educate the clinician reader Why not start each section for the 4 categories of studies (RCT, Case-control, Cohort, HCC Cohort) with a simple diagram of their design? (These could serve as a template for other evidence reviews as well.) It would be particularly useful to delineate/distinguish the 3 observational study designs (e.g., a case has experienced the outcome: HCC death. Who are the controls? A patient with cirrhosis? Who is in the non-HCC cohorts? What is the HCC cohort?). Then devote a few words to the generic weakness of each. | We added a 4x2 table to the methods section to briefly orient the reader to the difference between the observational study designs. Additional information is a bit beyond our review scope and perhaps adds too much technical description.
30 | 4 | 3. Better distinguish systematic error (bias) and random error (precision).; I know you want to combine the two for the “level of certainty” assessment, but they are very different issues and deserve separate consideration. I think you want to emphasize bias, “While we identified 74 eligible studies (including 5 RCTs) all but 15 were assessed as being high or critical risk of bias.” Who cares about a precise study that is precisely wrong? | To remain transparent and unbiased ourselves we chose to report all non-high risk of bias trials/studies in the results document.; GRADE Certainty of Evidence assessment incorporates both of these different domains and are considered separately.
31 | 4 | 4. Avoid reinforcing biased measures of early detection: Stage distribution & Survival; The word “survival” appears more than 100 times in the document - with the implication that it is a valid metric in the context of screening. It is not. But I fear your frequent use of the tern will lead readers to infer that any data showing prolonged survival associated with screening is evidence of benefit.; I understand you are primarily using the word in the context of “Overall Survival” (but not always). Find a different name: 10 year risk of death? Nevertheless, the starting point is ambiguous (e.g. measured from the time of diagnosis or the time of the cohort entry?); Better yet ask yourself, What does this metric adds to all-cause mortality? I understand one is a risk and the other a rate but they are essentially the same information. I tend to lose the duplicative metric; simpler is better.; I suggest you avoid the word “survival” entirely, unless you want to explain why it is biased in the setting of early detection. Make sure readers understand the [underlined: ultimate goal] of screening is to reduce mortality, not increase survival.; You don’t refer to the stage distribution per se, but you do lapse into the measure, “a higher proportion of patients receiving early stage diagnosis” and “Detection of localized disease has increased with increased screening; moving from 49.4% in 2000 to 62.1% diagnosed at a localized stage in 2016.” Without further explanation, readers may infer this as evidence of benefit. As I’m sure the authors recognize, this change may simply reflect increased early-stage incidence, without necessitating any decline in late-stage incidence. You should be clear that the [underlined: intermediate goal] of screening is to reduce the clinical presentation of late-stage cancer (i.e. late-stage incidence), not simply finding more early stage cancers. | We reviewed and limited the use of the word “survival” to studies specifically reported on “overall survival”. We agree that use of disease specific survival is not a valid metric of the effectiveness of screening.
32 | 4 | 5. Use more precise language/Reduce unneeded text & abbreviations; “Screening” and “surveillance” appear to be used as synonyms throughout the text. “Screening” implies the search for disease in individuals without symptoms of the disease. I believe “surveillance” should be reserved for treated cancer patients who have no symptoms of recurrence, but undergo testing for cancer recurrence. I understand the term is also applied to screening high risk groups. But you don’t need to muddy the water. Your working title is clear: Screening for hepatocellular carcinoma in increased risk adults: A systematic review. Stick with screening throughout.; Now that I write this, I found myself wondering whether this is about screening for hepatocellular carcinoma or screening for liver cancer. You do highlight that the former is a subset of the latter, “HCC is the most common form of liver cancer and accounts for approximately 75% of cases”. (I assume this refers to liver primaries, not metastatic disease.) | The text has been updated to use the term “screening” throughout.; Regarding liver cancer and HCC. We use these as synonymous. In most cancer statistics bile duct cancers are included in the category of “liver cancers”. We have clarified this to state that we are referring to this as screening for HCC/liver cancer and that these make up approximately 75% of all liver and bile duct cancers. While beyond the scope of this review we believe it is likely that cancers of the bile duct would likely be detected and treated incidentally in HCC screening programs. The net benefit of that is is not known and beyond our review scope.
33 | | It feels like some text has been recycled from other reviews. For example, there is an entire methods paragraph on pooling. Yet there are no pooled results. Go through the text and ruthless remove irrelevant boilerplate language. | Thanks for pointing this out. We have updated our methods section to remove what we anticipated we were going to do (and listed in our protocol) with what was actually done (narrative synthesis).
34 | | Finally, a pet peeve. Do you really need so many abbreviations? They make the document harder to read. I first got tripped up in the executive summary “incidence of HCV-related HCC”. Fine to use a select few (like HCC), but why not “incidence of hepatitis C-related HCC”.; Of course, a gastroenterologist won’t get tripped up by HCV. But they sure will with COE and RoB… Your goal should be to make it easier. | Thanks for this suggestion, we have updated the report to remove abbreviations that are only used seldomly, in favor of spelling out the term(s).
35 | 4 | 6. Reconsider the executive summary; First, you are right to start with the descriptive epidemiology. But why not draw a graph of the US incidence/mortality trends? A picture is worth 1000 words… (Again, you’ll have to decide if this is for HCC or all liver cancers).; It is also important to emphasize that the risk of HCC/liver cancer is higher among veterans. But this sentence missed the mark: “Incidence was higher in Medicare and Veterans Health Administration (VA) patients, (22.3 and 45 per 100,000 person-years respectively), compared to the USA population (9.5 per 100,000)”; Of course, the incidence is elevated in the population over age 65 (Medicare) relative to the general population – as it would be for virtually all cancers. See if you can compare the VA and non-VA population adjusted to the same age standard. (Failing this, you could argue the VA incidence is twice that of Medicare, despite the VA population being younger. But you need to explain it.) | We included the recent SEER data as a graph.; We note that these data are not age or comorbidity adjusted.
36 | 4 | Second, address the question: Who is at increased risk? (It’s in your title) You don’t really deal with this question until the Background and then overwhelm the reader with lists and no sense of magnitude of the risk. (Does Hispanic ethnicity and cirrhosis confer the same increase in risk?) I suggest a simple table here: major risk factors and the associated RR (go for big ones RR>2). I have the sense that you believe that cirrhosis for any reason (Hep C, Hep B, alcohol) is the central element for identifying the high risk population. If that’s right, say it. | We have streamlined the information provided. We agree that there are multiple risk factors for HCC. We also state that “increased risk” is broadly and variably defined by different authors. We noted that we took an expansive definition of increased risk, described the populations in the respective studies and stratified results where possible by “risk category” (eg, cirrhosis, Hep B (with or without cirrhosis). We also highlight how existing guidance statements provide similar stratified patient level recommendations by similar categories
37 | | Third, how about a small table of the various screening tests proposed. Maybe subcategorized by imaging, biochemical. You could define some abbreviations here (e.g. MRI, CT, US, AFP). | We believe these are described in text and the included tables of identified studies: ie, imaging modalities, including at various intervals (MRI, CT, US alone or in combination and with or without AFP). No additional tables are provided.
38 | 4 | Finally, I am confused by your summary table. I can find no reference to it in the text. It follows a results paragraph that includes “Of the 5 RCTs, 2 were rated some concerns RoB, while the other 3 were rated high RoB.” – yet the table includes only one RCT. More space is devoted to observation studies (particularly those I believe you think contribute least information: HCC cohort). Similarly, a lot of space is devoted to repeating one of two phrases: “The evidence is very uncertain” or “There may be little to no difference”. Invent a way to do this more efficiently. And, again, ask yourselves whether Overall Survival (or 10-year risk of death) adds anything to All-Cause Mortality. | Thank you for catching the missing RCT from our summary table, it has been added in. We used standard language recommended by GRADE to describe the summary results. The phrases: “The evidence is very uncertain” or “There may be little to no difference” are standard in the GRADE framework.
39 | 4 | 7. Call for a RCT in VA CSP; Why not end by calling for a VA trial of screening vs. no screening? You report that the risk of HCC death among VA patients with cirrhosis is about 8% @ 3years (Table 3 Pocha). That is really high. If that’s right, the sample size required to detect a 25% reduction in HCC mortality is only ≈ 5000 patients. Smaller, of course, with a 5 year trial. That’s feasible, right? | We have included this. We did previously but have highlighted some more. We note that the Premium trial claimed such a RCT would not be feasible. We include an article by Lederle et al that proposed such a trial, which was submitted to VA-CSP but not approved for planning.
40 | 4 | In general, there are too many numbers in the text. Some numbers are just not relevant to the central question at hand: Does screening reduce HCC mortality? (I understand there is no information on harms) | Thank you we have reviewed and streamlined when possible.
41 | 4 | I suggest you get rid of costs…distracting, more words…focus on the question of effectiveness. I also suggest you get rid of diagnostic performance measures (sensitivity, specificity, etc.). They are not only distracting, but also potentially misleading. | Thank you for the suggestion, however these were outcomes that were listed in our protocol to identify, extract data, and report on.
42 | 4 | Avoid repeating findings in tables and text – tables are where numbers are best digested, just focus on the most important (e.g. main effect, primary finding) in text. | Thank you we have reviewed and reduced repetitious use of findings when possible.
43 | 5 | Conclusions; - Page X (lines 14-16): The report concludes that, “Until evidence gaps are closed regarding HCC screening in adults at increased risk should be incorporated into patient, clinician and health system communication, decision-making and implementation strategies.” I believe that the extremely weak evidence of any benefits, the potential for harms, and the burden of time for patient/clinician communication of the issue, warrant a stronger statement. For example, I think that the report could state that until stronger studies are available, the state of evidence does not justify a role for HCC screening/surveillance in routine management or discussions with patients unless the patient spontaneously inquires. Instead, the VA may wish to incorporate that conclusion into a guideline rather than the evidence report. But at the least, you can make a clear statement of fact: the current state of the evidence presents a serious challenge to patient-clinician communication and informed decision-making. | We updated the conclusions to be more informative while avoiding statements that are more in scope for our topic nominators, particularly around recommendations for implementation or not.
44 | 5 | Methods (Analytic Framework; - Page 6 (line 27): You did not include treatment-related harms triggered by screening/surveillance, a reasonable decision given the lack of evidence. However, you refer to treatment-related harms as an “intermediate outcome.” Treatment-related harms are true health outcomes if increased by screening/surveillance. For example, you list overdiagnosis as a true, direct harm. A salient harm of overdiagnosis is unnecessary harm from treatment. So, if the data were available (e.g., from randomized clinical trials), excess harms associated with screening would count as a true health outcome along with overdiagnosis. This is analogous to excess all-cause mortality noted in some RCTs of cancer screening. | Thank you. We agree. Our analytic framework has treatment related harms in a separate oval consistent with Analytic Framework infographic methods. Our review was not intended to address treatment related harms as that would have markedly expanded review scope. We agree that treatment related harms for identified HCC (whether found on screening or otherwise) are important considerations.
45 | 5 | Discussion; - Page 29 (line 57-58): The increased incidence of HCC is identified as accompanied by a stage shift to local stage. However, simple increase in incidence of early-stage disease is not equivalent to an true stage shift. True stage shift implies an accompanying reduction in late-stage disease, not simply an increase in early-stage disease. | Thank you. Agree. Modified in the discussion. In our introduction we noted that the percentage of liver cancers detected as localized disease has increased with increased screening; moving from 49.4% in 2000 to 62.1% diagnosed at a localized stage in 2016
46 | 5 | Conclusions; - Page 34: Same comment as for Page X regarding a factual statement that the current state of the evidence presents a serious challenge to patient-clinician communication and informed decision-making. Preferably, you could make the statement that the state of evidence does not justify a role for HCC screening/surveillance in routine management or discussions with patients unless the patient spontaneously inquires. | We modified to emphasize the former while avoiding policy statements that are beyond the scope of our review.
47 | 6 | US vs. CT; cohort studies: (page 32 [19]) why were the studies considered to be low quality (what was the reason) | Individual risk of bias assessments for each study are available in the Appendix.
48 | 6 | Page 43, line53: remove extra “that” | This has been addressed.
49 | 7 | I appreciate the opportunity to review this ESG which is thoughtfully written. The authors are honest in their examination of the flaws in existing studies and helpful in proposing methodological approaches to close the evidence gaps. The writing is unclear at times and lacks uniformity. It is a highly methodological assessment of the analytical flaws and weakness of the evidence in a field fraught with heterogeneity. On the brighter side, future directions are offered with constructive suggestions and promising new studies are highlighted. | Thank you.
50 | 7 | The terms “screening” and “surveillance” are used interchangeably in this manuscript. However, HCC occurs in an at-risk population and we are performing surveillance (rather than screening which would be for an average risk/healthy population). It would be helpful if the language was uniform throughout the manuscript. | We used screening throughout for consistency. Screening is conducted in asymptomatic individuals and the term can be applied to those at “increased risk”. We recognize some variation in the field with these two terms. We prefer screening as surveillance may also include those with abnormalities on imaging tests that might undergo additional and more intensive “surveillance” and were out of scope for this review.
51 | 7 | In the conclusion, it is important to note that reference 45 is a guidance paper, not a guideline paper. The AASLD issued a guideline on HCC in 2018 with accompanying systematic reviews. The guidance published in 2023 is meant to be an update to the guideline. GRADE methodology was NOT used. In fact, we clearly state in the introduction: “AASLD guidelines are supported by systematic reviews of the literature, formal ratings of evidence quality and strength of recommendations, and, if appropriate, meta-analysis of results using the Grading of Recommendations Assessment Development and Evaluation system. In contrast, this document was developed by consensus of a multidisciplinary expert panel and provides guidance statements based on formal review and analysis of the literature on the topics and questions related to the prevention, diagnosis, and treatment of HCC. Although the literature review for this document is comprehensive and unbiased, the lack of mandatory systematic reviews facilitated more rapid publication. The expert panel rated the level of evidence for each recommendation based on the Oxford Center for EvidenceBased Medicine.1 Additionally, the panel categorized the strength of recommendations based on the level of evidence, risk–benefit ratio, and patient preferences.” | We have noted that change and more fully described the AASLD guidance document, processes and AASLD stated use of guidance documents and their incorporation into AASLD practice metrics.
52 | 7 | Please change all “guideline(s)” terms to “guidance” in this paragraph (page 31, lines 24, 37, 38, 39, and 42). The sentence beginning, “Most guideline panel members had industry financial conflicts of interest…” is frankly untrue. The AASLD has strict policies regarding conflict of interest (COI) for authors on guidance/guideline writing groups. Both the AASLD and IOM require the majority of Writing Group members to be free of all commercial COI. In addition, the AASLD sets a financial limit on compensation that can be received for those members with COI (please see https://doi.org/10.1002/hep.29810). Furthermore, the writing group included medical, surgical, and radiation oncologists, radiologists, interventional radiologists, and transplant surgeons in addition to hepatologists - with broad geographical and institutional diversity. I don’t see primary care physicians or public representatives on ASCO or other specialty society guidelines, so why is the AASLD held to a higher standard? | Done. We included the AASLD “strict policies” regarding COI. Of note, the guidance chair and most of the writing group members have listed disclosues that appear to be in conflict with AASLD policies (ie, consultation with and ownership of stocks in pharmaceutical and biotechnology companies.; AASLD and other guideline committees are held to standards set by the Institute of Medicine and Guidelines International for High Quality Guidelines. The intent of clinical guidelines is to provide rigorous, readable, relevant information that is free of real or perceived bias and incorporates a broad perspective. We reference and used an established metric for assessment (AGREE) for assessing quality of guideline. Primary care clinicians are often responsible for implementing screening strategies, referring patients and engaging in discussions. A detailed discussion of the AASLD guidance statement, their stated methods, processes and policy implications is now provided in the Discussion.
53 | 7 | The use of the abbreviation USA is important to distinguish this from ultrasound, abbreviated as US. Please check for uniformity of this abbreviation (e.g., page 12, lines 36 and 39; page 24, line 48) and introduce the abbreviation properly on page 4, line 8 as “United States of America”. | We have updated the text to spell out the word “ultrasound” and reserved the abbreviation (US) for the tables only. We have also reviewed the report to make sure all instances of “USA” are accurate.
54 | 7 | On page 4, line 20, “A recently published, 2022, systematic review…” in erroneous as this paper was published in 2020. | This sentence was revised and the review has been cited appropriately.
55 | 7 | On page 4, line 34 (and throughout the manuscript), consider adopting the new nomenclature of Steatotic Liver Disease to replace NAFLD. | This has been updated to MASLD throughout the text.
56 | 7 | Page 4, line 39-41 should be restated as “Of concern for the USA population, both diabetes and body mass index (BMI) have been associated with HCC in individuals with ALD cirrhosis. The association between diabetes and HCC is also observed in individuals with NAFLD cirrhosis.” (The term cirrhotic is pejorative and the sentence is awkward.) | Thank you for the suggested wording, we have updated for clarity.
57 | 7 | Page 4, line 47, “populations have a 5-fold HCC incidence” - should be “5-fold higher HCC incidence” | Thank you, this has been corrected.
58 | 7 | Page 4, line 49, “costs in the VA related to cirrhosis is…” - “is” should be changed to “are” | Thank you, this has been corrected.
59 | 7 | Page 4, line 51, “indentification of liver cancers may reduce disease specific and…” is nebulous (remember that people who get liver cancer usually have liver disease, so I would clarify this as “identification of liver cancers may reduce cancer-related and…”) | Thank you, this has been corrected.
60 | 7 | Page 6, line 17, should read “…HCC based on a current or past history of liver disease (including cirrhosis) or infection.” This sentence and the analytic framework are a bit nebulous. The population at risk are those with cirrhosis (all etiologies) and chronic hepatitis B, correct? | Thank you, this has been corrected.
61 | 7 | Page 7, the analytic framework - in the Treatement of Detected HCC box, change “radiofrequency ablation” to “ablation” as there are many techniques (RFA, microwave, cryo, etc.). Consider transarterial therapies, rather than transarterial chemoembolization, as some centers use bland embolization and some centers use Y90. Chemotherapy should be changed to “systemic therapy” as conventional chemotherapy is not used for HCC. In the box labeled KQ2: Variables, take out the double hash marks for the etiologies and have a uniform approach to either capitalize (or not) the patient characteristics. | We agree and updated the analytic framework as suggested.
62 | 7 | Page 8, line 12, why is “severity” in quotes? Liver disease severity is a key factor in HCC treatment assignment, as often times, treating HCC in a patient with severe liver disease will cause great harm. | The quotes have been removed.
63 | 7 | Page 8, line 32, All-cause mortality (rather than All-Cause Mortality) | Thank you, this has been corrected.
64 | 7 | Page 8, line 34, a liver biopsy is not a screening related harm - it may be a screening related necessity (e.g., for a LI-RADS M lesion). a liver biopsy complication may be a screening related harm. | A liver biopsy is an invasive and costly procedure. At a minimum there is patient inconvenience and time. Biopsies result in patient anxiety, worry and pain and out of pocket costs even in the absence of a “complication” such as bleeding or infection. A biopsy is a harm as a downstream consequence. Harris and colleagues have written about a taxonomy of screen related harms. These include psychological and financial and physical. Liver biopsies are associated with all of these even if there are not more severe harms such as a “complication”.
65 | 7 | Page 12, the language changes, for example, the phrase “reporting on” becomes frequent. The phrase “reporting on” should be changed to “reporting” on page 12, lines 39 and 40; page 23, line 38; page 24, line 8. | Thank you, this has been corrected.
66 | 7 | Page 14, lines 4 and 5, the terms “fewer” and “more” are odd choices when referring to overall mortality - lower or higher make more sense. | This entire paragraph has been reworked for clarity, the terms “fewer” and “more” refer to the absolute effect estimates of all-cause mortality (e.g., fewer deaths).
67 | 7 | Page 17, line 16, “The first study” should read “In the first study…” | Thank you, this has been corrected.
68 | 7 | Page 23, lines 41-44, consider changing the last sentence of the paragraph to “Tong, et al reported that in a population including a substantial portion of HBV patients (>50%), individuals undergoing routine imaging ultrasound (ultrasound plus AFP) were more likely to receive liver transplant (21.7%) than those in a non-screening group (5.7%). | Thank you for the suggestion, we have updated this sentence.
69 | 7 | Page 29, line 50 should read “increased detection without decline in mortality” | Thank you, this has been corrected.
70 | 7 | Page 29, line 60 should read “…increase in HCC attributable death has occurred…” | Thank you, this has been corrected.
71 | 7 | Page 30, line 16 should read “…slower progressing cancer which has a better prognosis…” | Thank you, this has been corrected.
72 | 7 | Page 30, line 31 “(k=5)” is that n=5? | “k” is typically used to indicate number of studies identified in a review (while “n” is used to indicate sample size of a study); however, this sentence has been revised for clarity.
73 | 7 | Page 30, line 32 should read “…The remaining study by Kim, et al in 2020…” | Thank you, this has been corrected.
74 | 7 | Page 30, line 35 makes no sense to me: “While unique to individual studies these issue highlight data limitations and evidence uncertainty.” Are you talking about unique biases? Unique methodological flaws? | This sentence has been deleted.
75 | 7 | Page 30, line 53, the word “that” is repeated twice: “Kansagara et al in that that their…” (also, the convention in this paper is Author, et al - so a comma needs to follow Kansagara) | Thank you, this has been corrected.
76 | 7 | Page 32, line 3, this sentence is odd. All treatments, curative or palliative may have attendant harms. The statement “Treatments have considerable harms due to surgical resection, ablation or liver transplantation.” makes absolutely no sense and connotes that treatment is equivalent to harm which is the antithesis of what we hope to achieve.7 | All treatments have harms. They may also have benefits. Surgery, ablation and liver transplantation have important physical, financial, psychologic, resource, time, societal harms. These exist beyond the typically viewed harms of “serious complications” of a procedure such as sepsis, perioperative bleeding, or death. It is surprising to us that the reviewer views our factual statement as odd. We now include a reference supporting our statement and slightly modified the statement; Harris RP, Sheridan SL, Lewis CL, Barclay C, Vu MB, Kistler CE, Golin CE, DeFrank JT, Brewer NT. The harms of screening: a proposed taxonomy and application to lung cancer screening. JAMA Intern Med. 2014 Feb 1;174(2):281-5. doi: 10.1001/jamainternmed.2013.12745. Erratum in: JAMA Intern Med. 2014 Mar;174(3):484. PMID: 24322781.
77 | 7 | Page 32, line 44, choose a term - outlined or identified | Thank you, this has been corrected.

## RANDOMIZED CONTROLLED TRIALS

Appendix Table 1 Outcomes Reported for Randomized Controlled Trials Rated Some Concerns Risk of Bias

Author, Year, Comparison | Overall Mortality k=1 | Overall Survival k=1 | HCC-Specific Mortality k=2 | HCC Stage at Diagnosis k=1 | % Receiving Curative Treatment k=0 | % Receiving Liver Transplant k=2 | % Diagnosed with Biopsy k=1 | Sensitivity/Specificity k=1 | Financial Burden k=1
Pocha, 2013,^22^; US (6m) vs US (12m) | | | X | X | | X | X | X | X
Trinchet, 2011,^23^; US (3m) vs US (6m) | X | X | X | | | X

HCC=hepatocellular carcinoma; m=months; US=ultrasound

Appendix Table 2 Detailed Characteristics and Outcomes Reported for RCTs Rated Some Concerns Risk of Bias

Author, Year Country | Inclusion Criteria Mean Follow-up | Baseline Characteristics | | Outcomes Reported
Author, Year Country | Inclusion Criteria Mean Follow-up | Intervention | Comparison | Intervention | Comparison
Pocha^*^, 2013^22^; USA | Adults aged 18-70 with Child’s A cirrhosis and were potential candidates for treatment of HCC.; CT arm: 31 months (range 0–84) Ultrasonography arm: 35 months (range 0–90) | US + AFP every 6 months; N=83; Age: 59.2 (SD 5.3); % Female: 0; % Black: 4.8; % Hispanic: 2.4; % White: 88; % HBV: 2.4; % HCV: 86.7; % Alcohol-related: 7.2; % Cirrhosis: 100 | CT+AFP every 12 months (AFP every 6 months); N=80; Age: 59.5 (SD 5.3); % Female: 1.2; % Black: 12.5; % Hispanic: 2.4; % White: 78.8; % HBV: 1.3; % HCV: 87.5; % Alcohol-related: 7.5; % Cirrhosis: 100 | HCC-specific mortality 5/83 (6%); BCLC Stage 0/A/B at diagnosis 66.6%; BCLC Stage C/D at diagnosis 33.3%; Liver transplant 4/83 (4.8%); HCC diagnosis with biopsy 6/9 (66.7%); False negative 2/83 (2.4%); False positive 3/83 (3.6%); Total cost per HCC detected: 12069 (VA); $17041 (nonVA) | HCC-specific mortality 7/80 (8.8%); BCLC Stage 0/A/B at diagnosis 75%; BCLC Stage C/D at diagnosis 25%; Liver transplant 2/80 (2.5%); HCC diagnosis with biopsy 6/8 (37.5%); False negative 1/80 (1.2%); False positive 9/80 (5.6%); Total cost per HCC detected: 18768 (VA); $57383 (nonVA)
Trinchet, 2011^23^; France/Belgium | Adults >18 with histologically proven cirrhosis without previous complications of cirrhosis or focal liver lesion; 3m arm: 47 months (range 29–65); 6m arm: 46 months (range 30–66) | US every 3 months; N=640; Age: 54 (IQR 47-61); % Female: 30.5; % HBV: 12.8; % HCV: 44.7; % Alcohol-related: 39.4; % Cirrhosis: 100 | US every 6 months; N=638; Age: 55 (48-64); % Female: 31.3; % HBV: 12.2; % HCV: 43.6; % Alcohol-related: 39.0; % Cirrhosis: 100 | All-Cause Mortality 72/640 (11.3%); Overall survival (estimated at 5 years) 84.9%; P=0.38; HCC-specific mortality 17/640 (23.6%); Liver transplant 17/640 (2.7%) | All-Cause Mortality 82/638 (12.1%); Overall survival (estimated at 5 years) 85.8%; HCC-specific mortality 12/638 (14.6%); Liver transplant 13/638 (2.0%)

Notes.

* Conducted in VHA.

Abbreviations. AFP=alpha-fetoprotein; CT=computed tomography; HBV=hepatitis B virus; HCC=hepatocellular carcinoma; HCV=hepatitis C virus; IQR=interquartile range; m=months; SD=standard deviation; US=ultrasound; USA=United States of America; VA=Veteran’s Health Administration.

## CASE-CONTROL STUDIES

Appendix Table 3 Detailed Study Characteristics for Case-Control Studies

Author, Year; Risk of Bias | Country; Data Source; (Year) | Screening Comparison | Population Characteristics | Disease Characteristics | Liver Disease Severity | Outcomes Reported
Moon, 2018^24^; Low | USA; VA CDW; (2013-2015) | US + AFP: within 4 years before HCC diagnosis; None: “probably not” and “definitely not” | N=476; Arm A N=241; Mean Age: NR; Race:; White 74%; Black 15%; Asian NR; Arm B N=235; Mean Age: NR; Race:; White 74%; Black 15%; Asian NR; Overall Mean Age: 62; Veterans: Yes | Arm A; Cirrhosis 100%; Hepatitis B: NR; Hepatitis C: 80%; Hepatitis B+C: NR; Alcohol: 13%; Metabolic disease: 2.9%; Arm B; Cirrhosis: 100%; Hepatitis B: NR; Hepatitis C: 80%; Hepatitis B+C: NR; Alcohol: 13%; Metabolic disease: 2.9% | NR | HCC-specific mortality; Diagnosis by biopsy; %Transplant
Su, 2021^25^; Low | USA; VA CDW; (2004-2017) | US +/- AFP: Unclear, up to 4 years before index date; None | N=338; Arm A N=169; Mean Age: 59.9; Race:; White 46.2%; Black 39.1%; Asian NR; Arm B N=169; Mean Age: 60.3; Race:; White 44.4%; Black 34.9%; Asian NR; Veterans: Yes | Arm A; Cirrhosis 36.7%; Hepatitis B: 100%; Hepatitis C: NR; Hepatitis B+C: NR; Alcohol: 36.7%; Metabolic disease: NR; Arm B; Cirrhosis: 36.7%; Hepatitis B: 100%; Hepatitis C: NR; Hepatitis B+C: NR; Alcohol: 42%; Metabolic disease: NR | NR | HCC-specific mortality; Diagnosis by biopsy; %Transplant

Abbreviations. AFP=alpha-fetoprotein; CDW=corporate data warehouse; HCC=hepatocellular carcinoma; NR=not reported; US=ultrasound; USA=United States of America; VA=Veteran’s Health Administration.

Appendix Table 4 Outcomes Reported for Included Case-Control Studies

Author, Year, Comparison | Overall Mortality k=0 | Overall Survival k=0 | HCC-Specific Mortality k=2 | HCC Stage at Diagnosis k=0 | % Receiving Curative Treatment k=0 | % Receiving Liver Transplant k=2 | % Diagnosed with Biopsy k=2 | Sensitivity/Specificity k=0 | Financial Burden k=0
Moon, 2018,^24^; US + AFP vs none | | | X | | | X | X
Su, 2021,^25^; US +/- AFP vs none | | | X | | | X | X

Abbreviations. AFP=alpha-fetoprotein; HCC=hepatocellular carcinoma; US=ultrasound.

Appendix Table 5 Detailed Results for for Case-Control Studies

Author, Year; Risk of Bias; Follow-Up | Intervention/Comparison Definition | HCC-Specific Mortality | | | Receiving Liver Transplant | | HCC Diagnosis Using Biopsy
Author, Year; Risk of Bias; Follow-Up | Intervention/Comparison Definition | Intervention; Events (n); Total (N) (%) | Comparison; Events (n); Total (N) (%) | Results | Intervention; Events (n); Total (N) (%) | Comparison; Events (n); Total (N) (%) | Intervention; Events (n); Total (N) (%) | Comparison; Events (n); Total (N) (%)
Moon, 2018^24^; Low; 0-4 years before index date, adjusted | US + AFP: within 4 years before HCC diagnosis; None: “probably not” and “definitely not” | n: 111/238; N: 238; 46.6% | n: 115; N: 238; 48.3% | US + AFP vs no screening HR 0.87 (95% CI 0.44, 1.72) | n: 0; N: NR; 0% | n: NR; N: NR; % NR | n: 69; N: 238; 29.0% | n: NR; N: NR; % NR
Su, 2021^25^; Low; 0-4 years before index date, adjusted | US +/- AFP: Unclear, up to 4 years before the index date; None | n: 57; N: 169; 33.7% | None: NA; n: 99; N: 169; 58.6% | US +/- AFP vs no screening aOR 0.21 (95% CI 0.09-0.50) | n: 2; N: 239; 1.2% | n: NR; N: NR; % NR | n: 79; N: 239; 46.7% | n: NR; N: NR; % NR

Abbreviations. AFP=alpha-fetoprotein; aOR=adjusted odds ratio; CI=confidence interval; HCC=hepatocellular carcinoma; HR=hazard ratio; NR=not reported; US=ultrasound.

## COHORT STUDIES

Appendix Table 6 Detailed Study Characteristics for Cohort Studies Rated Serious Risk of Bias

Author, Year; Risk of Bias | Country; Data Source; (Year) | Screening Comparison | Population Characteristics | Disease Characteristics | Liver Disease Severity; Child-Pugh Score | Outcomes Reported
Kim, 2020^26^; Serious | Korea; Four tertiary hospitals in Korea; (2007-2016) | US: q6m; US+CT: q6m | N=992; Arm A N=496; Mean Age: NR; Race: NR; Arm B N=496; Mean Age: NR; Race: NR | Arm A; Cirrhosis 100%; Hepatitis B: 100%; Hepatitis C: 0%; Hepatitis B+C: 0%; Alcohol: NR; Metabolic disease: NR; Arm B; Cirrhosis: 100%; Hepatitis B: 100%; Hepatitis C: 0%; Hepatitis B+C: 0%; Alcohol: NR; Metabolic disease: NR | %A/%B/%C; Arm; A: 87.1/12.9/0; B: 88.4/11.6/0 | Overall mortality; Overall survival

Abbreviations. CT=computed tomography; m=months; NR=not reported; q=every; US=ultrasound.

Appendix Table 7 Outcomes Reported for Cohort Studies Rated Serious Risk of Bias

Author, year, Comparison | Overall Mortality k=1 | Overall Survival k=1 | HCC-Specific Mortality k=0 | HCC Stage at Diagnosis k=0 | % Receiving Curative Treatment k=0 | % Receiving Liver Transplant k=0 | % Diagnosed with Biopsy k=0 | Sensitivity/Specificity k=0 | Financial Burden k=0
Kim, 2020,^26^; US vs US+CT | X | X

Abbreviations. CT= computed tomography; HCC=hepatocellular carcinoma; US=ultrasound.

Appendix Table 8 Detailed Results for for Cohort Studies

Author, Year; Risk of Bias; Follow-Up | Intervention/Comparison Definition | Overall Mortality | | Overall Survival
Author, Year; Risk of Bias; Follow-Up | Intervention/Comparison Definition | Intervention; Events (n); Total (N) (%) | Comparison; Events (n); Total (N) (%) | Results | Intervention; Events (n); Total (N) (%) | Comparison; Events (n); Total (N) (%)
Kim, 2020^26^; Serious; 10 years | US: 6 months; US+CT: 6 months | NR | NR | US vs US+CT HR = 0.42, 95% CI [0.24, 0.73], p=0.002 | n: NR; N: 659; 93.3% | n: NR; N: 576; 96.5%

Abbreviations. AFP=alpha-fetoprotein; CT=computed tomography; HCC=hepatocellular carcinoma; HR=hazard ratio; NR=not reported; US=ultrasound.

## HCC COHORT STUDIES

Appendix Table 9 Detailed Study Characteristics for HCC Cohort Studies

Author, Year; Risk of Bias | Country; Data Source; (Year) | Screening Comparison | Population Characteristics | Disease Characteristics | Liver Disease Severity; Child-Pugh Score | Outcomes Reported
An, 2020^27^; Serious | Korea; Prospective hospital-based registry - Asan Medical Center; (2007-2015) | AFP: biannually; US: biannually; US + AFP: biannually | N=1776; Arm A N=298; Mean Age: NR; Race:; White 0%; Black 0%; Asian 100%; Arm B N=978; Mean Age: NR; Race:; White 0%; Black 0%; Asian 100%; Arm C N=500; Mean Age: NR; Race:; White 0%; Black 0%; Asian 100% | Arm A; Cirrhosis 92.3%; Hepatitis B: 80.2%; Hepatitis C: 12.1%; Hepatitis B+C: NR; Alcohol: NR; Metabolic disease: NR; Arm B; Cirrhosis: 85.2%; Hepatitis B: 81.8%; Hepatitis C: 7.9%; Hepatitis B+C: NR; Alcohol: NR; Metabolic disease: NR; Arm C; Cirrhosis: 85.6%; Hepatitis B: 83.8%; Hepatitis C: 9.8%; Hepatitis B+C: NR; Alcohol: NR; Metabolic disease: NR | %A/%B/%C; Arm; A: 85.9/14.1/0; B: 91.8/8.2/0; C: 92/8/0 | Overall mortality; Overall survival; HCC-specific mortality; HCC stage at diagnosis; Diagnosis with biopsy; %Curative treatment; %Transplant
Bae, 2021^28^; Serious | Korea; National Health Insurance Service Database of Korea; (2008-2017) | US + AFP: q≤6m; US + AFP: q7-12m; US + AFP: q13-24m; US + AFP: q25-36m; No screening | N=64674; Arm A N=15587; Arm B N=6569; Arm C N=7383; Arm D n=3853; Arm E N=31282; Mean Age: NR; Race: NR | Overall; Cirrhosis 63.4%; Hepatitis B: 53.8%; Hepatitis C: 11.1%; Hepatitis B+C: 3.6%; Alcohol: 12.4%; Metabolic disease: NR | %A/%B/%C; NR | Overall mortality; %Curative
Kim, 2018^29^; Serious | Korea; Seoul National University Hospital; (2005-2012) | US +/- AFP: mean of ≤ 8 months for ≥ 2 years US +/- AFP: Irregular; None | N=1402; Arm A N=834; Mean Age: 58.4 (9.2); Race:; White 0%; Black 0%; Asian 100%; Arm B N=104; Mean Age: 57.6 (9.3); Race:; White 0%; Black 0%; Asian 100%; Arm C N=464; Mean Age: 57 (10.5); Race:; White 0%; Black 0%; Asian 100% | Arm A; Cirrhosis 86%; Hepatitis B: 83.5%; Hepatitis C: 11%; Hepatitis B+C: 0.4%; Alcohol: NR; Metabolic disease: NR; Arm B; Cirrhosis: 86.5%; Hepatitis B: 92.3%; Hepatitis C: 4.8%; Hepatitis B+C: 1%; Alcohol: 0%; Metabolic disease: NR; Arm C; Cirrhosis: 62.3%; Hepatitis B: 72.2%; Hepatitis C: 7.3%; Hepatitis B+C: 0.2%; Alcohol: 0%; Metabolic disease: NR | %A/%B/%C; Arm; A: 67.6/15.3/3; B: 69.2/11.5/5.8; C: 38.8/19/4.5 | Overall mortality; Overall survival; HCC stage at diagnosis; %Curative treatment
Mittal, 2016^30^; Serious | USA; VA administrative data files; (2004-2011) | US/MRI/CT +/- AFP: HCC surveillance defined as receipt of ≥1 liver imaging test with or without AFP for surveillance purposes within 2 years prior to HCC diagnosis date. AFP surveillance defined as receipt of 2 or more AFP tests at least 6 months apart; None | N=887; Arm A N=412; Race:; White 63.6%; Black 19.4%; Asian NR; Arm B N=475; Race:; White 57.7%; Black 26.3%; Asian NR; Overall mean age: 62.5 (8.9); US Veterans | Arm A; Cirrhosis 100%; Hepatitis B: 4.6%; Hepatitis C: 86.9%; Hepatitis B+C: NR; Alcohol: 86.7%; Metabolic disease: 1.5%; Arm B; Cirrhosis: 100%; Hepatitis B: 4.6%; Hepatitis C: 70.1%; Hepatitis B+C: NR; Alcohol: 90.3%; Metabolic disease: 4.4% | %A/%B/%C; Arm; A: 40.8/35.6/17.5; B: 42.2/44.2/11.7 | Overall mortality; HCC stage at diagnosis; %Transplant
Pelizzaro, 2022^31^; Serious | Italy; Italian Liver Cancer (ITA.LI.CA) database; (1987-2017) | US: q3±1 months; US: q6±1 months | N=1107; Arm A N=109; Arm B N=998; Mean Age: NR; Race: NR | Arm A; Cirrhosis 100%; Hepatitis B: 22%; Hepatitis C: 73.4%; Hepatitis B+C: 4.6%; Alcohol: NR; Metabolic disease: NR; Arm B; Cirrhosis: 100%; Hepatitis B: 12.6%; Hepatitis C: 85%; Hepatitis B+C: 2.4%; Alcohol: 0%; Metabolic disease: NR | %A/%B/%C; Arm; A: 69.8/28.4/1.8; B: 71.3/25.9/2.8 | Overall mortality; Overall survival; HCC-specific mortality; %Curative; %Transplant; Financial burden
Pinero, 2019^32^; Serious | Argentina; 14 hospitals in Argentina; (2009-2014) | US: Every 6 months during last year of follow-up until HCC diagnosis; None | N=553; Arm A N=345; Race: NR; Arm B N=208; Race: NR; Overall Mean Age: 62 (9) | Arm A; Cirrhosis NR; Hepatitis B: 4.3^*^%; Hepatitis C: 44.9^*^%; Hepatitis B+C: NR; Alcohol: 18.8^*^%; Metabolic disease: 11.6^*^%; Arm B; Cirrhosis: NR; Hepatitis B: NR; Hepatitis C: 44.2^*^%; Hepatitis B+C: NR; Alcohol: 0%; Metabolic disease: 13.0^*^% | %A/%B/%C; Overall Population; 53.3/41.9/4.7 | Overall mortality; HCC stage at diagnosis
Tanaka, 2006^33^; Serious | Japan; Okayama University Hospital; (1991-2003) | US + AFP: q6m; None | N=384; Arm A N=182; Mean age: 65; Arm B N=202; Mean age: 65; Race: NR | Arm A; Cirrhosis 84%; Hepatitis B: 0%; Hepatitis C: 100%; Hepatitis B+C: 0%; Alcohol: 14%; Metabolic disease: NR; Arm B; Cirrhosis: 76%; Hepatitis B: 0%; Hepatitis C: 100%; Hepatitis B+C: 0%; Alcohol: 18%; Metabolic disease: NR | %A/%B/%C; Arm; A: 64/32/3; B: 58/39/3 | Overall survival
Thein, 2015^34^; Serious | Canada; Ontario Cancer Registry (OCR) linked health administrative data; (2000-2010) | US: Routine surveillance; US: Inconsistent screening None | N=1483; Arm A N=302; Arm B N=641; Arm C N=540; Race NR; Mean age: NR | Arm A; Cirrhosis NR; Hepatitis B: NR; Hepatitis C: NR; Hepatitis B+C: NR; Alcohol: 3.6%; Metabolic disease: NR; Arm B; Cirrhosis: NR; Hepatitis B: NR; Hepatitis C: NR; Hepatitis B+C: NR; Alcohol: 11.2%; Metabolic disease: NR; Arm C; Cirrhosis: NR; Hepatitis B: NR; Hepatitis C: NR; Hepatitis B+C: NR; Alcohol: 18.1%; Metabolic disease: NR | %A/%B/%C; NR | Overall mortality; Overall survival; %Curative
Tong, 2017^35^; Serious | USA; Liver Center, Pasadena, CA; (1984-2014) | US + AFP: 6-12 months; None: NA | N=333; Arm A N=175; Mean age: 63.5 (11.1); Arm B N=158; Mean age: 59.8 (13.2); Overall race; White 18%; Black 2%; Asian 70% | Arm A; Cirrhosis 80%; Hepatitis B: 46%; Hepatitis C: 54%; Hepatitis B+C: <1%; Alcohol: NR; Metabolic disease: NR; Arm B; Cirrhosis: 74%; Hepatitis B: 57%; Hepatitis C: 41%; Hepatitis B+C: 2%; Alcohol: NR; Metabolic disease: NR | %A/%B/%C; Arm; A: 83/13/5; B: 63/32/4 | Overall survival; %Transplant; %Curative
Trevisani, 2004^36^; Serious | Italy; Clinic records from 7 Italian medical institutions; (1988-2001) | US + AFP: q6-12m; None: Incidentally detected; None: Detected by symptoms | N=363; Arm A N=158; Mean Age: 73.9 (3.6); Arm B N=138; Mean age: 74.9 (3.7); Arm C N=67; Mean age: 74.6 (4.5); Race: NR | Arm A; Cirrhosis NR; Hepatitis B: 9.5%; Hepatitis C: 67.1%; Hepatitis B+C: 2.5%; Alcohol: 5.7%; Metabolic disease: NR; Arm B; Cirrhosis: NR; Hepatitis B: 6.5%; Hepatitis C: 58%; Hepatitis B+C: 3.6%; Alcohol: 12.3%; Metabolic disease: NR; Arm C; Cirrhosis: NR; Hepatitis B: 11.9%; Hepatitis C: 53.7%; Hepatitis B+C: 7.5%; Alcohol: 10.4%; Metabolic disease: NR | %A/%B/%C; Arm; A: 76.8/18..5/4.6; B: 68.7/29.8/1.5; C: 42.4/43.9/13.6 | Overall survival; HCC stage at diagnosis
Wu, 2016^37^; Serious | Taiwan; Taiwan’s National Health Insurance Research Database (NHIRD); (2002-2007) | US: q1-6m; US: q7-12m; US: q13-24m; US: q25-36m months; No screening: never/not in last 3 years | N=52823; Arm A N=19115; Mean Age: 63 (11.9); Arm B N=4837; Mean Age: 63.9 (12.5); Arm C N=4795; Mean Age: 64.5 (13); Arm D N=2957; Mean Age: 64.3 (13.0); Arm E N=21119; Mean Age: 60.8 (14.7); Race: NR | Arm A; Cirrhosis 69.4%; Hepatitis B: 32.2%; Hepatitis C: 33.7%; Hepatitis B+C: %; Alcohol: 12.8%; Metabolic disease: %; Arm B; Cirrhosis: 56.7%; Hepatitis B: 29%; Hepatitis C: 30.7%; Hepatitis B+C: %; Alcohol: 9.4%; Metabolic disease: %; Arm C; Cirrhosis: 50.6%; Hepatitis B: 28.3%; Hepatitis C: 24.7%; Hepatitis B+C: %; Alcohol: 8.1%; Metabolic disease: %; Arm D; Cirrhosis: 46.8%; Hepatitis B: 25.1%; Hepatitis C: 22.5%; Hepatitis B+C: %; Alcohol: 7.9%; Metabolic disease: NR; Arm E; Cirrhosis: 38.6%; Hepatitis B: 27% | %A/%B/%C; NR | Overall mortality; Diagnosis with biopsy; %Curative treatment

Notes.

* Calculated by ESP team.

Abbreviations. AFP=alpha-fetoprotein; CT=computed tomography; HCC=hepatocellular carcinoma; m=months; MRI=magnetic resonance imaging; NR=not reported; q=every; US=ultrasound; USA=United States of America; VA=Veteran’s Health Administration.

Appendix Table 10 Outcomes Reported for Included HCC Cohort Studies

Author, Year, Comparison | Overall Mortality k=8 | Overall Survival k=7 | HCC-Specific Mortality k=2 | HCC Stage at Diagnosis k=4 | % Receiving Curative Treatment k=7 | % Receiving Liver Transplant k=4 | % Diagnosed with Biopsy k=2 | Sensitivity/Specificity k=0 | Financial Burden k=1
An, 2020,^27^ US vs AFP vs US + AFP (biannually) | X | X | X | X | X | X | X
Bae, 2021,^28^ US + AFP (1-6m) vs different intervals | X | | | | X
Kim, 2018,^29^ US +/- AFP (routine) vs irregular vs none | X | X | | X | X
Mittal, 2016,^30^ Any imaging +/- AFP vs none | X | | | X | | X
Pelizzaro, 2022,^31^ US (3m) vs US (6m) | X | X | X | | X | X | | | X
Piñero, 2019,^32^ US (6m) vs none | X | | | X
Tanaka, 2006,^33^ US + AFP (6m) vs none | | X
Thein, 2015,^34^ US (routine) vs different intervals vs none | X | X | | | X
Tong, 2017,^35^ US + AFP (6-12m) vs none | | X | | | X | X
Trevisani, 2004,^36^ US + AFP vs none | | X
Wu, 2016,^37^ US (1-6m) vs different intervals | X | | | | X | | X

Abbreviations. AFP=alpha-fetoprotein; HCC=hepatocellular carcinoma; m=months; US=ultrasound.

Appendix Table 11 Results for All-Cause Mortality for HCC Cohort Studies

Author, Year; Risk of Bias; Follow-Up | Arm A Intervention; Mortality; Events (n); Total (N); (%) | Arm B Intervention; Mortality; Events (n); Total (N); (%) | Arm C, D, E Intervention; Mortality; Events (n); Total (N); (%) | Results
An, 2020^27^; Serious; 5 years | AFP: biannually; n: 88; N: 298; 29.5% | US: biannually; n: 253; N: 978; 25.9% | US + AFP: biannually; n: 198; N: 500; 39.6% | US biannually; vs US + AFP: biannually; HR (95% CI) 0.53 (0.43, 0.64)* no lead time adjustment; AFP biannually vs US + AFP: biannually; HR (95% CI) 0.74 (0.57, 0.95) with lead time=120 days
Bae, 2021^28^; Serious; 8 years | US + AFP: 6 months or fewer; n: 5608; N: 15587; 36.0% | US + AFP: 7-12 months; n: 2185; N: 6569; 33.3% | US + AFP: 13-24 months; n: 2751; N: 7383; 37.3; US + AFP: 25-36 months; n: 1666; N: 3853; 43.2%; No screening: NA; n: 16069; N: 31282; 51.4% | 7-12 months vs ≤6 months HR (95% CI) 0.91 (0.87, 0.96)^a^; HR (95% CI) 0.91; (0.86, 0.95)^b^; 13-24 months vs ≤6 months HR (95% CI) 1.01 (0.97, 1.06)^a^; HR (95% CI) 1.01 (0.96, 1.06)^b^; 25-36 months vs ≤6 months HR (95% CI) 1.08 (1.02, 1.14)^a^; HR (95% CI) 1.07 (1.01, 1.13)^b^; No screening vs ≤6 months HR (95% CI) 1.28 (1.24, 1.32)^a^; HR (95% CI) 1.27 (1.23, 1.31)^b^; ^a^lead time=157 days; ^b^lead time=174 days
Kim, 2018^29^; Serious; 5 years | US +/- AFP: mean of < or = to 8 months for at least 2 years; n: NR; N: NR; % NR | US +/- AFP: Irregular; n: NR; N: NR; % NR | None: NA; n: NR; N: NR; % NR | Irregular vs none HR (95% CI) 0.94 (0.69, 1.28); Mean ≤8 months for at least 2 years vs none HR (95% CI) 0.69 (0.57, 0.83); Lead time=140 days
Mittal, 2016^30^; Serious; Follow-up NR | US/MRI/CT +/- AFP: ≥1 imaging test in 2 years prior to HCC diagnosis; n: NR; N: NR; % NR | None: NA; n: NR; N: NR; % NR | - | Surveillance vs none HR (95% CI) 0.77 (0.67, 0.90), adjusting for HCC stage and treatment; Lead time=100 days
Pelizzaro, 2022^31^; Serious; 5 years | US: 3±1 months; n: 69; N: 109; 63.3% | US: 6±1 months; n: 373; N: 668; 55.8% | - | 3±1 months vs 6±1 months HR (95% CI) 0.93 (0.65, 1.32); Lead time=85 days
Piñero, 2019^32^; Serious; 5 years | US: Every 6 months during last year of follow-up until HCC diagnosis; n: NR; N: 345; 27% | None: NA; n: NR; N: 208; 36.4% | - | Every 6 months during last year of follow-up until HCC diagnosis vs none HR (95% CI) 0.51 (0.38, 0.69); Lead time=3.5 months
Thein, 2015^34^; Serious; 5 years | US: Routine surveillance (≥1 imaging annually); n: NR; N: NR; % NR | US: Inconsistent screening; n: NR; N: NR; % NR | None: NA; n: NR; N: NR; % NR | Routine surveillance vs none HR (95% CI) 0.76 (0.64, 0.91); Inconsistent screening vs none HR (95% CI) 0.86 (0.75, 0.98); Lead time=70 days
Wu, 2016^37^; Serious; 5 years | US: 1-6 months; n: 14626; N: 19115; 76.5% | US: 7-12 months; n: 3740; N: 4837; 77.3% | US: 13-24 months; n: 3799; N: 4795; 79.2%; US: 25-36 months; n: 2418; N: 2957; 81.8%; No screening: never/not in last 3 years; n: 17883; N: 21119; 84.7% | 7-12 months vs 1-6 months HR (95% CI): 1.11 (1.07, 1.15); 12-25 months vs 1-6 months HR (95% CI): 1.23 (1.19, 1.28); 25-35 months vs 1-6 months HR (95% CI): 1.31 (1.26, 1.37); No screening vs 1-6 months HR (95% CI): 1.47 (1.43, 1.51); Lead time=140 days

Abbreviations. AFP=alpha-fetoprotein; CI=confidence interval; CT=computed tomography; HCC=hepatocellular carcinoma; HR=hazard ratio; MRI=magnetic resonance imaging; NA=not applicable; NR=not reported; US=ultrasound.

Appendix Table 12 Results for Overall Survival for HCC Cohort Studies

Author, Year; Risk of Bias; Follow-Up | Arm A Intervention; Events (n); Total (N); (%) | Arm B Intervention; Events (n); Total (N); (%) | Arm C Intervention; Events (n); Total (N); (%) | Results
An, 2020^27^; Serious; 5 years | AFP: biannually; n: NR; N: NR; 64.8% | US: biannually; n: NR; N: NR; 69.9% | US + AFP: biannually; n: NR; N: NR; 55.5% | -
Kim, 2018^29^; Serious; 5 years | US +/- AFP: Regular screening (mean interval ≤8 months); n: NR; N: NR; 64.4% | US +/- AFP: Irregular screenig; n: NR; N: NR; 52.7% | None: NA; n: NR; N: NR; 25.3% | Regular screening vs irregular screening; HR (95% CI) 0.77 (0.64, 0.93); With lead time=140 days
Pelizzaro, 2022^31^; Serious; 5 years | US: 3±1 months; n: NR; N: 109; 40.7% | US: 6±1 months; n: NR; N: 668; 47.2% | - | US: 3±1 months vs US: 6±1 months; HR (95% CI) 0.87 (0.67, 1.13) with lead time=63 days
Tanaka, 2006^33^; Serious; 5 years | US + AFP: 6 months; n: 46; N: 182; 25.2% | None: NA; n: 32; N: 202; 15.8% | - | US + AFP vs none; RR: 0.63 (95% CI 0.48-0.82); Lead time adjusted results NR
Thein, 2015^34^; Serious; 5 years | US: Routine surveillance (≥1 imaging annually); n: NR; N: NR; 31.9% (95% CI: 25.8, 38.2) | US: Inconsistent screening; n: NR; N: NR; 22.4% (95% CI: 18.7, 26.3) | None: NA; n: NR; N: NR; 20.7% (95% CI: 16.9, 24.7) | -
Tong, 2017^35^; Serious; 5 years | US + AFP: 6-12 months; n: NR; N: NR; 37.5% | None: NA; n: NR; N: NR; 14.2% (p<0.001) | - | -
Trevisani, 2004^36^; Serious; Median 17 months | US + AFP: 6-12 months; NR | None (Incidentally detected HCC); NR | None (Symptom-detected HCC); NR | Unable to extract; authors provided figure but no in-text numbers

Abbreviations. AFP=alpha-fetoprotein; CI=confidence interval; CT=computed tomography; HCC=hepatocellular carcinoma; HR=hazard ratio; NA=not applicable; NR=not reported; US=ultrasound.

Appendix Table 13 Results for HCC-Specific Mortality for HCC Cohort Studies

Author, Year; Risk of Bias; Follow-Up | Arm A Intervention; Events (n); Total (N); (%) | Arm B Intervention; Events (n); Total (N); (%) | Arm C, D, E Intervention; Events (n); Total (N); (%) | Results
An, 2020^27^; Serious; 5 years | AFP: biannually; n: 63; N: 298; 20.1% | US: biannually; n: 162; N: 978; 16.6% | US + AFP: biannually; n: 148; N: 500; 29.6% | AFP vs US + AFP; HR (95% CI); 0.67 (0.50, 0.90) with lead time=120 days; Ultrasound vs US + AFP; HR (95% CI) 0.46 (0.37, 0.58) p<0.001*not adjusted for lead time
Pelizzaro, 2022^31^; Serious; 5 years | US: 3±1 months; n: NR; N: NR; 66.7% | US: 6±1 months; n: NR; N: NR; 57.4% | - | NR

Abbreviations. AFP=alpha-fetoprotein; CI=confidence interval; HCC=hepatocellular carcinoma; HR=hazard ratio; US=ultrasound.

Appendix Table 14 Results for HCC Stage at Diagnosis for HCC Cohort Studies

Author, Year; Risk of Bias; Follow-Up | Arm A Intervention; Events (n); Total (N); (%) | Arm B Intervention; Events (n); Total (N); (%) | Arm C Intervention; Events (n); Total (N); (%)
Kim, 2018^29^; Serious; 5 years | US +/- AFP: Regular screening (mean interval ≤8 months); BCLC Stage 0-A-B; n: 578; N: 834; % 69.3%; BCLC Stage C-D; n: 256; N: 834; 30.7% | US +/- AFP: Irregular; BCLC Stage; 0-A-B; n: 53; N: 104; % 51.0%; BCLC Stage; C-D; n: 51; N: 104; 49.0% | None: NA; BCLC Stage; 0-A-B; n: 187; N: 464; % 40.3%; BCLC Stage C-D; n: 277; N: 464; 59.7%
Piñero, 2019^32^; Serious; 5 years | US: Every 6 months during last year of follow-up until HCC diagnosis; BCLC Stage 0-A-B; n: 322; N: 345; 93.3%; BCLC Stage C-D; n: 23; N: 345; 6.7% | None: NA; BCLC Stage; 0-A-B; n: NR; N: NR; % NR; BCLC Stage C-D; n: NR; N: NR; % NR | -
Mittal, 2016^30^; Serious; Follow-up NR | US/MRI/CT +/- AFP: ≥1 imaging test in 2 years before HCC diagnosis; BCLC Stage 0-A-B; n: 206; N: 412; 50.0%; BCLC Stage C-D; n: 171; N: 412; 41.5% | None: NA; BCLC Stage; 0-A-B; n: 160; N: 475; 33.7%; BCLC Stage C-D; n: 283; N: 475; 59.8% | -
An, 2020^27^; Serious; 5 years | AFP: biannually; BCLC Stage 0-A-B; n: 267; N: 298; 89.6%; BCLC Stage C-D; n: 31; N: 298; 10.4% | US: biannually; BCLC Stage; 0-A-B; n: 911; N: 978; 93.1%; BCLC Stage C-D; n: 67; N: 978; 6.9% | US + AFP: biannually; BCLC Stage; 0-A-B; n: 430; N: 500; 86.0%; BCLC Stage C-D; n: 70; N: 500; 14.0%

Abbreviations. AFP=alpha-fetoprotein; BCLC=Barcelona Clinic Liver Cancer; CT=computed tomography; HCC=hepatocellular carcinoma; HR=hazard ratio; MRI=magnetic resonance imaging; US=ultrasound.

Appendix Table 15 Results for Diagnosis Using Biopsy for HCC Cohort Studies

Author, Year; Risk of Bias; Follow-Up | Arm A Intervention; Events (n); Total (N); (%) | Arm B Intervention; Events (n); Total (N); (%) | Arm C Intervention; Events (n); Total (N); (%) | Arm D Intervention; Events (n); Total (N); (%) | Arm E Intervention; Events (n); Total (N); (%)
An, 2020^27^; Serious; 5 years | AFP: biannually; n: 140; N: 298; 46.9% | US: biannually; n: 450; N: 978; 46.0% | US + AFP: biannually; n: 232; N: 500; 46.4% | - | -
Wu, 2016^37^; Serious; 5 years | US: 1-6 months; n: 9256; N: 19115; 48.4% | US: 7-12 months; n: 2503; N: 4837; 51.8% | US: 13-24 months; n: 2333; N: 4795; 48.6% | US: 25-36 months; n: 1434; N: 2957; 48.5% | No screening: never/not in last 3 years; n: 9710; N: 21119; 46.0%

Abbreviations. AFP=alpha-fetoprotein; HCC=hepatocellular carcinoma; RoB=risk of bias; US=ultrasound.

Appendix Table 16 Results for Receiving Curative Treatment for HCC Cohort Studies

Author, Year; Risk of Bias; Follow-Up | Arm A Intervention; Events (n); Total (N); (%) | Arm B Intervention; Events (n); Total (N); (%) | Arm C Intervention; Events (n); Total (N); (%) | Arm D Intervention; Events (n); Total (N); (%) | Arm E Intervention; Events (n); Total (N); (%)
An, 2020^27^; Serious; 5 years | AFP: biannually; n: NR; N: NR; 60.1% | US: biannually; n: NR; N: NR; 63.1% | US + AFP: biannually; n: NR; N: NR; 56.4% | - | -
Bae, 2021^28^; Serious; 8 years | US + AFP: 6 months or fewer; n: 8095; N: 15587; 51.9% | US + AFP: 7-12 months; n: 3176; N: 6559; 48.3% | US + AFP: 13-24 months; n: 3236; N: 7383; 43.8% | US + AFP: 25-36 months; n: 1591; N: 3853; 41.3% | No screening: NA; n: 10787; N: 31282; 34.5%
Kim, 2018^29^; Serious; 5 years | US +/- AFP: Regular screening (mean interval ≤8 months); n: 437; N: 834; 52.4% | US +/- AFP: Irregular; n: 41; N: 104; 39.4% | None: NA; n: 108; N: 464; 23.3% | - | -
Mittal, 2016^30^; Serious; Follow-up NR | US/MRI/CT +/-AFP: ≥1 imaging test in 2 years prior to HCC diagnosis; n: 86; N: 412; 20.8% | None: NA; n: 53; N: 475; 11.2% | - | - | -
Pelizzaro, 2022^31^; Serious; 5 years | US: 3±1 months; n: 76; N: 109; 69.7% | US: 6±1 months; n: 456; N: 668; 68.2%; Compared to 3 months, OR (95% CI) 0.93 (0.60, 1.45) p=0.76 | - | - | -
Thein, 2015^34^; Serious; 5 years | US: Routine surveillance (≥1 imaging annually); n: NR; n: NR; 59.3% | US: Inconsistent screening; n: NR; n: NR 45.6% p<0.001 vs routine surveillance | None: NA; n: NR; n: NR; 43.1%; p<0.001 vs routine surveillance | - | -
Tong, 2017^35^; Serious; 5 years | US + AFP: 6-12 months; n: 106; N: 175; 60.1% | None: NA; n: 42; N: 158; 26.6% | - | - | -
Wu, 2016^37^; Serious; 5 years | US: 1-6 months; n: 5613; N: 19115; 29.4% | US: 7-12 months; n: 1472; N: 4837; 30.4% | US: 13-24 months; n: 1211; N: 4795; 25.3% | US: 25-36 months; n: 694; N: 2957; 23.5% | No screening: never/not in last 3 years; n: 4195; N: 21119; 19.7%

Abbreviations. AFP=alpha-fetoprotein; CI=confidence interval; CT=computed tomography; HCC=hepatocellular carcinoma; MRI=magnetic resonance imaging; NA=not applicable; OR=odds ratio; RoB=risk of bias; US=ultrasound.

Appendix Table 17 Results for Receiving Liver Transplant for HCC Cohort Studies

Author, Year; Risk of Bias; Follow-Up | Arm A Intervention; Events (n); Total (N); (%) | Arm B Intervention; Events (n); Total (N); (%) | Arm C Intervention; Events (n); Total (N); (%)
An, 2020^27^; Serious; 5 years | AFP: biannually; n: 15; N: 298; 5.0% | US: biannually; n: 22; N: 978; 2.3% | US + AFP: biannually; n: 10; N: 500; 2.0%
Mittal, 2016^30^; Serious; Follow-up NR | US/MRI/CT +/- AFP:; ≥1 imaging test in 2 years before HCC diagnosis; n: 15; N: 412; 3.6% | None: NA; n: 18; N: 475; 3.8% | -
Pelizzaro, 2022^31^; Serious; 5 years | US: 3±1 months; n: 11; N: 109; 10.1% | US: 6±1 months; n: 32; N: 668; 0.5% | -
Tong, 2017^35^; Serious; 5 years | US + AFP: 6-12 months; n: 38; N: 175; 21.7% | None: NA; n: 9; n: 158; 5.7% | -

Abbreviations. AFP=alpha-fetoprotein; CT=computed tomography; HCC=hepatocellular carcinoma; MRI=magnetic resonance imaging; NA=not applicable; US=ultrasound.

Appendix Table 18 Results for Financial Burden for HCC Cohort Studies

Author, Year; Risk of Bias; Follow-Up | Arm A Intervention; Events (n); Total (N); (%) | Arm B Intervention; Events (n); Total (N); (%)
Pelizzaro, 2022^31^; Serious; 5 years | US: 3±1 months; Arm overall cost: €316,645; cost for a patient tested quarterly: €2,905 | US: 6±1 months; Arm overall cost €1,217,764; cost for a patient tested twice a year €1,823

Abbreviations. US=ultrasound.