# ABBREVIATIONS TABLE

Abbreviation: Definition
AASLD: American Association for the Study of Liver Diseases
AFP: Alpha-fetoprotein
ALD: Alcohol-associated liver disease
ALT: Alanine transaminase
AST: Aspartate transaminase
BCLC: Barcelona Clinic Liver Cancer
BMI: Body mass index
CCRCT: Cochrane Central Register of Controlled Trials
CI: Confidence interval
COE: Certainty of evidence
CT: Computed tomography
EASL: European Association for the Study of the Liver
EMR: Electronic medical records
ESP: Evidence Synthesis Program
GRADE: Grading of Recommendations, Assessment, Development, and Evaluation
HCC: Hepatocellular carcinoma
HR: Hazard ratio
MASLD: Metabolic dysfunction-associated steatotic liver disease
aMRI: Abbreviated MRI
MRI: Magnetic resonance imaging
NGHP: National Gastroenterology and Hepatology Program
OR: Odds ratio
RCT: Randomized controlled trial
RoB: Risk of bias
ROBINS-I: Risk of Bias in non-Randomized Studies
RR: Risk ratio
US: Ultrasound
VHA: Veterans Health Administration