# REFERENCES

1 Anonymous. Gulf War and Health: Volume 10: Update of Health Effects of Serving in the Gulf War, 2016. Mil Med. 2017;182(3):1507–1508.28290920
2 Bourdette DN, McCauley LA, Barkhuizen A, . Symptom factor analysis, clinical findings, and functional status in a population-based case control study of Gulf War unexplained illness. J Occup Environ Med. 2001;43(12):1026–1040.11765674
3 Fukuda K, Nisenbaum R, Stewart G, . Chronic multisymptom illness affecting Air Force veterans of the Gulf War. JAMA. 1998;280(11):981–988.9749480
4 Haley RW, Kurt TL, Hom J. Is there a Gulf War Syndrome? Searching for syndromes by factor analysis of symptoms. JAMA. 1997;277(3):215–222.9005271
5 Kang HK, Li B, Mahan CM, Eisen SA, Engel CC. Health of US veterans of 1991 Gulf War: a follow-up survey in 10 years. J Occup Environ Med. 2009;51(4):401–410.19322107
6 Spencer PS, McCauley LA, Joos SK, . U.S. Gulf War Veterans: service periods in theater, differential exposures, and persistent unexplained illness. Portland Environmental Hazards Research Centre. Toxicol Lett. 1998;102–103:515–521.
7 Steele L. Prevalence and patterns of Gulf War illness in Kansas veterans: association of symptoms with characteristics of person, place, and time of military service. Am J Epidemiol. 2000;152(10):992–1002.11092441
8 Institute of Medicine. Chronic Multisymptom Illness in Gulf War Veterans: Case Definitions Reexamined. National Academies Press (US) 2014;03(12).
9 US Department of Veterans Affairs. Gulf War Veterans’ Medically Unexplained Illnesses. Military Exposures Web site. https://www.publichealth.va.gov/exposures/gulfwar/medically-unexplained-illness.asp. Accessed February 5, 2020.
10 Abou-Donia MB, Conboy LA, Kokkotou E, . Screening for novel central nervous system biomarkers in veterans with Gulf War Illness. Neurotoxicol Teratol. 2017;61:36–46.28286177
11 Steele L, Sastre A, Gerkovich MM, Cook MR. Complex factors in the etiology of Gulf War illness: wartime exposures and risk factors in veteran subgroups. Environ Health Perspect. 2012;120(1):112–118.21930452
12 Koslik HJ, Hamilton G, Golomb BA. Mitochondrial dysfunction in Gulf War illness revealed by 31Phosphorus Magnetic Resonance Spectroscopy: a case-control study. PLoS ONE [Electronic Resource]. 2014;9(3):e92887.
13 Golomb BA. Acetylcholinesterase inhibitors and Gulf War illnesses. Proc Natl Acad Sci U S A. 2008;105(11):4295–4300.18332428
14 Mawson AR, Croft AM. Gulf War Illness: Unifying Hypothesis for a Continuing Health Problem. International Journal of Environmental Research & Public Health [Electronic Resource]. 2019;16(1):03.
15 Kodali M, Hattiangady B, Shetty GA, Bates A, Shuai B, Shetty AK. Curcumin treatment leads to better cognitive and mood function in a model of Gulf War Illness with enhanced neurogenesis, and alleviation of inflammation and mitochondrial dysfunction in the hippocampus. Brain Behav Immun. 2018;69:499–514.29454881
16 Fall DJ, Stessman H, Patel SS, . Utilization of Translational Bioinformatics to Identify Novel Biomarkers of Bortezomib Resistance in Multiple Myeloma. J Cancer. 2014;5(9):720–727.25368671
17 McGowan J, Sampson M, Salzwedel DM, Cogo E, Foerster V, Lefebvre C. PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. J Clin Epidemiol. 2016;75:40–46.27005575
18 Hackshaw A. Small studies: strengths and limitations. Eur Respir J. 2008;32(5):1141–1143.18978131
19 Whiting PF, Rutjes AW, Westwood ME, . QUADAS-2: a revised tool for the quality assessment of diagnostic accuracy studies. Ann Intern Med. 2011;155(8):529–536.22007046
20 Wirsching J, Graßmann S, Eichelmann F, . Development and reliability assessment of a new quality appraisal tool for cross-sectional studies using biomarker data (BIOCROSS). BMC Med Res Methodol. 2018;18(1):122.30400827
21 Haines DD, Ottenweller JE, Dickens BF, Mahmoud FF, Levine PH. Activity of Paraoxonase/Arylesterase and Butyrylcholinesterase in Peripheral Blood of Gulf War Era Veterans With Neurologic Symptom Complexes or Post-Traumatic Stress Disorder. J Occup Environ Med. 2017;59(10):1000–1006.28991135
22 Lo SC, Levin L, Ribas J, . Lack of serological evidence for Mycoplasma fermentans infection in army Gulf War veterans: a large scale case-control study. Epidemiol Infect. 2000;125(3):609–616.11218212
23 Asa PB, Cao Y, Garry RF. Antibodies to squalene in Gulf War syndrome. Exp Mol Pathol. 2000;68(1):55–64.10640454
24 Emmerich T, Zakirova Z, Klimas N, . Phospholipid profiling of plasma from GW veterans and rodent models to identify potential biomarkers of Gulf War Illness. PLoS ONE [Electronic Resource]. 2017;12(4):e0176634.
25 Georgopoulos AP, James LM, Mahan MY, Joseph J, Georgopoulos A, Engdahl BE. Reduced Human Leukocyte Antigen (HLA) Protection in Gulf War Illness (GWI). EBioMedicine. 2016;3:79–85.26870819
26 Johnson GJ, Leis LA, Slater BC, Bach RR. Elevated platelet count, C-reactive protein and thromboxane analog-induced platelet aggregation in patients with Gulf War veterans’ illnesses: evidence of a chronic inflammatory state? Blood Coagul Fibrinolysis. 2013;24(7):736–741.23751609
27 James LM, Engdahl BE, Leuthold AC, Georgopoulos AP. Brain Correlates of Human Leukocyte Antigen (HLA) Protection in Gulf War Illness (GWI). EBioMedicine. 2016;13:72–79.27765642
28 Butterick TA, Trembley JH, Hocum Stone LL, Muller CJ, Rudquist RR, Bach RR. Gulf War Illness-associated increases in blood levels of interleukin 6 and C-reactive protein: biomarker evidence of inflammation. BMC Res Notes. 2019;12(1):816.31852524
29 Johnson GJ, Slater BC, Leis LA, Rector TS, Bach RR. Blood Biomarkers of Chronic Inflammation in Gulf War Illness. PLoS ONE [Electronic Resource]. 2016;11(6):e0157855.
30 Phillips CJ, Matyas GR, Hansen CJ, Alving CR, Smith TC, Ryan MA. Antibodies to squalene in US Navy Persian Gulf War veterans with chronic multisymptom illness. Vaccine. 2009;27(29):3921–3926.19379786
31 Skowera A, Hotopf M, Sawicka E, . Cellular immune activation in Gulf War veterans. J Clin Immunol. 2004;24(1):66–73.14997036
32 Calley CS, Kraut MA, Spence JS, Briggs RW, Haley RW, Hart J, Jr. The neuroanatomic correlates of semantic memory deficits in patients with Gulf War illnesses: a pilot study. Brain Imaging Behav. 2010;4(3–4):248–255.20824394
33 Cooper CM, Briggs RW, Farris EA, Bartlett J, Haley RW, Odegard TN. Memory and functional brain differences in a national sample of U.S. veterans with Gulf War Illness. Psychiatry Research: Neuroimaging. 2016;250:33–41.27017423
34 Gopinath K, Gandhi P, Goyal A, . FMRI reveals abnormal central processing of sensory and pain stimuli in ill Gulf War veterans. Neurotoxicology. 2012;33(3):261–271.22327017
35 Liu P, Aslan S, Li X, . Perfusion deficit to cholinergic challenge in veterans with Gulf War Illness. Neurotoxicology. 2011;32(2):242–246.21147163
36 Odegard TN, Cooper CM, Farris EA, Arduengo J, Bartlett J, Haley R. Memory impairment exhibited by veterans with Gulf War Illness. Neurocase. 2013;19(4):316–327.22519425
37 Tillman GD, Green TA, Ferree TC, . Impaired response inhibition in ill Gulf War veterans. J Neurol Sci. 2010;297(1–2):1–5.20719339
38 Tillman GD, Calley CS, Green TA, . Event-related potential patterns associated with hyperarousal in Gulf War illness syndrome groups. Neurotoxicology. 2012;33(5):1096–1105.22691951
39 Tillman GD, Calley CS, Green TA, . Visual event-related potentials as markers of hyperarousal in Gulf War illness: evidence against a stress-related etiology. Psychiatry Res. 2013;211(3):257–267.23149040
40 Tillman GD, Spence JS, Briggs RW, Haley RW, Hart J, Jr., Kraut MA. Gulf War illness associated with abnormal auditory P1 event-related potential: Evidence of impaired cholinergic processing replicated in a national sample. Psychiatry Research: Neuroimaging. 2019;283:7–15.30453127
41 Weiner MW, Meyerhoff DJ, Neylan TC, . The relationship between Gulf War illness, brain N-acetylaspartate, and post-traumatic stress disorder. Mil Med. 2011;176(8):896–902.21882779
42 Blanchard M, Molina-Vicenty HD, Stein PK, . Medical Correlates of Chronic Multisymptom Illness in Gulf War Veterans. Am J Med. 2019;132(4):510–518.30576630
43 Davis SD, Kator SF, Wonnett JA, Pappas BL, Sall JL. Neurally mediated hypotension in fatigued Gulf War veterans: a preliminary report. Am J Med Sci. 2000;319(2):89–95.10698092
44 Haley RW, Charuvastra E, Shell WE, . Cholinergic autonomic dysfunction in veterans with Gulf War illness: confirmation in a population-based sample. JAMA Neurology. 2013;70(2):191–200.23407784
45 Li M, Xu C, Yao W, . Self-reported post-exertional fatigue in Gulf War veterans: roles of autonomic testing. Front Neurosci. 2014;7:269.24431987
46 Nagelkirk PR, Cook DB, Peckerman A, . Aerobic capacity of Gulf War veterans with chronic fatigue syndrome. Mil Med. 2003;168(9):750–755.14529252
47 Hotopf M, Mackness MI, Nikolaou V, . Paraoxonase in Persian Gulf War veterans. J Occup Environ Med. 2003;45(7):668–675.12855907
48 Amin MM, Belisova Z, Hossain S, Gold MS, Broderick JE, Gold AR. Inspiratory airflow dynamics during sleep in veterans with Gulf War illness: a controlled study. Sleep & Breathing. 2011;15(3):333–339.20703820
49 Roland PS, Haley RW, Yellin W, Owens K, Shoup AG. Vestibular dysfunction in Gulf War syndrome. Otolaryngology - Head & Neck Surgery. 2000;122(3):319–329.10699803
50 Sharief MK, Priddin J, Delamont RS, . Neurophysiologic analysis of neuromuscular symptoms in UK Gulf War veterans: a controlled study. Neurology. 2002;59(10):1518–1525.12451190
51 Wallace HL, 2nd, Natelson B, Gause W, Hay J. Human herpesviruses in chronic fatigue syndrome. Clin Diagn Lab Immunol. 1999;6(2):216–223.10066657
52 Zhou Q, Verne ML, Zhang B, Verne GN. Evidence for Somatic Hypersensitivity in Veterans With Gulf War Illness and Gastrointestinal Symptoms. Clin J Pain. 2018;34(10):944–949.29570102
53 Peskind ER, Petrie EC. Multimodal Biological Assessment of Gulf War Illness. https://projectreporter.nih.gov/project_info_description.cfm?aid=9278098&icde=0. Published 2014. Accessed 8 May 2020.
54 Defining and Characterizing GWI Pathobiology Using Longitudinal Brain Imaging Biomarkers of White Matter Integrity and Hemodynamic Response. https://cdmrp.army.mil/search.aspx?LOG_NO=GW180099. Accessed 6 May 2020.
55 Little DM. Assessment of MRI-Based Marker of Dopaminergic Integrity as a Biological Indicator of Gulf War Illness. Temple, TX: Scott and White Memorial Hospital; October 2016.
56 Clarifying the Role Played by Microglia and Astrocyte Activation in Veterans with Gulf War Illness Using Positron Emission Tomography (PET). https://cdmrp.army.mil/search.aspx?LOG_NO=GW180103. Accessed 6 May 2020.
57 Assessing Neuroinflammation in Gulf War Illness with Whole-Brain Magnetic Resonance Spectroscopy. https://cdmrp.army.mil/search.aspx?LOG_NO=GW180071. Accessed 6 May 2020.
58 An Objective Blood Test from Stimulated Gene Expression for Classification and Outcome Assessment in Clinical Trials of Gulf War Illness. https://cdmrp.army.mil/search.aspx?LOG_NO=GW140158. Accessed 8 May 2020.
59 US Department of Veterans Affairs. CSP #2006: Genomics of Gulf War Illness in Veterans. https://www.vacsp.research.va.gov/CSPEC/Studies/INVESTD-R/CSP-2006-Genomics-Gulf-War-Illness.asp. Published 2018. Accessed 26 June 2020.
60 Identification of Epigenetic Signatures as Biomarkers of Gulf War Illness. https://cdmrp.army.mil/search.aspx?LOG_NO=GW160096. Accessed 6 May 2020.
61 Identifying Objective Diagnostic Markers of Gulf War Illness: Salivary and Plasma Autoantibodies Against Neural Proteins Validated with Brain Imaging. https://cdmrp.army.mil/search.aspx?LOG_NO=GW180121. Accessed 8 May 2020.
62 James LM. Human Leukocyte Antigen in Gulf War Veterans: Association with Symptoms and Inflammatory Markers. October 2018.
63 Research SFVAFf, Education. Glutathione vs Curcumin Clinical Trial. In:2016.
64 Next-Generation Biomarkers of Gulf War Illness https://cdmrp.army.mil/search.aspx?LOG_NO=GW160161. Accessed 6 May 2020.
65 Biomarkers and Brain Mechanisms of Gulf War Illness. https://cdmrp.army.mil/search.aspx?LOG_NO=GW140114. Accessed 8 May 2020.
66 Autonomic Dysfunction, Brain Blood Flow, and Cognitive Decline in Veterans with Gulf War Illness. https://cdmrp.army.mil/search.aspx?LOG_NO=GW180103. Accessed 6 May 2020.
67 Mitochondrial Dysfunction and Gulf War Illness. https://cdmrp.army.mil/search.aspx?LOG_NO=GW150184. Accessed 8 May 2020.
68 Muscle Mitochondrial Assessments in Gulf War Illness. https://cdmrp.army.mil/search.aspx?LOG_NO=GW140045. Accessed 8 May 2020.
69 NCT03082638. Identification of Gulf War Illness (GWI) Biomarkers. In. Roskamp Institute I, United States Department of D, trans2017.
70 Keating JA, Shaughnessy C, Baubie K, . Characterising the gut microbiome in veterans with Gulf War Illness: a protocol for a longitudinal, prospective cohort study. BMJ Open. 2019;9(8):e031114.
71 Small Intestinal Microbial Community in Gulf War Illness. https://cdmrp.army.mil/search.aspx?LOG_NO=GW080151. Accessed 8 May 2020.
72 GWI: Molecular Analysis of Disease Endophenotypes and Response to Acupuncture Treatment https://cdmrp.army.mil/search.aspx?LOG_NO=GW150202. Accessed 27 May 2020.
73 Metabolomics in Gulf War Illness: A Systems Biology Approach to Dissecting Mechanisms of Disease. https://cdmrp.army.mil/search.aspx?LOG_NO=GW180150. Accessed 8 May 2020.
74 Biomarker Discovery in Gulf War Veterans: Development of a War Illness Diagnostic Panel. https://cdmrp.army.mil/search.aspx?LOG_NO=GW110078. Accessed 8 May 2020.
75 Steele L. Assessment of Diverse Biological Indicators in Gulf War Illness: Are They Replicable? Are They Related? Waco, TX: Baylor University; October 2012.
76 XMRV and GWI: Is There an Association? https://cdmrp.army.mil/search.aspx?LOG_NO=GW100007. Accessed 8 May 2020.
77 US Department of Veterans Affairs. VA Cooperative Studies Program 585: Information for Veterans. https://www.vacsp.research.va.gov/CSP_585/CSP_585_Information_for_Veterans.asp. Accessed 28 August 2020.
78 Chester JE, Rowneki M, Van Doren W, Helmer DA. Progression of intervention-focused research for Gulf War illness. Mil Med Res. 2019;6(1):31.31627737
79 Gulf War Illness Research Program. The Gulf War Illness Landscape. March 2020.
80 Chedekel L. Identifying Biomarkers of Gulf War Illness. Boston University School of Public Health,. https://www.bu.edu/sph/2017/03/29/identifying-biomarkers-of-gulf-war-illness/. Published 2017. Accessed 29 June 2020.
81 Koo B-B. Computer aided decoding of brain-immune interactions in Gulf War Illness (GWI): a joint embedding on brain connectomic and immunogenetic markers. 2019.
82 Measurement of Biomarkers in Samples Collected in a Coenzyme Q10 Treatment Trial in Gulf War Illness and Control Subjects. https://cdmrp.army.mil/search.aspx?LOG_NO=GW160101. Accessed 29 June 2020.
83 Abou-Donia MB, Conboy LA, Kokkotou E, . Screening for novel central nervous system biomarkers in veterans with Gulf War Illness. Neurotoxicol Teratol. 2017;61:36–46.28286177
84 Brimacombe M, Zhang Q, Lange G, Natelson B. Immunological variables mediate cognitive dysfunction in gulf war veterans but not civilians with chronic fatigue syndrome. Neuroimmunomodulation. 2002;10(2):93–100.12372983
85 Broderick G, Kreitz A, Fuite J, Fletcher MA, Vernon SD, Klimas N. A pilot study of immune network remodeling under challenge in Gulf War Illness. Brain Behav Immun. 2011;25(2):302–313.20955779
86 Broderick G, Fletcher MA, Gallagher M, Barnes Z, Vernon SD, Klimas NG. Exploring the Diagnostic Potential of Immune Biomarker Co-expression in Gulf War Illness. Methods Mol Biol. 2018;1781:101–120.29705845
87 Diaz-Torne C, Schumacher HR, Yu X, . Absence of histologic evidence of synovitis in patients with Gulf War veterans’ illness with joint pain. Arthritis Rheum. 2007;57(7):1316–1323.17907214
88 Everson MP, Shi K, Aldridge P, Bartolucci AA, Blackburn WD. Immunological responses are not abnormal in symptomatic Gulf War veterans. Ann N Y Acad Sci. 2002;966:327–342.12114290
89 Golomb BA, Koslik HJ, Christians U, . Depressed prostaglandins and leukotrienes in veterans with Gulf War illness. Journal of Environmental Science & Health - Part B: Pesticides, Food Contaminants, & Agricultural Wastes. 2019:1–17.
90 Halpin P, Williams MV, Klimas NG, Fletcher MA, Barnes Z, Ariza ME. Myalgic encephalomyelitis/chronic fatigue syndrome and gulf war illness patients exhibit increased humoral responses to the herpesviruses-encoded dUTPase: Implications in disease pathophysiology. J Med Virol. 2017;89(9):1636–1645.28303641
91 Hannan KL, Berg DE, Baumzweiger W, . Activation of the coagulation system in Gulf War Illness: a potential pathophysiologic link with chronic fatigue syndrome. A laboratory approach to diagnosis. Blood Coagul Fibrinolysis. 2000;11(7):673–678.11085289
92 Khaiboullina SF, DeMeirleir KL, Rawat S, . Cytokine expression provides clues to the pathophysiology of Gulf War illness and myalgic encephalomyelitis. Cytokine. 2015;72(1):1–8.25514671
93 Klaustermeyer WB, Kraske GK, Lee KG, Klaustermeyer WB, Kurohara ML. Allergic and immunologic profile of symptomatic Persian Gulf War veterans. Ann Allergy Asthma Immunol. 1998;80(3):269–273.9532977
94 O’Bryan TA, Romano PJ, Zangwill BC. Human leukocyte antigens in Gulf War veterans with chronic unexplained multiple symptoms. Mil Med. 2003;168(12):1015–1018.14719628
95 Parkitny L, Middleton S, Baker K, Younger J. Evidence for abnormal cytokine expression in Gulf War Illness: A preliminary analysis of daily immune monitoring data. BMC Immunol. 2015;16:57.26420016
96 Skowera A, Stewart E, Davis ET, . Antinuclear autoantibodies (ANA) in Gulf War-related illness and chronic fatigue syndrome (CFS) patients. Clin Exp Immunol. 2002;129(2):354–358.12165094
97 Smylie AL, Broderick G, Fernandes H, . A comparison of sex-specific immune signatures in Gulf War illness and chronic fatigue syndrome. BMC Immunol. 2013;14:29.23800166
98 Tsilibary EC, Souto EP, James LM, Engdahl BE, Georgopoulos AP. Human Immunoglobulin G (IgG) Neutralizes Adverse Effects of Gulf War Illness (GWI) Serum in Neural Cultures: Paving the Way to Immunotherapy for GWI. Journal of Neurology & neuromedicine. 2018;3(5):23–28.31032477
99 Vojdani A, Thrasher JD. Cellular and humoral immune abnormalities in Gulf War veterans. Environ Health Perspect. 2004;112(8):840–846.15175170
100 Whistler T, Fletcher MA, Lonergan W, . Impaired immune function in Gulf War Illness. BMC Medical Genomics [Electronic Resource]. 2009;2:12.
101 Zhang Q, Zhou XD, Denny T, . Changes in immune parameters seen in Gulf War veterans but not in civilians with chronic fatigue syndrome. Clin Diagn Lab Immunol. 1999;6(1):6–13.9874656
102 Alshelh Z, Albrecht DS, Bergan C, . In-vivo imaging of neuroinflammation in veterans with Gulf War illness. Brain Behav Immun. 2020;04:04.
103 Baraniuk JN, Casado B, Maibach H, Clauw DJ, Pannell LK, Hess SS. A Chronic Fatigue Syndrome - related proteome in human cerebrospinal fluid. BMC Neurol. 2005;5:22.16321154
104 Chao LL, Mohlenhoff BS, Weiner MW, Neylan TC. Associations between subjective sleep quality and brain volume in Gulf War veterans. Sleep. 2014;37(3):445–452.24587566
105 Chao L. Do Gulf War veterans with high levels of deployment-related exposures display symptoms suggestive of Parkinson’s disease? Int J Occup Med Environ Health. 2019;32(4):503–526.31309787
106 Christova P, James LM, Engdahl BE, Lewis SM, Carpenter AF, Georgopoulos AP. Subcortical brain atrophy in Gulf War Illness. Exp Brain Res. 2017;235(9):2777–2786.28634886
107 Clarke T, Jamieson JD, Malone P, . Connectivity differences between Gulf War Illness (GWI) phenotypes during a test of attention. PLoS ONE [Electronic Resource]. 2019;14(12):e0226481.
108 Concato J, Aslan M, Palmisano MM, . Acetylcholinesterase activity in veterans of the first Gulf War. J Investig Med. 2007;55(7):360–367.
109 Engdahl BE, James LM, Miller RD, . A Magnetoencephalographic (MEG) Study of Gulf War Illness (GWI). EBioMedicine. 2016;12:127–132.27592598
110 Georgopoulos AP, James LM, Carpenter AF, Engdahl BE, Leuthold AC, Lewis SM. Gulf War illness (GWI) as a neuroimmune disease. Exp Brain Res. 2017;235(10):3217–3225.28762055
111 Gopinath KS, Sakoglu U, Crosson BA, Haley RW. Exploring brain mechanisms underlying Gulf War Illness with group ICA based analysis of fMRI resting state networks. Neurosci Lett. 2019;701:136–141.30825590
112 Haley RW, Hom J, Roland PS, . Evaluation of neurologic function in Gulf War veterans. A blinded case-control study. JAMA. 1997;277(3):223–230.9005272
113 Haley RW, Marshall WW, McDonald GG, Daugherty MA, Petty F, Fleckenstein JL. Brain abnormalities in Gulf War syndrome: evaluation with 1H MR spectroscopy. Radiology. 2000;215(3):807–817.10831703
114 Haley RW, Spence JS, Carmack PS, . Abnormal brain response to cholinergic challenge in chronic encephalopathy from the 1991 Gulf War. Psychiatry Res. 2009;171(3):207–220.19230625
115 Hubbard NA, Hutchison JL, Motes MA, . Central Executive Dysfunction and Deferred Prefrontal Processing in Veterans with Gulf War Illness. Clinical Psychological Science. 2014;2(3):319–327.25767746
116 Jamal GA, Hansen S, Apartopoulos F, Peden A. The “Gulf War syndrome”. Is there evidence of dysfunction in the nervous system? J Neurol Neurosurg Psychiatry. 1996;60(4):449–451.8774417
117 James LM, Christova P, Engdahl BE, Lewis SM, Carpenter AF, Georgopoulos AP. Human Leukocyte Antigen (HLA) and Gulf War Illness (GWI): HLA-DRB1 13:02 Spares Subcortical Atrophy in Gulf War Veterans. EBioMedicine. 2017;26:126–131.29137891
118 Li X, Spence JS, Buhner DM, . Hippocampal dysfunction in Gulf War veterans: investigation with ASL perfusion MR imaging and physostigmine challenge. Radiology. 2011;261(1):218–225.21914840
119 Menon PM, Nasrallah HA, Reeves RR, Ali JA. Hippocampal dysfunction in Gulf War Syndrome. A proton MR spectroscopy study. Brain Res. 2004;1009(1–2):189–194.15120596
120 Moffett K, Crosson B, Spence JS, . Word-finding impairment in veterans of the 1991 Persian Gulf War. Brain Cogn. 2015;98:65–73.26114921
121 Rayhan RU, Raksit MP, Timbol CR, Adewuyi O, Vanmeter JW, Baraniuk JN. Prefrontal lactate predicts exercise-induced cognitive dysfunction in Gulf War Illness. American Journal Of Translational Research. 2013;5(2):212–223.23573365
122 Rayhan RU, Stevens BW, Raksit MP, . Exercise challenge in Gulf War Illness reveals two subgroups with altered brain structure and function. PLoS ONE [Electronic Resource]. 2013;8(6):e63903.
123 Rayhan RU, Stevens BW, Timbol CR, . Increased brain white matter axial diffusivity associated with fatigue, pain and hyperalgesia in Gulf War illness. PLoS ONE [Electronic Resource]. 2013;8(3):e58493.
124 Rayhan RU, Washington SD, Garner R, . Exercise challenge alters Default Mode Network dynamics in Gulf War Illness. BMC Neurosci. 2019;20(1):7.30791869
125 Tillman GD, Calley CS, Buhl VI, . Electrophysiological correlates of semantic memory retrieval in Gulf War Syndrome 2 patients. J Neurol Sci. 2017;373:66–72.28131230
126 Turner MP, Hubbard NA, Himes LM, . Cognitive Slowing in Gulf War Illness Predicts Executive Network Hyperconnectivity: Study in a Population-Representative Sample. NeuroImage Clinical. 2016;12:535–541.27672557
127 Washington SD, Rayhan RU, Garner R, . Exercise alters cerebellar and cortical activity related to working memory in phenotypes of Gulf War Illness. Brain Communications. 2020;2(1):fcz039.32025659
128 Wylie GR, Genova H, Dobryakova E, . Fatigue in Gulf War Illness is associated with tonically high activation in the executive control network. NeuroImage Clinical. 2019;21:101641.30558870
129 Falvo MJ, Chen Y, Klein JC, Ndirangu D, Condon MR. Abnormal rheological properties of red blood cells as a potential marker of Gulf War Illness: A preliminary study. Clin Hemorheol Microcirc. 2018;68(4):361–370.29660926
130 Fiedler N, Giardino N, Natelson B, . Responses to controlled diesel vapor exposure among chemically sensitive Gulf War veterans. Psychosom Med. 2004;66(4):588–598.15272108
131 Haley RW, Vongpatanasin W, Wolfe GI, . Blunted circadian variation in autonomic regulation of sinus node function in veterans with Gulf War syndrome. Am J Med. 2004;117(7):469–478.15464703
132 Peckerman A, LaManca JJ, Smith SL, . Cardiovascular stress responses and their relation to symptoms in Gulf War veterans with fatiguing illness. Psychosom Med. 2000;62(4):509–516.10949096
133 Stein PK, Domitrovich PP, Ambrose K, . Sex effects on heart rate variability in fibromyalgia and Gulf War illness. Arthritis Rheum. 2004;51(5):700–708.15478168
134 Baraniuk JN, Shivapurkar N. Exercise-induced changes in cerebrospinal fluid miRNAs in Gulf War Illness, Chronic Fatigue Syndrome and sedentary control subjects. Sci Rep. 2017;7(1):15338.29127316
135 Craddock TJ, Harvey JM, Nathanson L, . Using gene expression signatures to identify novel treatment strategies in gulf war illness. BMC Medical Genomics [Electronic Resource]. 2015;8:36.
136 Liu G, Ye CJ, Chowdhury SK, . Detecting Chromosome Condensation Defects in Gulf War Illness Patients. Current Genomics. 2018;19(3):200–206.29606907
137 Mackness B, Durrington PN, Mackness MI. Low paraoxonase in Persian Gulf War Veterans self-reporting Gulf War Syndrome. Biochem Biophys Res Commun. 2000;276(2):729–733.11027539
138 NCT00810225. Study of Gulf War Illness (GWI) by Comparing GWI and Healthy Veterans. In. Georgetown U, Research USAM, Materiel C, trans2008.
139 Steele L, Lockridge O, Gerkovich MM, Cook MR, Sastre A. Butyrylcholinesterase genotype and enzyme activity in relation to Gulf War illness: preliminary evidence of gene-exposure interaction from a case-control study of 1991 Gulf War veterans. Environ Health. 2015;14:4.25575675
140 Trivedi MS, Abreu MM, Sarria L, . Alterations in DNA Methylation Status Associated with Gulf War Illness. DNA Cell Biol. 2019;38(6):561–571.30920300
141 Urnovitz HB, Tuite JJ, Higashida JM, Murphy WH. RNAs in the sera of Persian Gulf War veterans have segments homologous to chromosome 22q11.2. Clin Diagn Lab Immunol. 1999;6(3):330–335.10225831
142 Vladutiu GD, Natelson BH. Association of medically unexplained fatigue with ACE insertion/deletion polymorphism in Gulf War veterans. Muscle Nerve. 2004;30(1):38–43.15221876
143 Nicolson GL, Nasralla M, Nicolson NL, Haier J. High prevalence of Mycoplasma infections in symptomatic (chronic fatigue syndrome) family members of Mycoplasma-positive Gulf War Illness patients. Journal of Chronic Fatigue Syndrome. 2003;11(2):21–36.
144 Naviaux RK, Naviaux JC, Li K, . Metabolic features of Gulf War illness. PLoS ONE [Electronic Resource]. 2019;14(7):e0219531.
145 Falvo MJ, Lindheimer JB, Serrador JM. Dynamic cerebral autoregulation is impaired in Veterans with Gulf War Illness: A case-control study. PLoS ONE [Electronic Resource]. 2018;13(10):e0205393.
146 Chen Y, Meyer JN, Hill HZ, . Role of mitochondrial DNA damage and dysfunction in veterans with Gulf War Illness. PLoS ONE [Electronic Resource]. 2017;12(9):e0184832.
147 Henry C. Lin M, System NMVH. Bacterial Overgrowth Associated With Chronic Multisymptom Illness Complex. In:2009.
148 Fletcher MA, Rosenthal M, Antoni M, . Plasma neuropeptide Y: a biomarker for symptom severity in chronic fatigue syndrome. Behavioral & Brain Functions [Electronic Resource]: BBF. 2010;6:76.
149 Khan F, Kennedy G, Spence VA, Newton DJ, Belch JJ. Peripheral cholinergic function in humans with chronic fatigue syndrome, Gulf War syndrome and with illness following organophosphate exposure. Clin Sci. 2004;106(2):183–189.
150 Lindheimer JB, Cook DB, Klein-Adams JC, . Veterans with Gulf War Illness exhibit distinct respiratory patterns during maximal cardiopulmonary exercise. PLoS ONE [Electronic Resource]. 2019;14(11):e0224833.
151 Compston JE, Vedi S, Stephen AB, . Reduced bone formation in UK Gulf War veterans: a bone histomorphometric study. J Clin Pathol. 2002;55(12):897–899.12461052
152 Pessler F, Chen LX, Dai L, . A histomorphometric analysis of synovial biopsies from individuals with Gulf War Veterans’ Illness and joint pain compared to normal and osteoarthritis synovium. Clin Rheumatol. 2008;27(9):1127–1134.18414968
153 NCT00810329. Proteomics of Cerebrospinal Fluid in Chronic Fatigue Syndrome. In. Georgetown University N, National Institute of Environmental Health S, University of South A, trans2008.
154 Broderick G, Ben-Hamo R, Vashishtha S, . Altered immune pathway activity under exercise challenge in Gulf War Illness: an exploratory analysis. Brain Behav Immun. 2013;28:159–169.23201588
155 Bunegin L, Mitzel HC, Miller CS, Gelineau JF, Tolstykh GP. Cognitive performance and cerebrohemodynamics associated with the Persian Gulf Syndrome. Toxicol Ind Health. 2001;17(4):128–137.12479508
156 Haley RW, Fleckenstein JL, Marshall WW, McDonald GG, Kramer GL, Petty F. Effect of basal ganglia injury on central dopamine activity in Gulf War syndrome: correlation of proton magnetic resonance spectroscopy and plasma homovanillic acid levels. Arch Neurol. 2000;57(9):1280–1285.10987894
157 Latimer JJ, Alhamed A, Sveiven S, . Preliminary Evidence for a Hormetic Effect on DNA Nucleotide Excision Repair in Veterans with Gulf War Illness. Mil Med. 2020;185(1–2):e47–e52.31334811
158 Janulewicz PA, Seth RK, Carlson JM, . The Gut-Microbiome in Gulf War Veterans: A Preliminary Report. International Journal of Environmental Research & Public Health [Electronic Resource]. 2019;16(19):04.