# CONCLUSIONS

Gulf War Illness (GWI) is a chronic multisymptom illness comprised of a wide range of systemic symptoms and functional impairments. Hypothesized etiology includes exposure to anticholinergic agents, with suspected dysfunction in cellular energy metabolism with downstream CNS disruption related to inflammation.^78^ Thus, much of the literature focused on evaluating biomarkers along this cascade of biological processes. In the current review, we sought to evaluate existing studies validating existing diagnostic tests for GWI, and to determine whether biological measurements with promise for further establishment as biomarkers either in completed or ongoing/upcoming studies have been demonstrated. The establishment of biological measures for GWI would allow for increased accuracy in diagnosis and potential mechanisms for treatment.

Our review indicates that biological measures within the immune and central nervous systems have more often been investigated for their potential relationship with GWI, consistent with some dominant theories of disease etiology and dysfunction, but the literature also suggests other avenues of inquiry in upcoming studies, such as the gut microbiome. More importantly, our review revealed that existing studies are insufficient for determining promising biomarkers due to the extent of heterogeneity in biological measures across studies, inadequate comparator groups, and several other methodological limitations. Future studies that employ ideal control groups, reproduce findings of existing studies, and otherwise apply rigorous methodological practices and reporting specifically appropriate for investigating potential biomarkers would contribute to the establishment of a base of targeted, highly reliable studies from which lines of investigation could grow.