# DISCUSSION

This systematic review provides a broad overview of the state of biomarker research in GWI. We found no studies assessing the diagnostic accuracy of biomarkers in GWI (KQ1). We found 56 studies assessing the potential association of a broad variety of biological measures in participants with and without GWI (KQ2), and 24 ongoing or unpublished studies examining biological measures for their association with GWI (KQ3).

Most of the GWI biomarker literature to date could be characterized as “discovery” studies (see Figure 2 for biomarker discovery process diagram, and Figures 4 and 5 for summary graphs of studies by category) and were largely designed to shed light on the potential causes of GWI. Most studies fell into biological system categories that have been theorized as pathophysiologic contributors to GWI. We did not find studies assessing the relationship between biomarkers and severity of GWI illness. Studies in the discovery phase are an early step toward diagnostic test development and help identify biomarkers that are likely to be differentially expressed in participants with GWI. We categorized biological measure studies according to biological system and further identified those studies which found statistically significant associations between the biological measure and GWI (Figures 4 and 5). The vast majority of studies identified biological measures that were significantly more commonly expressed in participants with GWI. We found it challenging to identify a particular biomarker or set of biomarkers as potentially promising because nearly all of these studies were “one-off” studies where the findings have not been replicated in additional studies.

One potential way to prioritize areas of inquiry for further study would be to focus on those areas which have already been tested in populations in which there is some diagnostic uncertainty. These studies included comparator groups of deployed GWVs without GWI (either healthy individuals or those with health conditions other than GWI) and are the studies that were reviewed in the body of this report.

In Key Question 1, we searched for studies evaluating diagnostic tests for GWI. An included study would have been an evaluation of a diagnostic test’s ability to provide differential results for cases (per Kansas or CDC criteria) versus non-cases of GWI. It is not surprising that no such studies were found, because the case definition for GWI is still debated. In the absence of a gold standard definition or diagnostic test, the determination of biological measures to distinguish a case from a non-case is challenging.

For Key Question 2, the reviewed body of evidence included a range of studies examining relationships between GWI and biological measures. The range of included biological measures was wide, from indicators of immune function in serum samples, to general brain activity measured with EEG. While the biological measures tended to cluster within a few broadly-defined biological systems (eg, immune system, genetic, etc), there was significant heterogeneity among the specific biological measures within these groups. The marked variability in the types of measures that were studied, the lack of corroborating data from multiple studies, and methodological limitations of many of the included studies limit clinical application of this evidence. Instead, the current review provides (1) an overview of the range of biological measures that have been examined, and (2) a highlight of methodological limitations of current studies that may be adjusted to better position future studies to identify biological measures that distinguish cases of GWI from other conditions.

A majority of the studies we identified were focused on the immune and central nervous systems, with fewer on the autonomic nervous system and genetic markers (Figures 4). The emphasis on immune and central nervous systems is consistent with some hypotheses implicating dysfunction in these systems in GWI.^78^ The majority of the immune literature has focused on peripheral blood cytokines (4 studies), with the remainder focused on squalene antibodies (2 studies) mycoplasma fermentans antibodies (1 study), phospholipids (1 study), and human leukocyte antigen alleles (1 study). Most of the studies measuring central nervous system activation have been focused on cognitive/emotional processing, with 7 of 9 of the studies measuring general brain activation in response to cognitive/emotional tasks/stimuli. The studies examining the autonomic nervous system involved both cardiovascular and neurological measurements, with greater emphasis on cardiovascular measures. The studies measuring genetic properties both examined PON1 activity. The remaining studies measured sleep parameters, cardiorespiratory and metabolic responses to maximal exercise, audiovestibular measurements, serum enzymes, neurophysiologic parameters, and presence of viruses.

The lower priority studies (Appendix D) – those that did not include comparator groups of deployed GWI Veterans with or without other health conditions, or that had total sample sizes of <25 – were also heavily focused on the central nervous (28 studies) and immune (20 studies) systems, with several studies in each of the genetic (10 studies), autonomic nervous (5 studies), general nervous system (3 studies), energy metabolism (2 studies), gastrointestinal (2 studies) and skeletal (2 studies) systems, as well as single studies of measures within the respiratory and circulatory systems, and of various measures, biochemical pathways, and bacteria (Figure 5).

Ongoing and upcoming studies of potential associations between biological measures and GWI (Key Question 3) include an emphasis on studies of measurements in the central nervous system (5 studies^53–57^) and immune system (5 studies^61–65^), which parallels the distribution of biological systems emphasized in the reviewed completed studies. Studies of genetic (3 studies^58–60^) and ANS measures (1 study^66^) are less represented. Additional upcoming studies are diverse in their range of proposed biological measurements, with some emphasis on mitochondrial dysfunction (3 studies^67–69^) and gut microbiome (2 studies^70,71^), which were not areas represented in the completed studies we included.

Figure 4 Number of studies of GWI biological measures by biological system

Abbreviations: ANS=Autonomic Nervous System; CNS=Central Nervous System; KQ=Key Question

Figure 5 Studies of GWI biological measures with lower priority comparator group,^*^ * Priority comparator group=. See Appendix D for summary of studies in this figure. no comparator, or inadequate sample size (N<25) by biological system and promise as a biomarker

Yes=Indication by statistical significance of association of a biological measure with GWI case status; No=No indication by statistical significance of association of a biological measure with GWI case status

## LIMITATIONS

There were significant limitations in the body of evidence in regard to its applicability to the questions posed in this review, including limitations in study design, and heterogeneity in important aspects of the studies. Additionally, we limited inclusion of studies in the review based on the appropriateness of the comparator group for the purpose of identifying potential biological measures, though we tried to mitigate this limitation by providing additional details about the excluded studies (Appendix D). The text below evaluates limitations of the body of evidence.

### Study Design

The choice of comparator group was a key limitation of this evidence base. The intent behind Key Question 1 was to identify potential biological measures that identify cases of GWI, and distinguish cases from non-cases, including the distinction between GWI and conditions with overlapping symptomology (eg, CFS or depression). To establish a biological metric capable of making this distinction would require biological measures to be compared between cases versus individuals without GWI yet with other health conditions with overlapping symptomology with GWI. The ability of a biologic measure to distinguish GWI when comparing participants with symptoms to healthy participants without symptoms may not translate to its ability to distinguish GWI from another illness in participants presenting with symptoms (which is more typically the context in which a diagnostic test would be used). Therefore, the ideal comparator group to deployed GWVs with GWI would be deployed GWVs without GWI with a condition with overlapping symptoms to GWI. A promising biological measure, then, would have differential results in GWI (loosely defined here) and controls (per the ideal comparator group described above). Studies in the identified body of evidence for the current review almost exclusively employed comparator groups of healthy deployed GWV, with only 1 instance of an ill comparator among deployed GWV.^21^ While studies with this composition of comparator groups may contribute to understanding of biological differences between individuals with GWI and healthy individuals, their contribution to establishing biological measures of GWI that are clinically relevant for differential diagnostic purposes is limited.

Still, while the state of the literature may indicate limited studies with the above-described ideal specifications, other types of exploratory studies hold some value in the search for biological measure with promise for development as biomarkers. Thus, the Appendix D table that includes studies that did not include the ideal comparator, as described above, including those studies without a comparator group at all, and studies with n<25, also indicates where there are statistically significant associations of GWI with some biological measure.

In addition to inadequate control groups for the purposes of the current review specifically, there was a general lack of reporting of several features of the study design, which limits the consumer’s ability to adequately interpret study results. Many studies did not report power calculations, details regarding how or from where the samples were selected, blinding of investigators to group, recruitment non-response rate, information about the distribution of the data, or whether corrections were made when multiple comparisons were conducted. In the absence of a reported power analysis, it could not be determined whether or not the sample size included in the study was sufficient. Some studies claimed to have insufficient sample sizes but did not provide metrics behind the claim. It was also often not reported how, or from where, the sample was selected, or, in some cases when the selection criteria were reported, all participants were selected from the same battalion, limiting the representativeness of the sample. Further, non-response rate of potential participants during recruitment was also not reported, again limiting the ability to assess the representativeness of the sample.

Blinding of the assessors was also often not reported. When it was reported, it was often the investigators conducting the test who were reported as being blinded to case status and it was very rarely reported that the investigators conducting the data analyses were blinded. Also rarely reported were details of the data analysis including whether or not features of the data, such as the distribution of the data and outliers in the data, were evaluated, and what, if any, adjustments were made in the face of non-normally distributed data or the presence of outliers, for example. Further, when multiple comparisons were conducted, it was often not reported whether steps were taken to limit false positives due to chance by making corrections to statistical criteria.

Another remarkable feature of study design in the body of evidence was the use of the Haley criteria for case definition.^4^ As noted above, the Haley definition categorizes cases of GWI into 6 syndromes based on groupings of related symptoms. In the current body of evidence, the Haley criteria was primarily used in studies of the central nervous system. There were instances of the use of CDC or Kansas criteria for case definition plus stratification of syndrome types using the Haley criteria. Future studies may benefit from the addition of a similar kind of symptom-based stratification, as it is possible that different GWI syndrome types would be associated with different biological measures.

### Heterogeneity

In addition to limitations pertaining to study design, the current body of evidence was also limited for the purposes of answering our posed questions due to the heterogeneity of outcome measures, as well as case definition. While there were a few instances of repeated outcome measures – in the case of 2 instances of replication studies, for example – in general the outcome measures were heterogeneous, with only 1 study per outcome measure. Consequently, we were unable to conduct meta-analyses and were unable to otherwise draw conclusions in terms of biological metrics that might hold promise for further establishment as biological measures.

The heterogeneity of case definition in the current body of studies is expected given that the GWI diagnostic criteria is somewhat debated and there are several prevailing case definitions. Namely, a gold standard case definition has not been established and the pursuit of an identification of biological measures is intended to contribute to the development of a gold standard. Consequently, heterogeneity in case definition is expected and we were purposefully inclusive of a wide range of definitions in the current review. One consideration that arose from the current review that might contribute to more effective future studies of potential GWI biological measures is the potential use of stratified clusters of symptoms (eg, similar to Haley criteria syndromes). The application of stratified symptom groups may allow for the identification of potential biological measures that are specific to different subsets of GWI, or syndromes. It is possible that GWI itself is too heterogeneous in symptomology to be effectively categorized as 1 cohesive condition, and that stratification may help to organize the condition into more clinically relevant components.

## RESEARCH GAPS/FUTURE RESEARCH

While the review of the current body of evidence did not provide insight into promising biological measures, it did provide insight into methodological features of the studies that limit applicability to the questions posed in this review. Future studies examining biological measures of GWI would benefit from using comparator groups composed of deployed GWVs with conditions with overlapping symptomology to GWI and reporting study methods with sufficient detail, including: conducting and reporting a power analysis to determine adequate sample size; providing details regarding how or from where the samples were selected; blinding those collecting and analyzing the data as to group designation, where possible; reporting recruitment non-response rate; making adjustments for non-normally-distributed data or outliers, and reporting these methods; and potentially stratifying by syndrome sub-category. In addition, for funders of GWI biomarker research, requiring proposed projects to include funding to support the technical expertise, data management, and biostatistical assistance may help to address some of the methodological challenges of these studies. Importantly, the DoD Congressionally Directed Medical Research Program (CDMRP) has implemented a strategic funding mechanism pipeline composed of the following: 1) a discovery stage representing innovative biomarker research that is in the earliest stages of development; 2) a qualification stage representing research already supported by preliminary or published data in the GWI field that is ready for validation through expansion, replication, or comparative studies; 3) a verification stage representing clinical translation (testing in a GW Veteran population) of concepts previously replicated and validated; and 4) a confirmation stage representing large-scale confirmatory and pivotal trials that will transform and revolutionize the clinical management of GWI.^79^ This strategy will aid in the translation of the current state of biomarker research into the development of diagnostic and clinical tools.

Additionally, since the outcome measures were diverse, there was an insufficient volume of studies of any given biological measure to draw conclusions about any specific biological measure. Future studies that employ 1) appropriate control groups for GWI biological measure investigation, and 2) methodology that allows for sufficient internal and external validity, would position positive findings of GWI to biological measure associations to be built upon, thus establishing bodies of evidence for promising biological measures. Future research might also consider the complexity between using biological measures to diagnose GWI in the context of the development of other chronic health comorbidities that may impact this aging group of Veterans.

We also identified ongoing or upcoming studies related to GWI biological measures that did not meet our inclusion criteria but are likely to contribute to our knowledge. The Gulf War Illness Consortium has awarded funds to investigate a wide range of metrics: epigenetic DNA changes in Veterans with GWI; effects of exposure to cholinergic compounds; abnormalities in tau, a cytoskeletal protein; and probability scores of case qualification at the individual level using a computerized diagnostic system that incorporates multiple biological measure data.^80^ The US Army Medical Research and Development Command is also involved in studies of computer-based diagnostic system for identifying brain-immune interactions in GWI.^81^ GWI treatments are being studied simultaneously, including an upcoming trial by the Gulf War Illness Research Program (GWIRP) of an antioxidant, Coenzyme Q10 (CoQ10).^82^