# RESULTS

We reviewed a total of 2,102 titles and abstracts and identified 270 articles for review at the full-text level. We included a total of 56 studies for KQs 1-3 (Figure 3). However, we also summarized a larger group of lower-priority studies that met our inclusion criteria but did not include a priority comparator group (72 studies), and/or had total sample sizes of less than 25 (5 studies) – these studies are listed in Appendix D.

Figure 3 Literature flow chart

Abbreviations: GWI=Gulf War Illness; GWV=Gulf War Veteran; KQ=Key Question

## KEY QUESTION 1 Which diagnostic tests (or test combinations) are candidates for distinguishing individuals diagnosed with GWI from individuals without GWI?

We did not identify any studies that evaluated diagnostic tests (or test combinations) for their ability to distinguish individuals diagnosed with GWI (with CDC or Kansas criteria, or any other criteria) from individuals without GWI (Key Question 1).

In order to identify a biomarker for use as a diagnostic test for GWI, studies would first need to assess the diagnostic accuracy of a given biomarker in identifying people with GWI. In a diagnostic accuracy study, all participants would be subjected to a “gold standard” test in order to distinguish those with the disease from those without the disease. Ideally, there would be diagnostic uncertainty among all participants in a diagnostic accuracy study (ie, as opposed to a study which enrolled participants with severe symptoms and participants with no symptoms). The biomarker in question would be assessed in all participants without knowledge of the results of the “gold standard” test, and then measures of diagnostic accuracy such as sensitivity and specificity could be assessed.

## KEY QUESTION 2 Which biological measures have been examined for their potential association with GWI, and which among them have been shown to be associated with GWI?

We identified 32 studies of biological measures that have been examined for their association with GWI and grouped them broadly into categories under distinct biological systems: 10 studies of immune system biological measures; 10 central nervous system (CNS) studies; 5 studies of autonomic nervous system (ANS) biological measures; 1 of genetic biological measures; and 6 studies of biological measures in other biological systems (See Figure 4). All cases of GWI in all included studies were in participants who were Gulf War Veterans (ie, no studies including civilian contractors present in the Persian Gulf during the same time period were identified). Only 1 study^21^ included deployed GWVs with health conditions other than GWI; in all other studies, health conditions were not reported and participants were presumed healthy. Eleven studies used the CDC case definition to identify participants with GWI and 2 used the Kansas definition. Ten studies used the Haley criteria, alone or in combination with CDC criteria. The Haley criteria categorizes cases of GWI into 6 syndromes based on symptom groups, 3 of which are referenced in the included studies: impaired cognition (Syndrome 1); confusion-ataxia (Syndrome 2); and arthro-myo-neuropathy (Syndrome 3).^4^ Table 2 details the characteristics of these studies. The detailed study findings are reported according to biological system below.

Further, we identified 77 studies that used a lower-priority comparator group (that is, a comparator group other than deployed GWVs without GWI, with or without other health conditions), no comparator group, or an inadequate sample size (N<25). While not included in this main report, a summary of these studies is provided in Appendix D and Figure 5. Figure 5 indicates that most studies examined biological measures within the central nervous and immune systems, and that the majority of studies in all biological systems showed a statistically significant association of the biological measure with GWI case status.

Table 2 Characteristics of Gulf War Illness Biological Measure Studies

Study; Design; N=total participants | Biological Measure(s) Examined | Data Collection | Population; n GWI vs comparator; GWI case definition; Population/Sample source | Demographics; GWI vs comparators; Age: Mean years (SD); Female: %; Race/Ethnicity: %
IMMUNE SYSTEM
Asa, 2000 ^23^; Cross-sectional; N=50 | Squalene antibody status | Serum samples.; Anti-squalene Antibody Assay which measures the binding of serum immunoglobulin (IgG) to squalene immobilized on nitrocellulose | GWI: 38; Comparator: 12 healthy; Case def: CDC; Source: Service in the US or UK military during Persian Gulf during 1990-1991 | Age: NR; Female: NR; Race: NR
Butterick, 2019 ^28^; Cross-sectional; N=80 | IFN-γ, IL-6, IL-8, IL-10, and TNF-α and C-reactive protein | Meso Scale Discovery (MSD) plate-based electrochemiluminescence reactive protein (ECL) assay platform to quantify plasma concentrations of interferon gamma (IFN-γ), IL-1β, interleukin 2 (IL-2), interleukin 4 (IL-4), IL-6, interleukin 8 (IL-8), interleukin 10 (IL-10), interleukin 12 p70 (IL-12 p70), interleukin 13 (IL-13), and tumor necrosis factor alpha (TNF-α). | GWI: 53; Comparator: 27 healthy; Case def: CDC; Source: Parent study “Biological measures of Gulf War Veterans’ Illnesses: Tissue Factor, Chronic Coagulopathy, and Inflammation” | Age: NR; Female: NR; Race: NR
Emmerich, 2017 ^24^; Cross-sectional; N=33 | Several phospholipid species in the plasma. PC, LPC, PE, LPE and PI | lipid extracts from plasma were resuspended in isopropanol and separation was achieved using hydrophilic interaction chromatography | GWI: 22; Comparator: 11; Case def: Kansas; Source: GWI biorepository from Boston and Miami areas | Age: 48.4 (6.3) vs 48.5 (7.7); Female: 23 vs 18; Race: Caucasian 54 vs 45; Hispanic 9 vs 18; Other 5 vs 9
Georgopoulos, 2016 ^25^; Cross-sectional; N=82 | HLA alleles | DNA isolation, 3 ml of whole blood. High-resolution HLA Sequence-based Typing conducted on purified DNA. | GWI: 66; Comparator: 16 healthy; Case def: Kansas or CDC; Source: VA medical records | Age: 50.6 (7.9) vs 50.6 (7.9); Female: 3 vs 6; Race: NR
James, 2016 ^27^; Cross-sectional; N=81 | Human leukocyte antigen, brain synchronicity | High-resolution HLA Sequence-based Typing conducted on purified DNA and MRI | GWI: 65; Comparator: 16 healthy; Case def: CDC; Source: Same sample (-1) studied in a previous study^25^ | Age: 50.8 (7.9) vs 54.9 (10.2) years; Female: 3 vs 6; Race: NR
Johnson, 2013 ^26^; Cross-sectional; N=64 | Platelet count, immature platelet fraction (IPF), plasma thrombopoietin (TPO), C-reactive protein (CRP), platelet aggregation and ATP secretion | CRP and TPO assayed by Multi-Analyte Profiling. Platelet aggregation was measured by preparing citrated blood at 160g for 25 min, completed within 4 h of venipuncture. Aggregation was evaluated at the platelet count of the PRP without dilution or concentration. Agonists (0.5 mmol/l arachidonic acid, 5mmol/l epinephrine, 5mmol/l ADP, 0.5mmol/lU46619, 1.0mmol/l U46619, 1mg/ml collagen, 10mmol/thrombin receptor agonist peptide 6 (TRAP 6), and 50 mmol/l TRAP 6; final concentrations) were added to 450ml PRP, preincubated at 37°C, and stirred in a Chronolog Lumi-Aggregometer. ATP release was measured by Chronolog Lumi-Aggregometer. | GWI: 43; Comparator: 21 Healthy; Case def: CDC; Source: Veterans identified through the resources of the US Department of Veterans Affairs as persons who served in Kuwaiti Theater of Operations 1990-1991 | Age: 49.9 (8.55) vs 50.4 (11.0); Female: 7 vs 0; Race: NR
Johnson, 2016 ^29^; Cross-sectional; N=85 | Plasma lymphocytes, monocytes and neutrophils | Proteomic analysis performed by quantitative multiplexed immunoassays using a Multi-Analyte Profile (MAP) platform | GWI: 57; Comparator: 28 Healthy; Case def: CDC; Source: VA Minnesota Gulf War Registry, invited via letter | Age: Median – 46 vs 48; Female: 5 vs 4; Race: White 93 vs 93; Black 4 vs 7; Hispanic 4 vs 0
Lo, 2000 ^22^; Cross-sectional, population-based; N=2,951 | Mycoplasma fermentans antibodies | Pre- and post-deployment serum was obtained from the DoD Serum Repository | GWI: 718; Comparator: 2,233 healthy; Case def: Per medical examination; Source: Pt selection and serum specimen coding were performed by USACHPPM | Age >35 years: 136 (18.9) vs 425 (19.0); Female: 15.9 vs 15.7; Race: Black/AA 230 (32.0) vs 494 (22.1); White 410 (57.1) vs 1,552 (69.5); Other 78 (10.9) vs 187 (8.4)
Phillips, 2009 ^30^; Case-control; N=175 | Squalene antibody status | ELISA for antibodies to squalene in human serum | GWI: 29; Comparator: 146 healthy; Case def: Unusual fatigue with 3 of 38 additional symptoms; Source: 3 epidemiologic team visits (late 1994 - early 1995) to each of 2 Navy Seabee Centers | Age: 25.9 vs NR; Female: 0 vs NR; Race: White 84 vs NR; Black/AA 5 vs NR; Other/unknown 12 vs NR
Skowera, 2004 ^31^; Cross-sectional; N=120 | Th1/Th2 balance by measuring intracellular production of IFN-γ, IL-2 (Th1), IL-4 (Th2), and IL-10 by CD4 T cells | Blood samples were obtained; Flow cytometry was used to measure intracellular cytokine production by CD4 T lymphocytes. | GWI: 40; Comparator: 80 healthy; Case def: Score ≤72.2 on SF-36 Physical Functioning subscale; Source: Random sample of Veterans of the Gulf conflict (1990-91) | Age: NR; Female: NR; Race: NR
CENTRAL NERVOUS SYSTEM
Calley, 2010 ^32^; Cross-sectional; N=38 | Percent signal change | brain activation during semantic memory task: indicate if 2 features (written words) elicit the retrieval of a memory of a specific object (retrieval), or not (non-retrieval) | GWI: 26 (syndromes 1-3: 9;10;7); Comparator: 12 Healthy; Case def: Haley criteria; Source: Construction Battalion in US Naval Reserve | Age: NR; Female: 0; Race: NR
Cooper, 2016 ^33^; Cross-sectional; N=67 | Regional brain activation | brain activation during a face-name episodic memory task | GWI: 57; syndrome 1,2,3=19, 20, 18; Comparator: 10 Healthy; Case def: Haley criteria; Source: Sampled from nationally representative sample of Gulf War-era Veterans (N=8020) | GWI (syndromes 1, 2, 3) vs comparators:; Age: 49.16 (8.84) vs 49.95 (8.39) vs 51.44 (8.15) vs 45.60 (7.41); Female: 32, 30, 17 vs 10; Race/eth: Caucasian 68, 80, 72 vs 60; Black/AA 11, 15, 17 vs 30; Hispanic 5, 5, 6 vs 10; Other 16, 0, 6 vs 0
Gopinath, 2012 ^34^; Cross-sectional; N=54 | Brain activation | brain activation to innocuous and noxious heat stimuli | GWI (syndromes 1, 2, 3): 11; 17; 12; Comparator: 14 Healthy; Case def: Haley criteria; Source: 24^th^ Reserve Naval Mobile Construction Battalion | Age: 51 (6); 63 (7); 57 (7) vs 61 (7); Female: 0%; Race: NR
Liu, 2011 ^35^; Cross-sectional; N=47 | Cerebral blood flow | MRI with an inhibitory cholinergic challenge, physostigmine infusion | GWI: syndromes 1,2, 3; 11;12;10; Comparator: 14 Healthy; Case Def: Fukuda/Haley; Source: Members of the U.S. Naval construction battalion | GWI (syndromes 1, 2, 3) vs comparators:; Age: 51.4 (6.1), 60.9 (6.0), 57.3 (6.7) vs 60.1 (6.3); Female: 0; Race: NR
Odegard, 2013 ^36^; Cross-sectional; N=47 | Brain activation | brain activation during face-name associative memory paradigm | GWI: 33; Comparator: 14 Healthy; Case def: Haley criteria; Source: Construction battalion of the U.S. Naval Reserve | GWI (syndromes 1, 2, 3) vs comparators:; Age: 51.30, 61.67, 57.27 vs 60.36; Female: NR; Race: NR
Tillman, 2010 ^37^; Cross-sectional; N=48 | Event-related potential | EEG recordings during a go/no-go task (response inhibition) | GWI: 25; Comparator: 23 Healthy; Case def: Presented with major cognitive complaints; Source: Construction battalion of the U.S. Naval Reserve during 1991 Persian Gulf War | Age: 58.4 vs 58.8; Female: 0; Race: NR
Tillman, 2012 ^38^; Cross-sectional; N=28 | Event-related potential | EEG recordings during an auditory task: threatening sounds as distractor stimuli, 1000 hz square wave tone as nontarget stimulus, 250-hz square wave tone as the target stimulus | GWI: 20; Comparator: 8 Healthy; Case def: Haley criteria; Source: Construction battalion of the U.S. Naval Reserve during the 1991 Persian Gulf War | GWI (syndromes 1, 2, 3) vs comparators:; Age: 53.17 (5.38), 63.75 (7.05), 53.833 (6.85) vs 61.6 (7.58); Female: NR; Race: NR
Tillman, 2013 ^39^; Cross-sectional; N=30 | Event-related potentials | EEG recordings during visual task: threatening distractor pics, target stimuli (animals), nonthreatening nontarget stimuli | GWI: 22; Comparator: 8 Healthy; Case def: Haley criteria; Source: Construction battalion in U.S. Naval Reserve during the 1991 Persian Gulf War | Age: 57.2 vs 61.6; Female: 0; Race: NR
Tillman, 2019 ^40^; Cross-sectional; N=62 | Event-related potential | EEG recordings during an auditory task: threatening distractor sounds, target tone stimulus | GWI: 40; Comparator: 12 Healthy; Case def: Haley criteria; Source: Nationally representative dataset of the Gulf War Veteran population from 4 military branches | GWI (syndromes 1, 2, 3) vs comparators:; Age: 49.2 (10.4), 52.0 (7.3), 49.7 (7.8) vs 48.4 (7.9); Female: 25 vs 14; Race: Caucasian: 87 vs NR; Other: 13 vs NR
Weiner, 2011 ^41^; Cross-sectional; N=178 | N-acetylaspartate, creatine-and choline-containing metabolites | Spectroscopy (MRI, MRS, MRSI) | GWI: 81; Comparator: 97 healthy; Case def: CDC and Haley criteria; Source: N. California VA GWI clinics, fliers at VA hospitals/clinics, and direct mailing to DoD list of GWVs | Age: 44.6 (8.8) vs 44.6 (9.9); Female: 9 vs 15; Race/eth: White 64 vs 61; Black/AA 14 vs 16; Hispanic 11 vs 9; Asian 2 vs 3; Pacific islander 2 vs 4; Other 2 vs 4
AUTONOMIC NERVOUS SYSTEM
Blanchard, 2019 ^42^; Cross-sectional case-control cohort study; N=295 | 24-hr heart-rate variability, urinary catecholamines and cortisol, hypertension, insulin sensitivity, dyslipidemia, body fat, bone mineral density, and ultrasensitive CRP | Hypothalamic-Pituitary-Adrenal Axis measures: overnight dexamethasone suppression testing; ANS Measures: ECG via 24-hour digital monitors, looking at HRV | GWI: 73; Comparator: 111 healthy; Case def: CMI – CDC definition; Source: NR | Age: 47.1 (8.1) vs 47.5 (9.0); Female: 36 vs 17; Race: White 73 vs 83
Davis, 2000 ^43^; Cross-sectional; N=27 | Heart rate, blood pressure | 3-stage tilt-table testing with isoproterenol | GWI: 14; Comparator: 13 healthy; Case def: Chronic Fatigue (ICD-9-CM Code 780.7); Source: Mostly active duty soldiers who went through DoD CCEP (Evans Army Community Hospital; 1994-1997) | Age: 32.1 (1.6) vs 38.9 (1.9); Female: 14 vs 8; Race: NR
Haley, 2013 ^44^; Cross-sectional; N=82 | Autonomic function and high-frequency HRV | CASS, measuring the severity of autonomic dysfunction from 0 (no deficit) to 10 (maximal deficit), using sudomotor (range, 0-3), cardiovagal (range, 0-3), and adrenergic (range, 0-4) measurements. 24-hour Holter ECG recordings, performed at home, complexes and artifacts. | GWI: 66 (syndromes 1, 2, 3: 21, 24, 21); Comparator: 16 healthy; Case def: CDC and Haley criteria; Source: Population sample of the US Military Health Survey | GWI (syndromes 1, 2, 3) vs comparators:; Age: 48.2 (8.6), 49.8 (8.0), 51.0 (7.9) vs 47.8 (7.9); Female: 33, 29, 19 vs 19; Race: Black/AA 14, 17, 14 vs 25
Li, 2014 ^45^; Cross-sectional; N=28 | BP, HR, tilt-table, nerve conduction, sensory testing, sudomotor axon reflex testing | BP, HR, tilt-table, nerve conduction, sensory testing, sudomotor axon reflex testing | GWI: 16; Comparator: 12 healthy; Case def: Post-exertional fatigue: patient-reported recurrent post-exertional fatigue lasting >24 hours, or chronic fatigue >6 months since deployment; Source: “Health of US Veterans of 1991 Gulf War: A Follow-Up Survey in 10 years” 2005 survey pts in Washington DC and nearby states | Age: 48.3 (1.4) vs 48.1 (2.0); Female: 19 vs 8; Race: NR
Nagelkirk, 2003 ^46^; Cross-sectional; N=38 | Cardiorespiratory and metabolic responses (maximal oxygen uptake, HR, exercise time, workload achieved) to maximal exercise test | Maximal exercise test: BP electronically monitored + verified with concurrent mercury sphygmomanometry; HR monitored by ECG; expired air collected with one-way nonrebreathing valve + analyzed with Max-1 system | GWI: 19; Comparator: 19 healthy; Case def: CDC case def for CFS; Source: Mailed health survey; study site East Orange, NJ VAMC | Age: 41.9 (7.8) vs 43.1 (5.1); Female: 16 vs 16; Race: NR
GENETIC
Hotopf, 2003 ^47^; Cross-sectional, population-based; N=190 | Paraoxonase (PON1) activity and genotype | PON1–55 and -192 genotype determined by polymerase chain reaction and restriction enzyme digestion using standard published protocols. Plasma apolipoprotein AI (apoAI) and high-density lipoprotein (HDL) measured with Cobas Mira S autoanalyser with reagents. | GWI: 95; Comparator: 95 healthy; Case def: SF-36 (physical functioning subscale); Source: Randomly selected cohorts of UK Armed Forces | Age: 36.9 (7.3) vs 34.3 (5.4); Female: 6 vs 5; Race: NR
OTHER BIOLOGICAL SYSTEMS
Amin, 2011 ^48^; Cross-sectional; N=29 | Sleep parameters; Sleep-related respiratory parameters | 2 nights in sleep lab: full night PSG, surface electromyographic activity (for movement); nasal/oral pressure catheter (nose+mouth airflow); piezoelectric belts (for Thoraco-abdominal movement); oxyhemoglobin saturation monitored at the finger using pulse oximeter. Continuous ECG monitored HR and rhythm | GWI: 18; Comparator: 11 healthy; Case def: Modified CDC; Source: Gulf War Registry | Age: 42 (4) vs 41 (6.6); Female: 0%; Race: NR
Haines, 2017 ^21^; Cross-sectional, population-based; N=43 | Cholinesterase, Serum cytokines | Peripheral venous blood draw | GWI: 25; Comparator: 4 healthy, 14 PTSD; Case def: Neurologic factor (4 symptoms): blurred vision, balance problems/dizziness, tremors/shaking, and speech difficulty; Source: UK military personnel | Age: NR; Female: NR; Race: NR
Roland, 2000 ^49^; Cross-sectional; N=33 | Integrity of auditory pathways (inner ear through upper brain stem and vestibulocular reflex) | Audiovestibular testing: Rotary chair for Sinusoidal Harmonic Acceleration; Electronystagmography for ocular motor, positional, and caloric responses; Electrocochleography for auditory-evoked potentials; dynamic platform posturography for balance. | GWI: 23 (Syndrome 1, 2, 3: 5, 13, 5); Comparator: 10 healthy; Case def: Haley criteria; Source: 24th Reserve Naval Mobile Construction Battalion | Age: 46.6 ± 8.6 vs 48.0 ± 6.2; Female: NR; Race: NR
Sharief, 2002 ^50^; Cross-sectional, population-based; N=75 | Distal motor latency, amplitude of compound motor action potential (CMAP), motor nerve conduction velocity (CV), and F-wave latency; functions of unmyelinated (C) + small myelinated (A-) fibers | Nerve conduction studies on dominant limbs + symptomatic side if symptoms were unilateral, at skin temperatures of 34 °C. Motor conductions recordings; Quantitative sensory and autonomic function tests: thermal thresholds in dominant hand and foot using TSA-2001 machine; Concentric needle and single-fiber EMG: On proximal + distal muscles in upper + lower limbs (biceps brachii, first dorsal interosseus, vastus medialis, and tibialis anterior) | GWI: 49; Comparator: 26 healthy; Case def: >4 neuromuscular symptoms: fatigue, joint stiffness, muscle weakness, myalgia at rest or after exercise, sensory symptoms, and autonomic symptoms + SF-36 score <72.2; Source: UK servicemember database | Age: NR; Female: NR; Race: NR
Wallace, 1999 ^51^; Cross-sectional, not population-based; N=78 | (HHVs) HHV6, HHV7, Epstein-Barr virus (EBV), and cytomegalovirus | Blood samples: DNA extraction from PBMC cells; PCR was performed with primers for HHV6, HHV7, EBV, HCMV, TCR-beta | GWI: 46; Comparator: 32 healthy; Case def: CDC; Source: Veterans from 10 states east of the Mississippi River | Age: 35.3 vs 32; Female: 17% vs NR; Race: Caucasian 73% vs NR
Zhou, 2018 ^52^; Cross-sectional; N=91 | Heat pain threshold, cold pressor pain threshold; ischemic pain threshold and ischemic pain tolerance | Experimental pain procedures (3 random pain stimuli) | GWI: 53 GWI+GI symptoms; 38 no GI symptoms; Comparator: 47 healthy; Case def: Documented GWI +/− GI symptoms; Source: VAMCs in Cincinnati, OH and Gainesville, FL | GWI (with, without GI symptoms) vs comparators:; Age: 49.1 (3.7), 48.2 (1.2) vs 46.6 (4.1); Female: 9, 0 vs 10; Race/eth: White 51, 83 vs 21; Black/AA 47, 17 vs 45; Hispanic 0, 0 vs 0; Asian 2, 0 vs 0

Abbreviations: AA=African American; ADP=Adenosine Diphosphate; ANS=Autonomic Nervous System; apoAI=Plasma Apolipoprotein AI; ATP=Adenosine Triphosphate; BOLD=Blood Oxygen Level Dependent; BP=Blood Pressure; CASS=Composite Autonomic Severity Score; CCEP=Comprehensive Clinical Evaluation Program; CDC=Centers for Disease Control and Prevention; CFS=Chronic Fatigue Syndrome; CMAP=Compound Motor Action Potential; CMI=Chronic Multisymptom Illness; CRP=C-Reactive Protein; CV=Conduction Velocity; DNA=Deoxyribonucleic Acid; DoD=Department of Defense; EBV=Epstein-Barr Virus; ECG=Electrocardiogram; ECL=Electrochemiluminescence; EEG=Electroencephalograph; ELISA=Enzyme-Linked Immunosorbent Assay; EMG=Electromyograph; fMRI=Functional Magnetic Resonance Reasoning; GI=Gastrointestinal; GWI=Gulf War Illness; GWV=Gulf War Veteran; HCMV=Human Cytomegalovirus; HDL=High-Density Lipoprotein; HHV=Human Herpesvirus; HLA=Human Leukocyte Antigen; HR=Heart Rate; HRV=Heart Rate Variation; ICD-9-CM=International Classification of Diseases, Ninth Revision, Clinical Modification; IFN=Interferon; IgG=Immunoglobulin; IL=Interleukin; IPF=Immature Platelet Fraction; LPC=Lysophosphatidylcholines; LPE=Lysophosphatidylethanolamine; MAP=Multi-Analyte Profile; MRI=Magnetic Resonance Imaging; MRS=Magnetic Resonance Spectroscopy; MRSI=Magnetic Resonance Spectroscopic Imaging; MSD=Meso Scale Discovery; NR=Not Reported; PBMC=Peripheral Mononuclear Cell; PC=Phosphatidylcholine; PCR=Polymerase Chain Reaction; PE=Phosphatidylethanolamine; PI=Phosphatidylinositol; PON1=Paraoxonase; PRP=Platelet-Rich Plasma; PSG=Polysomnogram; PTSD=Posttraumatic Stress Disorder; SD=Standard Deviation; SF-36=Short Form-36 Question Questionnaire; TCR=T-Cell Receptor; TNF=Tumor Necrosis Factor; TPO=Plasma Thrombopoietin; TRAP=Thrombin Receptor Agonist Peptide; UK=United Kingdom; US=United States; USACHPPM=United States Army Center for Health Promotion and Preventive Medicine; VA=Veterans Affairs; VAMC=Veterans Affairs Medical Center

### Immune System Biological Measure Studies

Table 3 provides results of the 10 studies of immune system biological measures we identified. Identified studies focused on a wide range of immune system-related functions including squalene antibodies (2 studies^23,30^), a variety of inflammatory cytokines (5 studies^24,26,28,29,31^), human leukocyte antigen (HLA) alleles (2 studies^25,27^), and mycoplasma antibodies (1 study^22^).

Two studies assessed the associations between the presence of squalene antibodies and GWI status.^23,30^ The first was a case-control design that included 43 Veterans with Chronic Multisymptom Illness (CMI) and 536 who did not have CMI, as defined by unusual fatigue accompanied by 3 of a list of symptoms in broad categories such as altered mood, GI issues, pain, dermatologic issues, and generalized malaise (eg, sore throat and weakness).^30^ Whole blood or sera was collected using standardized approaches and subjects were followed up with 3 years later. There was no significant difference between those who were squalene antibody-positive or -negative with regard to presence of GWI. Limitations to this study included use of a non-standard GWI case definition, lack of comparability between cases and control, and limited data on sample attrition. In contrast, the second study to examine squalene antibodies did find a difference in the presence of squalene antibodies between those with GWI (n=38) and compared to those with idiopathic immune disease or healthy controls (n=12), such that 95% of those with GWI had squalene antibodies, while 0% of healthy deployed GWVs had squalene antibodies. This study was a feasibility study, so no power analyses or inferential statistics were provided.^23^

Many of the other studies focused on measures of inflammation with peripheral blood cytokines^26,28,29,31^ and phospholipid species.^24^ Two studies focused on peripheral blood cytokines (Th1/Th2 balance measured by intracellular production of Interferon (IFN)-γ, Interleukin (IL)-2 (Th1), IL-4 (Th2), and IL-10 by CD4 T cells) among those who were symptomatic Gulf War Veterans versus non-symptomatic Gulf War Veterans.^28,31^ The first found that those who were ill had elevated levels of Th1 immune activation as evidenced by elevated levels of IL-10 by CD4 cells (p<0.001), IL-2 (p=0.01) and IL-4 (p=0.001).^31^ Analyses corrected for age, gender, vaccination status, antidepressant use, Beck Depression Inventory score, and history of atopic illness. All other cytokines were normal. This study was limited by not accounting for multiple testing bias, the cases and controls not being drawn from the same population, and a non-standard GWI case definition being used to identify cases (used Short Form [SF]-36 score to identify cases). The other study compared those with GWI (n=53) to healthy, deployed GWVs (n=27) using the CDC case definition. A similar set of cytokines were examined (IL-6, IL-8, IL-10, IFN-γ, tumor necrosis factor (TNF)-α, and C-reactive protein (CRP)) and no statistically significant between group differences were detected based on GWI status.^28^ Limitations include sample size and power not being calculated and adjustment for multiple comparisons not being conducted. Johnson and colleagues included 43 men with GWI and 21 men without GWI and compared CRP, platelet counts, platelet aggregation, and several other measures of platelet function and found GWI had elevated platelet counts, spontaneous aggregation, and thrombin receptor agonist peptide (TRAP) 6-induced secretion, but no impairment of platelet counts.^26^ Study limitations include multiple testing not adjusted for and non-response rate not reported. Another study examined a similar set of blood inflammatory cytokines measures that also included lymphocyte, monocyte, and neutrophil among 57 individuals with GWI compared to 28 GWVs without GWI. All included inflammatory markers were higher among those with GWI (see Table 3 for specific results).^29^ The combinations of lymphocytes, monocytes, and CPR had a predicted probability of 90% (95% CI=76-90%) for diagnosing GWI when the probability of having GWI was above 70%. Limitations of this study included not adjusting for multiple comparisons or difference between cases and controls, as well as some of the more ubiquitous limitations discussed listed below.

Another study obtained samples of phospholipids, which are inflammatory modulators, from a biorepository (11 controls matched for gender, age, and ethnicity, and 22 who met Kansas criteria for GWI) to examine several different phospholipids (Phosphatidylcholine [PC]; phosphatidylethanolamine [PE]).^24^ Peripheral lipids were present in GWI (human and animal models). The study found that multiple species of phospholipids were elevated in humans with GWI, suggesting dysfunction within docosahexaenoic acid and arachidonic acid containing phospholipid (PL) species. This study did correct for multiple testing, but it was unclear whether the cases and controls were derived from the same population and are comparable.

Two additional studies examined HLA alleles.^25,27^ The first included 82 Veterans, 66 with and 16 without GWI, and found that the number of copies of the 6 HLA alleles was significantly higher in the control group and correctly classified the GWI status of 84.1% of participants (13/16 control and 56/66 GWI).^25^ Limitations included lack of clarity about selection of controls and potential lack of comparability between cases and controls. An additional study examined HLA alleles and brain synchronicity in 81 Veterans (65 with GWI and 16 without GWI). Controls had higher counts of HLA protective alleles than those with GWI (chi-square test=21.9, p=0.000018). There was also an overall strong and significant effect of the HLA-related x neural synchrony interaction on symptom severity (SPRC |β|=0.274,0.232, and 0.200 for neurocutaneous melanocytosis (NCM), pain, and fatigue, respectively, p<0.001 for all 3 coefficients.^27^ Limitations included unrepresentativeness of cases and controls, lack of power calculation, lack of comparability between cases and control, and lack of reporting of blinding and non-response rate.

Finally, 1 study examined the presence of antibodies to Mycoplasma (M.) fermentans^22^ among 718 Veterans with GWI and 2,233 healthy Gulf War Veterans. There was no difference between rates of seroconversion between cases and controls, indicating that there is no association between GWI and M. fermentans infection.

Limitations across immune system studies included lack of blinding of outcome assessor and/or study team. Additionally, recruitment non-response rate was not reported, giving us little insight into issues of response bias. Sample size and power calculations were also often not reported, and very few studies discussed issues related to data normality and handling of outliers.

Table 3 Results of Gulf War Illness Immune System Biological Measure Studies

Biological Measure/Outcome Measure; n GWI vs n comparator | Detailed Results; GWI vs control | Summary of Findings | Study Limitations
Human leukocyte antigen, brain synchronicity (zero-lag, pairwise cross correlations calculated from pre-whitened, 60-second resting-state MEG recordings)^27^; 65 vs 16 | Human leukocyte antigen protective alleles: Cases had higher counts than healthy GWI chi-square test=21.9 (p=0.000018); Brain synchronicity: Significant effect of the HLA-related x neural synchrony interaction on symptom severity (SPRC \|β\|=0.274,0.232, and 0.200 for NCM, pain, and fatigue, respectively, p<0.001 for all t coefficients).; HLA-related effects spared the right anterior temporal lobe and were widespread, vs non-HLA-related effects focused on anterior temporal lobe, medial prefrontal cortex, posterior parietal, and occipital cortex. | HLA antigens are higher in those with GWI; HLA related x neural synchrony is related to symptom severity. | Lack of representativeness of cases and controls, lack of power calculation, lack of comparability between cases and control, lack of blinding, lack of reporting of non-response rate.
Mycoplasma (M.) fermentans antibodies^22^; 718 vs 2,233 | Positive for M. fermentans-specific antibodies, (%):; Pre-deployment: 34/718 (4.8%) vs 116/2233 (5.2%); Post-deployment seroconversion from negative to positive: 8/718 (1.1%) vs 26/2233 (1.2%); Seropositive at both pre- and post-deployment: 17 (2.4%) vs 54 (2.4%); OR=0.97 (95% CI: 0.56 to 1.69); Positive on pre-deployment and negative and post-deployment: 7 (2.4%) vs 62 (2.8%); OR=0.85 (95% CI: 0.49 to 1.46) | There was no difference between rates of seroconversion between cases and controls, indicating that there is no association between GWI and M. fermentans infection. | Lack of comparability of cases and controls, power calculation, non-response rate not reported, lack of blinding of outcome assessors.
Squalene antibody status^23^; 38 vs 12 | % participants with positive ASA reactivity: 95% of those with GWI vs 0% of healthy controls | Squalene antibodies may be associated with GWI. | Lack of comparability between cases and controls; unrepresentativeness of cases and controls.
Cytokines: IFN-γ, IL-6, IL-8, IL-10, and TNF-α and CRP^28^; 53 vs 27 | Plasma cytokine concentrations below the lowest level of detection (LLOD): Plasma concentrations for 4 cytokines were below the LLOD and were excluded.; Included plasma cytokines: No difference in concentrations of IFN-γ, IL-6, IL-8, IL-10, and TNF-α, but trend toward significance in IL-6 (p=0.08) | No between group difference detected on any of the cytokines measured. | Power calculations not reported; no adjustments made for multiple comparisons.
Phospholipid species in plasma: PC, LPC, PE, LPE and PI^24^; 22 vs 11 | Phospholipid levels in GWI vs healthy GWI controls:; No differences in PC, PE, LPE, PI (p>0.05); LPC was 15% greater for GWI (p=0.020); Unsaturation of PL classes: no differences in degree of unsaturation for PE and PI; SFA containing PC species: reduced by 22% in GWI compared to controls (p=0.024); LPC, SFA, MUFA, and PUFA containing species: elevated in GWI compared to controls by 16%, 15%, and 23% (p<0.05); LPE, PUFA containing species: increase of 50% in GWI compared to controls (p<0.001); SFA and MUFA containing LPE species: no difference between GWI and controls; Ether lipids in plasma: no differences for ePC, eLPC, ePE between GWI and controls; eLPE: increased in GWI by 43% compared to controls (p<0.001); AA- and DHA-containing phospholipid species: AA species within LPC and LPE were increased by 22% in GWI compared to controls (p=0.023) and 40% respectively (p=0.005) | Multiple species of phospholipids were elevated in humans with GWI | Comparability of cases and controls; and non-response rate not reported
Platelet count, IPF, TPO, CRP, platelet aggregation and ATP secretion^26^; 43 vs 21 | Platelet count, mean platelet volume, immature platelet fraction, C-reactive protein, and thrombopoietin: mean platelet count and plasma CRP: 4.05 (4.58) vs 1.54 (1.32); p=0.020; Mean MPV, IPF and TPO platelet aggregation: no difference; Spontaneous aggregation: 7.6 (2.2) vs (6.1 (2.5); p=0.017; Aggregation responses of platelets with each agonist: no difference; Platelet ATP secretion (stimulated with TRAP 6): 15.46 (4.48) vs 12.42 (2.84); p=0.011 | GWI had elevated platelet counts, spontaneous aggregation, and TRAP 6-induced secretion, but no impairment of platelet counts. | Multiple testing not adjusted for, non-response rate not reported
Plasma lymphocytes, monocytes and neutrophils^29^; 57 vs 28 | Hematological data:; Lymphocyte, monocyte, neutrophil, and platelet counts: higher in GWI; Proteomic analysis:; plasma CRP, leptin, BDNF, and MMP-9: higher in GWI H-FABP and MMP-2: lower in blood of GWI; Diagnostic model:; GWI diagnostic model using 3 biological measures (lymphocytes, monocytes, and CRP): c-statistic=0.77 (95% CI: 0.67 to 0.88; p=0.05) | Monocyte, and neutrophil and found that all were higher in those with GWI. | Lack of blinding of outcome assessors, lack of correction for multiple comparisons, no adjustment for differences between cases and controls
Squalene antibody status^30^; CMI; 29 vs 146 | Squalene antibodies Negative: 13/29 (44.8%) vs 71/146 (48.6%); Squalene antibodies Positive: 75/146 (51.4%) vs 16/29 (55.2%); No association between squalene antibody status and CMI (p=0.465). | Study did not find an association between presence of squalene antibodies between those with GWI compared to health controls. | Non-standard GWI case definition used, unclear whether cases and controls were comparable, lack of reporting of biological measure outliers
Th1/Th2 balance by measuring intracellular production of IFN-γ, IL-2 (Th1), IL-4 (Th2), and IL-10 by CD4 T cells^31^; 40 vs 80 | Immune activation in nonstimulated CD4 cells:; Mean levels of nonstimulated, IL-4C and IL-2C cells: higher in GWI (for IL-4, P <0.05; for IL-2,P <0.01); Memory cell cytokine balance: level of IL-10 producing CD4 cells higher in GWI (p<0.0001); Non-stimulated cytokine-positive cells: higher levels of IFN-γ, and IL-2 in GWI; Polyclonally activated cytokine-positive CD4 cells: higher levels of IL-10+ cells for GWI | IL -4C, -2C and -10 production by CD4 cells was elevated in those with GWI. | Cases and controls not selected from the same populations, using a non-standard definition of GWI, did not account for multiple testing bias
HLA alleles^25^; 66 vs 16 | Identified 144 HLA alleles in the sample, of which 6 Class II alleles yielded 84.1% correct classification as GWI vs control. All 6 allele frequencies were lower in GWI group (p=0.002) and all ORs < 1, ln(ω)=−1.792 ± 0.383 (mean ± SEM), t=−4.671, DF=5, p=0.005. Negative relationship between overall symptom severity and number of allele copies (t=−4.148, DF=80, p=0.000083, R^2^=0.177) | 6 HLA alleles correctly classified GWI vs control. These alleles were significantly less frequent in GWI. The number of allele copies were significantly associated with symptom severity. Authors interpretation: reduced HLA protection (ie, genetic susceptibility) in Veterans with GWI. | Non-standard case definition, sampling not population-based, lack of adjustment for multiple comparisons

Abbreviations: AA=Arachidonic Acid; ASA=Anti-Squalene Antibody; ATP=Adenosine Triphosphate; BDNF=Brain-derived Neurotrophic Factor; CI=Confidence Interval; CMI=Chronic Multisymptom Illness; CRP=C-reactive Protein; DF=Degrees of Freedom; DHA=Docosahexaenoic Acid; GWI=Gulf War Illness; H-FABP=Heart-type Fatty Acid Binding Protein; HLA=Human Leukocyte Antigen; IFN=Interferon; IL=Interleuken; IPF=Immature Platelet Fraction; LLOD=Lowest Level of Detection; LPC=Lysophosphatidylcholines; LPE=Lysophosphatidylethanolamine; MEG=Magnetoencephalograph; MMP=Matrix Metalloproteinase; MPV=Mean Platelet Volume; MUFA=Monosaturated Fatty Acids; NCM=Neurocutaneous Melanocytosis; OR=Odds Ratio; PC=Phosphatidylcholine; PE=Phosphatidylethanolamine; PL=Phospholipid; PI=Phosphatidylinositol; PUFA=Polyunsaturated Fatty Acids; SEM=Standard Error of the Mean; SFA=Saturated Fatty Acid; SPRC=Standardized Partial Regression Coefficient; TNF=Tumor Necrosis Factor; TPO=Plasma Thrombopoietin; TRAP=Thrombin Receptor Agonist Profile

### Central Nervous System Biological Measure Studies

Table 4 provides results of the 10 studies of central nervous system biological measures we identified. All but 1 of the studies measured brain activation, either with functional magnetic resonance imaging (fMRI), MRI, or electroencephalograph (EEG), during the presentation of specific stimuli/tasks. While there were 2 studies with an accompanying replication study each, the body of evidence was otherwise comprised of studies that employed varied stimuli/tasks. Seven studies, 5 with cognitive/emotional tasks^32,33,37–39^ and 2 with physical challenges,^34,35^ reported differences in brain activation between GWI and comparator groups, while only 2 studies, which involved cognitive/emotional tasks and were each replication/replicated studies, did not identify any group differences in brain activation.^36,40^

In 4 of the 9 CNS studies, the participants engaged in a cognitive task: 1 semantic memory processing task study,^32^ 2 face-name association task studies (the second a replication of the first with a different sample and larger sample size),^33,36^ and 1 response inhibition task study.^37^ In the first (N=47) of the 2 studies employing the face-name association task, no difference in brain activation was reported between the GWI and control groups,^36^ while in the replication study, there was greater brain activation in the putamen of GWI Syndromes 1 and 2, each compared to controls (N=67; t=3.63; t=3.45, respectively).^33^ Differences in brain activation between participants with GWI and controls were also reported in the study involving a semantic memory task, including differences in brain activation between GWI and controls in the thalamus and caudate head associated with participants correctly indicating a lack of association between words, and a difference in the relationships between reaction time to memory task stimuli and brain activation in GWI Syndrome 2 versus controls (N=38; p=0.02).^32^ In the study involving a response inhibition task, brain activation (ERP P3 amplitude) was dampened in the GWI group versus controls (N=48; F(1, 46)=6.501, p=0.0142, η2=.095).^37^

In another set of 3 studies, brain activation during the presentation of potentially threatening/emotionally triggering stimuli was recorded. In 2 of these studies (1 of them a replication study drawing from a larger, more representative pool of participants^40^) the stimuli were presented auditorily, and, in a third study, visually.^39,40^ There were differences in brain activation between GWI and control groups in the original study involving auditory stimuli, with differences in brain activation (EEG P1 amplitude and latency) between Syndromes 2 and 3 compared to controls and Syndrome 1 (N=28; F(1, 23)=9.915, p=0.004; (F(1, 23)=22.025, p=0.0001)). There were also differences in EEG P3a amplitude between Syndromes 1 and 2 versus controls and Syndrome 3 (N=28; F(1, 23)=11.172, p=0.003), and in EEG P3b amplitudes between GWI and controls (N=28; p=0.003),^38^ but there were not group differences in the replication study (N=62).^40^ There were also group differences in brain activation in the study in which the visual version of the task was presented, with greater brain activity (P3b amplitude) in the control than GWI groups (N=30; p=0.0004).^39^

In 2 studies, the stimuli presented during the measurement of brain activation were innocuous and noxious heat,^34^ and physostigmine (to provide an inhibitory cholinergic challenge),^35^ respectively. In the study involving innocuous and noxious heat, Syndromes 1 and 2 had greater brain activation to innocuous heat in ventral anterior cingulate (N=54; p<0.05) and less activation to innocuous heat in areas involving heat perception (N=54; p<0.05), but greater activation to noxious heat in brain areas involving pain, compared to controls. Syndrome 3 had greater activation to innocuous heat compared to controls only in the dorsolateral prefrontal cortex.^34^ In the study involving a physostigmine challenge, change in cerebral blood flow with the challenge was significantly greater in controls than GWI groups (N=47; p=0.014).^35^ The remaining study measured the brain chemical N-acetylaspartate, and reported no difference in concentrations in the basal ganglia or pons between GWI and controls.^41^

The body of evidence was limited in that none of the studies used an optimal control group for identifying biological measures that differentiate GWI cases from similar conditions – namely, deployed GWVs with health conditions other than GWI. Further, the outcome assessor was often not reported to be blinded to group status,^32,36–40^ participants in the CNS studies were often selected from the same battalion,^32,34–36^ decreasing the representativeness of the sample, and, when multiple comparisons were conducted, it was often not reported if statistical corrections were made.^32–35,37,39^

Also of note was the use of the Haley criteria for case definition in most of these CNS studies. Seven^32–34,36,38–40^ of the 9 studies identified cases with the Haley criteria, and another used both the CDC and the Haley criteria.^35^ The Haley criteria categorizes cases into 6 syndromes based on clusters of symptoms, as described above.

Table 4 Results of Gulf War Illness Central Nervous System Biological Measure Studies

Biological Measure/Outcome Measure; n GWI vs n comparator | Detailed Results; GWI vs control | Summary of Findings | Study Limitations
Percent BOLD signal change (PSC)^32^; 26 (syndromes 1, 2, 3: 9, 10, 7) vs 12 | Percent (BOLD) signal change (PSC): Thalamus PSC increase while correctly indicating no association between 2 given words in Syndrome 2 GWI vs control.; Caudate head PSC decrease while correctly indicating no association between 2 given words in GWI Syndrome 1 vs control.; Positive association between reaction time and PSC in GWI Syndrome 2 which differed from that of controls (p=0.02).; Thalamus PSC associated with an increase in reaction time in GWI Syndrome 2, trend toward statistical difference from all other groups (p<0.08) | Differences in a semantic memory processing task were associated with differences in BOLD PSC in the thalamus and caudate in GWI vs controls. The relationship between reaction time to task stimuli and brain activation also differed between GWI and controls. | Haley criteria case definition, non-representative sample, small sample size, lack of blinding of outcome assessors
Regional brain activation^33^; 57 (syndromes 1, 2, 3: 19, 20, 18) vs 10 | Regional brain activation (fMRI BOLD activity): Left insula (putamen) activation greater in control vs Syndromes 1 and 2 (t=3.63; t=3.45, respectively). No difference in activation in GWI Syndrome 3 vs control. | Greater brain activation in areas of the brain associated with processes including sensation, perception, and emotion during a face-name associative memory task in GWI Syndromes 1 and 2 vs controls. | Haley criteria case definition, small sample size
Brain activation^36^; 33 vs 14 | Brain activation (fMRI BOLD activity): No group differences. | There were no demonstrated differences in brain activation, as measured with fMRI, between GWI and controls during a face-name associative memory paradigm. | Haley criteria case definition, small sample size, lack of outcome assessor blinding
Event-related potential^37^; 25 vs 23 | EEG N2 amplitude during behavioral inhibition task: No interaction between group and condition (F(1, 46)=2.062, p=0.1578). Trend toward a main effect of group (F(1, 46)=3.373, p=0.0727, p=0.0727); EEG P3 amplitude during behavioral inhibition task: Interaction between group and condition (F(1, 46)=6.569, p=0.0137, η2=.017) on P3 amplitude. P3 amplitude showed an effect of group (F(1, 46)=6.501, p=0.0142, η2=.095) amplitude, with the control group greater than GWI. | EEG P3 amplitude in GWI during a task requiring behavioral inhibition was dampened compared to in controls. | Non-standard case definition, small sample size, no blinding of outcome assessor
Event-related potential^38^; 20 vs 8 | EEG P1: Main effect of illness group on P1 amplitude (F(3, 23)=3.509, MS_error_=2.021, p=0.031), with only 1 of the contrasts significant, Syndromes 2 and 3 compared to controls and Syndrome 1 (F(1, 23)=9.915, p=0.004, p=0.004).; Main effect of syndrome group on P1 latency (F(3, 23)=7.416, MS_error_=115.830, p=0.001), with only 1 of the contrasts significant, Syndromes 2 and 3 had longer latencies vs controls and Syndrome 1 (F(1, 23)=22.025, p=0.0001).; EEG P3: No interaction between distractor stimulus type and group, p>0.273.; Effect of syndrome group on P3a amplitude (F(3, 23)=4.700, MS_error_=1.188, p=0.011) with only 1 contrast significant, with controls and Syndrome 3 greater than Syndromes 1 and 2 (F(1, 23)=11.172, p=0.003).; There was no omnibus effect of GW Illness syndrome group on P3a latency (F(3, 23)=1.775, MS_error_=441.372, p=0.18). Effect of group on P3b amplitudes (p=0.006), with greater amplitude of the control group was greater than that of GWI p=0.003).; No effect of group on P3b latency (p=0.148). | EEG P1 and P3a responses to auditory stimuli that were previously demonstrated to elicit hyperarousal responses in GWI differed between GWI and control groups. | Haley criteria case definition, small sample size, lack of blinding of outcome assessor
Event-related potential^40^; 40 vs 22 | EEG P1 amplitude: No difference between deployed and nondeployed controls in P1 amplitude (p=0.550) or latency (p=0.555); data were collapsed into 1 control group. Interaction between group and condition on P1 amplitude (p=0.014), but no significant contrasts including control group comparisons.; EEG P1 latency: There was neither an effect of GWI syndrome group on P1 latency (F(3, 58)=0.748, MSE=275.714, p=0.528) nor an interaction between group and condition (F(9, 174)=0.955, MS_error_=75.297, p=0.479). | No differences between GWI and control groups in EEG responses during a task involving the presentation of auditory stimuli previously demonstrated to elicit hyperarousal responses in GWI. | Haley criteria case definition, small sample size, no reported blinding of outcome assessors
Event-related potentials^39^; 22 vs 8 | EEG P3 amplitude: No effect of group on P3a amplitude (F(3, 26)=.339, p=0.7973). Significant effect of group on P3b amplitude (F(3, 26)=5.282, p=0.0056, η2=0.3787), with control group amplitude higher than ill groups (p=0.0004).; EEG P3 latencies: Latencies of P3a and P3b did not differ significantly by group (p>0.27). | EEG P3b amplitude during a task involving the presentation of visual trauma-related stimuli was greater in control groups than in GWI. | Haley criteria case definition on, no reported blinding of outcome assessors, small sample size
Brain activation^34^; 40 vs 14 | Brain activation to innocuous heat: Syndromes 1 and 2 GWI greater (p<0.05) activation to innocuous heat than controls in ventral anterior cingulate and less activation than controls in areas involving heat perception (p<0.05). Syndrome 3 greater activation than controls in left DLPFC, but no other areas.; Brain activation to noxious heat: Syndromes 1-2 hyper-activation (p<0.05) compared to controls in regions involving pain. Syndromes 1-3 GWI significant (p<0.0001) activation to noxious heat in similar areas as controls. Syndrome 1 higher noxious heat activation than controls in left amygdala, arahippocampal gyrus, thalamus, and right basal ganglia.; Syndrome 3 activation was not different from controls (p>0.05). | GWI Syndromes 1 and 2 had greater brain activation toinnocuous heat in the ventral anterior cingulate than controls, and less activation to innocuous heat in brain areas involving heat perception, but greater activation to noxious heat in brain areas involving pain. Syndrome 3 had greater activation to innocuous heat than controls in only the left DLPFC, and no different activation to noxious heat than controls. | Haley criteria case definition on, non-representative sample, insufficient sample size, incomparability of cases and controls
Cerebral blood flow^35^; 33 vs 14 | Cerebral blood flow with physostigmine challenge: GWI (Syndrome groups combined) and controls CBF change significantly greater in control (p=0.014). | Change in cerebral blood flow with an inhibitory cholinergic challenge significantly greater in control than GWI groups, indicating persistent cholinergic deficits in GWI. | Non-representative sample, small sample size
Quantities of N-acetylaspartate in the basal ganglia and pons^41^ 81 vs 97 | No difference in PON1 genotype or paraoxonase activity between controls and GWI.; No group differences in N-acetylaspartate concentrations in the left basal ganglia and pons. | No differences in concentrations of N-acetylaspartate were found in the basal ganglia or pons of GWI vs controls. | Multiple comparisons without correction.

Abbreviations: BOLD=Blood-Oxygen-Level-Dependent; CBF=Cerebral Blood Flow; DLPFC=Dorsolateral Prefrontal Cortex; EEG=Electroencephalogram; GWI=Gulf War Illness; fMRI=functional Magnetic Resonance Imaging; PSC=Percent Signal Change

### Autonomic Nervous System

Table 5 provides results of the 5 studies examining various autonomic nervous system biological measures, including cardiovascular measures (using an electrocardiogram [ECG] or tilt-table test)^42–46^ and nervous system measures (using nervous conduction/reflex testing).^44,45^ There were biological measures in each of the studies that differed significantly between cases and controls.

Three studies examined primarily cardiovascular biological measures. In 1 study (N=184),^42^ measurement of heart rate with an ECG over 24 hours indicated increased randomness of beat-to-beat heart rate changes (measured by the short-term fractal scaling exponent [DFA1]) in the CMI group versus control group (1.28±0.16 versus 1.35±0.15; p=0.005). In the second study focused on cardiovascular measurements, (N=27)^43^ maximum heart rate variation (p<0.05) and maximum heart rate response to tilt (p<0.05) in a tilt test plus isoproterenol was greater in cases than controls. A study examining cardiorespiratory and metabolic responses to maximal exercise test found no difference in exercise capacity between GWVs with Chronic Fatigue Syndrome (CFS) and healthy GWVs controls.^46^

Two studies examined both cardiovascular and nervous system biological measures. In a 2013 (N=97) study,^44^ 24-hour heart rate variability (HRV) using an ECG was measured in 16 healthy Veteran controls and 3 other groups stratified by symptom domains (n=66): Syndrome 1 (impaired cognition, n=21); Syndrome 2 (confusion/ataxia, n=24); and Syndrome 3 (central neuropathic pain, n=21). High frequency HRV increased normally at night in control group, but not in syndrome groups (p<0.001). The syndrome groups had reduced distal postganglionic sudomotor function compared to controls. In the quantitative sensory tests, the confusion/ataxia group (Syndrome 2) had increased cooling detection threshold versus controls (p<0.05). A 2014 cross-sectional study (N=28)^45^ examined changes in blood pressure and heart rate (using a tilt-table test), nerve conduction, sensory testing, and sudomotor axon reflex testing in self-reported post-exertional fatigue (PEF, also known as post-exertional malaise [PEM]) versus controls. There was no significant difference in blood pressure, but there was in supine (p=0.003) and standing (p<0.001) heart rate between groups at baseline. There were no significant differences in thermal or vibration threshold testing on hands and feet, or large fiber nerve variables on sural sensory and peroneal motor nerves.

Only 2^42,46^ of the 5 studies used a “gold standard” definition for GWI/CMI/CFS (CDC or Kansas), with the others using ICD-9 codes,^43^ self-report^45^ for post-exertional fatigue, or another validated (Haley) definition/characterization of GWI^44^ as criteria for inclusion into the study. The sample sizes were relatively small: 2 studies had fewer than 30 total participants,^43,45^ 1 had fewer than 100,^44^ and 1 had fewer than 200 Veterans.^42^

Table 5 Results of Gulf War Illness Autonomic Nervous System Biological Measure Studies

Biological Measure/Outcome Measure; n GWI vs n comparator | Detailed Results; GWI vs control | Summary of Findings | Study Limitations
24-hr HRV, urinary catecholamines and cortisol, hypertension, insulin sensitivity, dyslipidemia, body fat, bone mineral density, and ultrasensitive CRP^42^; 184 (n=73 with CMI) vs 111 | Adjusted Least Squares Mean difference (95% CI):; HR: 1.85 (−0.76 to 4.45). p=0.16; SDNN (SD of the N-N interval): −6.64 (−16.64 to 3.35). p=0.19; SDNN index: −0.07 (−0.16 to 0.02). p=0.14; VLF: −0.15 (−0.32 to 0.03). p=0.10; LF: −0.15 (−0.36 to 0.06). p=0.16; DFA1 (short-term fractal scaling exponent): −0.03 (−0.07 to 0.01). p=0.03; HPA measures: Plasma and 24-hour urinary cortisol levels following overnight dexamethasone suppression testing did not differ between groups. | Values for a nonlinear heart-rate-variability parameter (the short-term fractal scaling exponent [DFA1]) were lower in cases than controls, but there were no group differences in HPA measures (cortisol levels following dexamethasone suppression testing). | Sample not representative of whole GW population, distribution of biological measure data not reported, there were significant descriptive differences that were not adjusted for, enrollment non-response rate not reported, unclear if outcome assessor was blinded.
Heart rate, blood pressure^43^; 14 vs 13 | Positive tilt response: not different between the 3 groups (p=0.098).; 70-degree head-up tilt: Maximum heart rate response to tilt was higher in the fatigued GWVs than in each of the control groups (p<0.05).; Maximum HRV was highest in the GWVs fatigued group (p<0.05).; No group difference in fall in systolic blood pressure with tilt. | Maximum heart rate response and variation to 70-degree tilt was higher in GWVs with fatigue symptoms than in controls. | Non-standard definition for GWI, sample not representative of whole GW population, sample size/power calculation not provided, distribution of biological measure data not reported, there were significant descriptive differences that were not adjusted for, enrollment non-response rate not reported.
Nerve conduction, sensory testing, sudomotor axon reflex testing^45^; 16 vs 12 | Cardiovascular measures:; BP: no differences at supine, active standing, or 70 degrees tilt.; HR: greater in GWI group at 5 min supine (P<0.001) and 3 min standing (p=0.003); Absolute heart rate increment (by HUT): no difference; HRV to Valsalva maneuver and HRV deep breathing: no difference; Large and small fiber nerve variables:; No group differences for large fiber nerve variables measured on sural sensory (amplitude: p=0.598, latency: p=0.235) and peroneal (amplitude: p=0.178; latency: p=0.462) motor nerves.; No difference between groups in averaged sweat volume from the feet.; Quantitative sensory testing:; No group difference for thermal (hands [left, right]: p=0.625, p=0.582; feet: p=0.491, p=0.925) and vibration (hands [left, right]: p=0.076, p=0.402; feet: p=0.500, p=0.031) threshold on hands and feet. | Greater supine and standing heart rates in cases versus controls, but no differences in neurological measures (large fiber nerve variables, or in thermal or vibration thresholds on hands and feet). | Definition for GWI other than CDC/Kansas used, sample not representative of whole GW population, sample size/power calculation not provided, there were significant descriptive differences that were not adjusted for, distribution of biological measure data not reported, enrollment non-response rate not reported, unclear if outcome assessor was blinded.
CASS, and high-frequency heart rate variability from a 24-hour ECG^44^; 66 (syndromes 1, 2, 3: 21, 24, 21) vs 16 | CASS: varied across groups (p=0.45) and was higher in syndrome 2 than controls (p=0.02). Syndrome groups had reduced distal postganglionic sudomotor function in the foot (p=0.02), ankle, and upper leg, but not in the arm, compared to controls. No group differences in tear production, sympathetic adrenergic function, or pupillary measures.; Quantitative Sensory Tests: Syndrome 2 increased cooling detection threshold vs controls (p<0.05). No group difference on heat pain threshold.; Circadian variation in parasympathetic tone: High frequency HRV increased normally at night in control group, but not syndrome groups.; High frequency HRV during the day for syndrome 1 not different from controls, but syndrome 2 significantly lower, and syndrome 3 significantly higher. | GWI groups had neurological differences from controls, with reduced distal postganglionic sudomotor function in the foot, and increased cooling detection threshold in syndrome 2, as well as cardiovascular differences from controls, with abnormal HRV at night, and lower and higher high frequency HRV during the day for syndromes 2 and 3, respectively. | Definition for GWI other than CDC/Kansas used, sample size/power calculation not provided, distribution of biological measure data not reported, enrollment non-response rate not reported.
Cardiorespiratory and metabolic responses to maximal exercise test^46^; 19 v 19 | Maximal oxygen uptake: 28.9 (6.7) mL/kg/min vs 30.8 (7.1) mL/kg/min; p=0.39; Heart rate: 155.8 (16.1) bpm vs 163.3 (14.9) bpm; p=0.17; Exercise time: 9.6 (1.5) minutes vs 10.2 (1.4) minutes; p=0.26; Workload achieved: 208 (36.7) W for CFS vs 224 +/− 42.9 W for controls; p=0.25; Submaximal intensities: ND (p > 0.05); *W=workload | No difference in exercise capacity between CFS and healthy controls. | Small, non-representative sample, data modeling not addressed, multiple comparisons without adjustment, response rate not reported.

Abbreviations: BP=Blood Pressure; BPM=Beats Per Minute; CASS=Composite Autonomic Severity Score; CDC=Centers for Disease Control and Prevention; CFS=Chronic Fatigue Syndrome; CI=Confidence Interval; CMI=Chronic Multisymptom Illness; CPTh=Cold Pressor Threshold; CRP=C-reactive Protein; ECG=Electrocardiogram; GI=Gastrointestinal; GW=Gulf War; GWI=Gulf War Illness; GWV=Gulf War Veterans; HPA=Hypothalamic-Pituitary-Adrenal Axis; HPTh=Heat Pain Threshold; HR=Heart Rate; HRV=Heart Rate Variability; HUT=Head-Up Tilt; LF=Low Frequency; ND=No Difference; SD=Standard Deviation; VLF=Very Low Frequency

### Genetic Biological Measures

Table 6 provides results of the 1 study examining associations between genetic measures and GWI. This study (N=190) of paraoxonase (PON1) genotypes and levels of PON1 activity in serum detected slightly lower levels of PON1 activity among Veterans with GWI, though the difference was not statistically significant (median difference 23.1; 95% CI=−27.7 to 73.9).^47^ This study examined genotype variants resulting from amino-acid substitutions at positions 55 and 192, which are associated with different levels of enzymatic activity on various substrates. No difference in the distribution of PON1-192 genotypes was observed (p=0.52). The L to M substitution of PON1-55 occurred more frequently among healthy GWVs (61.9%) compared with Veterans with GWI (41.2%), and the difference was statistically significant (p=0.02). Statistical correction for multiple comparisons was not performed, and the applicability of this study may be further limited by the use of a non-standard case definition for GWI. Non-population-based sampling in this study limits the interpretation of findings. While there was a genetic component in some of the other studies represented in other biological system sections, studies were categorized in the genetic section if the genetic measures were the emphasis of the study. For example, a study of HLA alleles is included with the previous section on immune system biological measures.^25^

Table 6 Results of Gulf War Illness Genetic Biological Measure Studies

Biological Measure/Outcome Measure; n GWI vs n comparator | Detailed Results; GWI vs control | Summary of Findings | Study Limitations
PON1 activity and genotype^47^; 95 vs 95/85 | PON1 activity, median (range):; 145.85 (48.3–423) vs 168.92 (59.3–521); p=0.03 GWI had slightly lower PON1 activity, but not statistically significant: Mean Difference=23.1 (95% CI −27.7 to 73.9); High-Density Lipoprotein (HDL): lower in GWI; Mean Difference=0.14 (95% CI: 0.04 to 0.25); PON1 genotype:; No difference in the distribution of PON1-192 genotype (p=0.52).; Difference between ill and well groups in PON1-55 genotype (p=0.02), with a higher proportion of D-GWVs healthy with LM genotype compared with GWI. | No statistically significant differences in PON1 activity between GWI and GWVs healthy. | Non-standard case definition (SF-36) and multiple comparisons.

Abbreviations: CI=Confidence Interval; D-GWV=Deployed Gulf War Veteran; GWI=Gulf War Illness; GWV=Gulf War Veteran; HDL=High Density Lipoprotein; PON1=Paraoxonase; SF-36=Short Form-36 Question Questionnaire

### Other Biological Systems

We identified 6 studies of other biological measures of GWI not categorized under the preceding biological systems. These included: 1 study of sleep parameters,^48^ 1 study examining cholinesterase and serum cytokines,^21^ 1 of neurophysiologic markers,^50^ a study of audiovestibular function,^49^ 1 study of pain tolerance, 1 study of human herpes viruses (HHVs),^51^ and 1 study of temperature and pain thresholds.^52^ Table 7 contains these study details.

Three studies found significant differences in biological measures assessed between GWVs with GWI and controls. In a study of sleep parameters and sleep-related respiratory parameters in GWVs with GWI versus healthy GWVs, sleep parameters did not differ, but sleep-disordered breathing (measured by sleep respiratory parameters: Apnea-Hypopnea Index [AHI], Respiratory Effort Related Arousal [RERA] index, and percent flow-limited breaths) was greater in those with GWI: RERA index (p=0.018); AHI (p=0.006); percent flow-limited breaths (p<0.0001).^48^ There were also significant differences between GWI and controls within all audiovestibular testing domains in a study of audiovestibular function in GWVs with the 3 Haley-defined syndromes and healthy GWVs controls: greater GWI interocular asymmetry of gain in rotational nystagmus; diminished GWI nystagmic velocity after caloric stimulation; greater GWI interaural asymmetry of caloric response; greater GWI saccadic velocity; more frequent GWI pathologic nystagmus; greater GWI interpeak latency differences between ears; lower GWI response strength from right component of platform posturography.^49^ One study examined only differences in nervous system functioning, namely pain tolerance and threshold. A 2018 study (N=91)^52^ examined hot, cold, and ischemic pain tolerances and thresholds in GWVs with “documented” (no definition specified) GWI and gastrointestinal (GI) symptoms (n=53), GWVs with “documented” GWI and no GI symptoms (n=47), and GWVs without GWI or GI symptoms (n=38). Veterans with GWI and GI symptoms showed lower pain thresholds for each stimulus (p<0.001) compared with controls, and 20% of Veterans with GWI and GI symptom showed hypersensitivity to all 3 stimuli.

In the remaining 4 studies, there were no differences in biological measures assessed between GWVs with GWI and controls. Notably, 1 of these studies used our ideal comparator group – deployed GWVs with a non-GWI health condition (in this case, posttraumatic stress disorder [PTSD]). Compared to GWVs with PTSD (but no GWI) and 4 healthy GWVs, the GWVs with GWI (“neurologic factor”) did not have significantly different activity in the “organophosphate detoxifying” enzymes (Butyrylchoninesterase [BuChE] and PON1), that, according to the authors, suggests that organophosphate exposure is not associated with neurological symptoms of GWI.^21^ In the study of neurophysiological markers, GWVs reporting neuromuscular symptoms had no quantitative evidence of neurological disorders and were not significantly different from healthy GWVs.^50^ Finally, in a study comparing prevalence of HHVs in GWVs with CFS versus healthy GWVs, there was no difference in prevalence of HHV7 between groups.^51^

All 6 studies suffered from methodological issues. Notably, they had small sample sizes that did not provide sufficient power to detect differences or power calculations were not described, insufficient or no description of data modeling such as normality of data and outlier detection, nor adjustment for multiple comparisons. Additional issues in some studies included unequal or unreported non-response rates and outcome assessor blinding not used or reported. For these reasons, and due to the fact that there were no 2 studies addressing the same biological system and/or marker, these findings do not provide sufficient evidence for GWI association, or lack thereof, with any of these biological measures.

Table 7 Results of Gulf War Illness Other Biological Systems Biological Measure Studies

Biological Measure/Outcome Measure; n GWI vs n comparator | Detailed Findings; GWI vs control | Summary of Findings | Study Limitations
Sleep parameters and sleep-related respiratory parameters^48^; 18 v 11 | Sleep parameters:; Total sleep time: 333 (95) min vs 329 (75) min; p=0.90; Sleep efficiency: 73% (24%) vs 76% (16%); p=0.66; Sleep latency: 13 (15) minutes vs 28 (30); p=0.08; REM latency: 137 (69) minutes vs 136 (65) minutes; p=0.97; NREM 1: 29% (17%) vs 22% (14%); p=0.26; NREM 2: 48% (13%) vs 46% (11%); p=0.74; Slow wave sleep: 12% (9%) vs 1%7 (11); p=0.17; REM: 12% (7%) vs 11% (7%); p=0.73; Arousals/hour: 34 (26) vs 10 (6); p=0.006; Total stage shifts: 39 (12) vs 40 (14); p=0.89; Sleep-related respiratory parameters:; RERA index: 16 (12) vs 6 (4); p=0.018; AHI: 18 (25) vs 3 (5); p=0.006; % flow-limited: 96 (5) vs 36 (25); p<0.0001 | Significantly greater sleep-disordered breathing in Veterans with GWI: RERA index (p=0.018); AHI (p=0.006); % flow-limited (p<0.0001). No difference in sleep parameters except arousals/hour (p=0.006). | Small, non-representative sample, data modeling not adequately addressed, multiple comparisons without adjustment, response rate not reported.
Integrity of auditory pathways (inner ear through upper brain stem and vestibulocular reflex)^49^; Syndrome 1 vs 2 vs 3 vs control: 5 vs 13 vs 5 vs 10 | Sinusoidal harmonic acceleration: Greater interocular asymmetry of gain in rotational nystagmus in GWI vs controls.; Asymmetry values of 0.01, 0.02, and 0.04 Hz, differed from controls for Syndrome 1 (p=0.015), Syndrome 2 (p=0.002), but not for Syndrome 3 (p=0.8). In controls, the magnitude of asymmetry decreased monotonically, but not in any GWI groups.; Nystagmic velocity after caloric stimulation: diminished in Syndrome 3 vs controls for all 4 irrigations (cool right, p=0.02; cool left, p=0.004; warm right, p=0.009; warm left, p=0.004). Interaural asymmetry of caloric response greater in Syndrome 2 than controls (p=0.07).; Asymmetry of saccadic velocity: greater in Syndrome 2 than controls (p<0.05); Nystagmus: pathologic nystagmus in 4 ill Veterans, but none of the controls (p=0.09); Inter-side asymmetry of wave I to III interpeak latency on auditory brain stem response: wave 1 to 3 interpeak latency differences between ears greater in cases than controls (p=0.02) - in Syndromes 1 (p=0.005) and 2 (p=0.07), but not 3. Similar number of cases and controls with unilateral latencies or amplitudes exceeding normal limits.; Platform posturography: Syndrome 3 lower response strength from right and left forward components of the platform than controls (p=0.10) No difference between GWI and controls in somatosensory, visual, and visual preference ratios | Within all audiovestibular testing domains, there were differences between GWI and controls. | Haley criteria for case definition, non-representative sample, inclusion/exclusion not equally applied across groups, small sample size, blinding of outcome assessor not reported.
Cholinesterase; Serum cytokines^21^; 25 vs 14 vs 4 | Serum enzyme activity:; PON1: 577 (81) vs 479 (107) vs 518 (248) µmol/mL/min (no differences); Arylesterase: 111 (3) vs 102 (7) vs 116 (8) µmol/mL/min (no differences); Serum BuChE activity: 0.63 (0.03) vs 0.64 (0.04) vs 0.65 (0.07) µM/mL/min (no differences); Serum cytokines (Th1, Th2, and proinflammatory): both GWI and PTSD groups had serum levels ≥20% higher than highest level expressed by controls | “Neurologic factor” in GWVs not correlated with low activity of the enzymes BuChE and PON1 | Not standard case definition, small sample size (+ very small control group), comparability of cases and controls not established, non-response rate and blinding NR
Neurophysiologic assessment: nerve conduction studies; quantitative sensory and autonomic function testing; concentric needle and single-fiber EMG^50^; 49 vs 26 | Nerve conduction studies: No evidence for axonal or demyelinating peripheral neuropathy. Comparisons of motor conduction measurements from median, ulnar, and common peroneal nerves showed no major peripheral nerve abnormalities. No differences. P-values NR throughout.; Quantitative sensory and autonomic assessments: No specific abnormalities in GWI group. No differences in vibration perception, warm and cool sensory thresholds; thermoregulatory function in face and limbs, or cardiovascular reflexes.; Concentric needle EMG: Combined mean polyphasic units in the 4 muscles examined: 6.1% vs 7.7%; Duration or amplitude of MUAPs: ND; Turns analysis: 240±96 vs 299±82 turns/s (ND, p-value NR); No difference in ratio of number of turns/second to mean amplitude; Single-fiber EMG: no difference in MCD or fiber density values | Results for GWI similar to controls: Peripheral nervous system functional; no chronic denervation or myopathic abnormalities; no impulse blocking.; No evidence of peripheral neurological disorders | Not standard case definition; small sample size; unequal non-response rate
HHV6, HHV7, EBV, and cytomegalovirus^51^; 46 vs 32 | Prevalence of:; HHV6 DNA: Detected in 1 control pt.; HHV7 DNA: 22/46 (47.8%) vs 14/32 (43.8%); p=0.82; EBV DNA: Detected in 1 CFS pt.; HCMV DNA: None detected | No difference in HHV7 infection rates | No description of sampling strategy, power NR, data modeling NR and no adjustment for multiple comparisons, non-response rate NR
Heat pain threshold, cold pressor pain threshold; ischemic pain threshold and ischemic pain tolerance^52^; 100 (GWI+GI symptoms) vs 38 healthy | Heat Pain Threshold (HPTh):; GWI+GI had lower HPTh compared with GWI no GI symptoms (p<0.01) and controls (p<0.001). No significant differences between controls and GWI no GI symptoms.; Cold Pressor Test (Cold Pressor Threshold [CPTh]): GWI+GI had lower CPTh compared with GWI-no GI symptoms (p<0.01) and vet controls (p<0.001). No differences between control and GWI-no GI symptoms.; Ischemic Pain Threshold and Ischemic Tolerance Test: GWI+GI had shorter time to ischemic pain threshold (p<0.001) than controls. GWI-no GI symptoms also had significantly shorter time to ischemic pain threshold (p<0.01) compared to controls. GWI+GI had lower ischemic pain tolerance compared to controls (p<0.001). GWI-no GI symptoms also had significantly shorter time to tolerance compared to controls (p<0.01). | Veterans with GWI and GI symptoms showed lower pain thresholds to heat, cold, and tourniquet tests (p<0.001) compared with controls, and 20% of the GWI+GI vets showed hypersensitivity to all 3 stimuli. | Definition for GWI other than CDC/Kansas used, sample not representative of whole GW population, sample size/power calculation not provided, distribution of biological measure data not reported, did not adjust for multiple comparisons, enrollment non-response rate not reported, unclear if outcome assessor was blinded.

Abbreviations: AHI=Apnea-Hypopnea Index; BPM=Beats Per Minute; BuChE= Butyrylchoninesterase; CFS=Chronic Fatigue Syndrome; DNA=Deoxyribonucleic Acid; EBV=Epstein-Barr Virus; EMG=Electromyography; GWI=Gulf War Illness; GWV=Gulf War Veteran; HCMV=Human Cytomegalovirus; HHV=Human Herpesvirus; MCD=Mean Consecutive Difference; MUAP=Motor Unit Action Potential; ND=No Difference; NR=Not Reported; NREM=Non-Rapid Eye Movement; PON1=Paraoxanase; PTSD=Posttraumatic Stress Disorder; REM=Rapid Eye Movement; RERA=Respiratory Effort Related Arousal

## KEY QUESTION 3 Which ongoing or unpublished research studies examine diagnostic tests or biological measures for potential association with GWI?

Table 8 provides results of the 24 ongoing research studies examining a wide variety of potential biological measures for GWI. Five studies are looking at how GWI impacts the central nervous system in GWVs.^53–57^ Three studies^58–60^ plan to look at genetic components associated with GWI (including 1 using data from the Million Veterans Program^59^). Five studies are examining the immune system.^61–65^ One study will look at autonomic function testing in Veterans with GWI,^66^ and 10 studies are examining biological measures in other biological systems.^67–76^

Of those studies proposing to examine measurements within other biological systems, 3 include measures of mitochondrial dysfunction^67–69^ and 2 of the gut microbiome.^70,71^ The 3 studies that include measures of mitochondrial dysfunction propose to examine mitochondrial and bioenergetic impairments,^68^ peripheral mononuclear cells (PBMCs) to determine mitochondrial function,^67^ and mitochondria and peroxisome function and lipids specific to inflammation.^69^ Studies of gut microbiomes will look generally at differences in gut microbiomes between GWVs with and without GWI,^70^ and at microbes of the small intestine.^71^

The remaining studies will examine plasma proteomics;^72^ plasma metabolomes;^73^ serum analytes;^74^ associations between adrenal, immune, inflammatory and coagulation in Veterans with GWI;^75^ and XMRV, a retrovirus.^76^

For all studies with control group information available, the comparator is healthy GWVs. No study uses our ideal comparator of ill GWVs without GWI.

Of note, the VA Cooperative Studies Program (CSP) 585,^77^ also known as The Gulf War Era Cohort and Biorepository, has enrolled 1,275 Veterans. These Veterans have submitted to VA researchers blood samples to analyze for research related to health conditions and other related factors. While we were unable to identify published studies using this particular biorepository, we did identify 1 study using data from VA CSP 2006, which analyzes the genomics of Gulf War Illness.^59^

Table 8 Ongoing Studies of Biological Measures for Gulf War Illness

Details: PI; Study design; Registration/award no.; Study sponsor; Setting & status | Focus of Investigation | Anticipated Participants | GWI Case Definition; Selection criteria/population | Biological Measure/Outcome Measure
CENTRAL NERVOUS SYSTEM
Killiany, R. ^56^; Cross-sectional; W81XWH-19-1-0765; CDMRP GWIRP; Boston University Medical Campus | Chronic inflammation | 20 GWVs: 10 GWI and 10 healthy controls | Case definition: Kansas Participants will be recruited from the BBRAIN for GWI | Astrocyte and microglial activation using PET
Peskind, E. R. ^53^; Study design: NR; Project number: 1I01CX001049-01; NIH; VA Puget Sound Health Care System; Started: Jan 1, 2014; Anticipated completion: Dec 31, 2017 | Brain metabolism, neuronal damage; and abnormalities in central and peripheral systems regulating pain perception, fatigue, and sleep | NR | Case definition: NR Criteria not specified | - Cerebral glucose metabolism in brain regions relevant to cognition (eg, medial temporal lobes) using fluorodeoxyglucose-PET; - Structural and compositional structural integrity using MRI, diffusion MRI and MPF mapping; - Brain regional connectivity among nodes of the ventral and dorsal attention networks on blood oxygen level dependent functional connectivity MRI; - CSF biological measures associated with neurodegeneration (decreased Ab42, increased CSF total tau and phosphorylated tau (ptau181) and oxidative damage (increased F2-isoprostanes), and decreases in the neurotrophin, brain-derived neurotrophic factor; - Pain sensitivity by Quantitative Sensitivity Testing and impaired activation of endogenous opioids in response to Conditioned Pain Modulation; - Abnormalities in neuropeptides, neurotransmitters, hormones, and immune factors associated with pain and fatigue perception and sleep.; - Cerebral glucose metabolism in brain regions modulating sensory pain (eg, thalamus).; - Frequency of the apolipoprotein E (APOE)-e4 - allele, the microtubule associated protein tau (MAPT) H1 haplotype, the Met allele of the brain derived neurotrophic factor Val66Met variant, the Val allele of the catechol-O-methyl transferase Val158Met variant, the G allele of the mu opioid receptor 1 A118G single nucleotide polymorphism (ie, rs1799971), the Arg allele of the PON1 Gln192Arg variant, and decreased functional activity of PON1.; - DNA methylation levels in CpG Islands in the PON1, APOE, MAPT, and BDNF genes.
Steele, L. ^55^; Case-control; W81XWH-14-1-0622; CDMRP; Baylor College of Medicine; Data collection was scheduled to start in 2016 | Nigrostriatal pathway; brainstem and basal ganglia integrity | 80 GWVs with GWI; 50 healthy GWVs controls | Case definition: NR “Well-characterized” sample of 1990-91 GWVs | Corticostriatal circuit using high-resolution DTI
Sullivan, K. ^54^; Longitudinal analysis; W81XWH-19-1-0767; CDMRP GWIRP; Boston University Medical | Brain health (all major aspects) | N=100, GW Veterans 50 cases and 50 controls | Case definition: Kansas GWVs with GWI And healthy GWVs recruited from BBRAIN | CBF patterns, BBB permeability, and WM microstructural integrity using DKI and HARDI
Younger, J. W. ^57^; Cross-sectional; W81XWH-19-1-0725; CDMRP GWIRP; University of Alabama, Birmingham | Neuroinflammation | 40 GWVs (deployed): 20 GWI vs 20 healthy controls | Case definition: Kansas Recruited from existing database of individuals interested in research | Whole-brain MRSI scan metabolite concentrations: myoinositol, lactate, choline, NAA, and absolute brain temperature
GENETIC
Haley, R. ^58^; Cross-sectional; W81XWH-15-1-0672; CDMRP GWIRP; University of Texas, Southwestern Medical Center at Dallas | Whole genome gene-expression | 140 GW-era Veterans: 4 clinical groups (the 3 GWIvariants of the Factor case definition and a control group) | Case definition: CDC definition of MSI, Factor case definition subset (Haley definition); From “samples who participated in our prior studies” | Level of gene expression of the messenger RNAs and micro-RNAs in pure suspensions of T lymphocytes after stimulating aliquots with LPS or ACh
Malanoski, A. P. ^60^; Case-control; CDMRPL-17-0-GW160096; CDMRP GWIRP; Naval Research Laboratory | Epigenetics | 125 GW Veterans, 75 GWI cases, 50 controls | Case definition: Kansas, CDC case criteria obtained for comparison purposes; GWVs with GWI or healthy; participants of Boston GWIC biorepository | DNA methylation, micro RNA expression
Provencale, D. ^59^; Nested case-control; VA CSP #2006; VA MVP | Genome-wide association study | 7,500 GWI case participants; 7,500 controls GWVs (estimated) | Case definition: NR; 1990-1991 GWVs (both deployed and nondeployed) who participated in the MVP | Potential genetic risk factors for GWI utilizing SNP genotyping
IMMUNE SYSTEM
Abou Donia, M. B. ^61^; Cross-sectional + follow-up after acupuncture treatment; W81XWH-19-1-0465; CDMRP GWIRP; Duke University | Plasma/serum autoantibodies; Neural cells | 150 GWVs: 100 with GWI (50 with CFS and 50 without) and 50 healthy GWVs | Case definition: NR; NR | IgG-class autoantibodies for CNS markers in the saliva, serum, and plasma compared to correlate brain volumetric and microstructural alterations on brain imaging
James, L. ^62^; Cross-sectional; W81XWH-17-1-0677; USAMRDC; University of Minnesota, Twin Cities; Recruiting as of Oct 2018 | Genes and biological measures of immune system dysfunction | Large sample of GWVs with and without GWI: randomly selected from a DoD list of 66,229 people in MN who served GW from August 2, 1990-April 11, 1991 | Case definition: NR; NR | Genes associated with immune system functioning, and biological measures of immune system dysfunction, inflammation, and autoimmunity
Klimas, N. ^63^; Double-blind RCT; NCT02848417; SFVAFRE, Miami; Recruiting as of Mar 2020; Expected: Aug 2020 | Intervention study (nutraceuticals) – homeostatic network biological measure response to treatment | 75 Veterans with GWI | Case definition: NR; Inclusion Criteria:; - Veterans with GWI; - 35-70 years old; - Good health by medical history prior to 1990; - No diagnoses exclusionary for GWI | 1. Biological measure response to therapy using a VO2 exercise test; 2. Biological measure response to therapy using cytokine panel
Monson, N. ^64^; Nested case-control (4 groups); W81XWH-17-1-0586; CDMRP GWIRP; University of Texas, Southwestern Medical Center, Dallas | Molecular blood biological measures | Development sample (n=142): 96 cases + 46 matched controls; Replication sample (n=142): cases and controls group-matched to development sample; Longitudinal sample (n~120); Neuroinflammatory sample (n=100) | Case definition: CDC, Factor, and modified Kansas Representative of the GW-era military population in the US Military Health Survey; and a sample of clinical patients with other neuroinflammatory diseases. | Autoantigen arrays, analyte arrays, custom Luminex bead-based arrays to detect neuronal, glial, immune, and neuroinflammatory mediators with high sensitivity in plasma (cytokines, chemokines, autoantibodies, autoantigens, analytes, and other proteins); genome-wide extent of methylation of CpG sites on banked DNA
Shungu, D. C. ^65^; Case-control; W81XWH-15-1-0437; CDMRP GWIRP; Weill Cornell Medicine | Neuroinflammation, oxidative stress, and mitochondrial dysfunction | 40 GWVs: 20 with GWI vs 20 without GWI | Case definition: NR; Criteria not specified | Binding potential of the ligand with PET; glutathione, brain levels of lactate and NAA, ATP, PCr, Pi, and phosphomonoesters and phosphodiesters all with proton MRS; cerebral blood flow with arterial spin-labeling MRI. Complementary: markers of neuroinflammation and oxidative stress will also be measured in the CSF
AUTONOMIC NERVOUS SYSTEM
Barnes, J. N. ^66^; Cross-sectional; W81XWH-19-1-0381; CDMRP GWIRP; University of Wisconsin, Madison | Impaired cerebrovascular and autonomic variables, and their association with neuroimaging biological measures of cognitive decline | NR | Case definition: NR; Veterans with GWI compared with age and deployment-matched Veterans | Autonomic function testing and MRI to determine brain structure and intracranial blood flow measurements at rest and in response to physiological stress to identify cerebral circulation vascular dysfunction; impaired neurovascular coupling of blood flow with metabolic demand, and/or autonomic dysregulation
OTHER BIOLOGICAL SYSTEMS
Abdullah, L. ^69^; Case-control; NCT03082638; DoD; Roskamp Institute, Inc. Sarasota, Florida; Recruiting as of Jun 2019; Expected completion: Dec 2019 | Lipids specific to inflammation and metabolic disturbances | 100 GWVs: 50 Cases with GWI, 50 Controls without. | Case definition: Kansas Served in GW 1990-1991, with or without GWI | Lipids specific to inflammation, mitochondria and peroxisome function using mass spectrometry technologies.
Golomb, B. ^68^; Cross-sectional; W81XWH-15-1-0626; CDMRP GWIRP; UC San Diego | Mitochondrial/bioenergetic impairments | 54 GWVs: 27 with GWI vs 27 healthy controls (matched 1:1 on age, sex, ethnicity) | Case definition: Kansas and CDC; NR | (1) Appearance of mitochondria, including mt density/number; mt networks including fission/fusion or elongation, mt cristae density and patterning, plus capillary #/density (re: energy substrates to mitochondria). (2) Function of mitochondria, specifically energetic function and energetic reserve function, stages of respiratory chain function, in intact/skinned muscle fibers and in isolated mitochondria. (3) Mt Membrane and OS Measures: Mt membrane rigidity-fluidity, integrity, barrier function, vulnerability to calcium induced swelling; mt OS and apoptosis markers.; Secondary: (A) Bioenergetic: Basal fasting respiratory exchange ratio. (B) Laboratory: Platelet mt assay. Tests of OS, inflammation. (C); Exploratory: Quantitative amino acids. Coagulation activation (subset).
Keating, J. A. ^70^; Prospective cohort study; Pilot Project #CX-001574; VA CSRD; NLM5T15LM007359; VAMC, Madison, WI; Protocol published May 2019 | Gut microbiome | 52 deployed GWVs: 26 with GWI and 26 without GWI | Case definition: Modified Kansas Aged 43–75 years. Deployed to Gulf as part of Operations Desert Shield and/or Desert Storm during 1^st^ GW (1990–1991) | Microbiome analyses (weekly): Stool total genomic DNA extraction; Saliva total genomic DNA extraction Blood analyses (2 total; 1 at enrollment & 1 at 8 weeks): C-reactive protein; Flow cytometry
Kokkotou, E. ^72^; Cross-sectional; W81XWH-16-1-0528; CDMRP GWIRP; BIDMC, Boston, MA | Plasma proteome | GWI participants matched to healthy individuals and 2 different disease controls | Case definition: NR; Existing database of a recently completed RCT testing the effectiveness of acupuncture treatment in GWI (PI: Lisa Conboy). | Plasma proteome; SOMA scan
Lin, H. C. ^71^; Cross-sectional; W81XWH-09-2-0073; CDMRP GWIRP; BRINM | Small intestinal microbial community | GWI vs controls (not specified) | Case definition: NR; Participants in a GWI antibiotic treatment trial | Quantitative PCR of total microbes on small intestinal mucosal biopsy tissue
Lipkin, W. I. ^73^; Case-control; W81XWH-19-1-0398; CDMRP GWIRP; Columbia University | Discovery project to survey plasma metabolomes | 100 pts: 50 with GWI and 50 GWVs and civilian controls without GWI | Case definition: NR; Criteria not specified | Primary metabolites, biogenic amines, complex lipids, and bioactive oxylipins
Meyer, J. N. ^67^; Cross-sectional (Aim 2 longitudinal); W81XWH-16-1-0663; CDMRP GWIRP; Duke University | Mitochondrial dysfunction | 152 GWVs: 76 with GWI vs 76 without GWI | Case definition: NR; Criteria not specified | Mitochondrial parameters measured in PBMCs: mtDNA copy number and damage
Steele, L. ^74^; Multiphase case-control; W81XWH-12-1-0382; CDMRP GWIRP | Serum analytes | 2 samples of 45 GWI vs 30 healthy GWVs Then validation in 3^rd^ sample (90 GWI cases, 60 controls) | Case definition: Kansas 1991 GWVs | Panel of ~190 serum analytes: cytokines, chemokines, growth factors, hormones, hematological measures, and neurotrophic factors
Steele, L. ^75^; Case-control; W81XWH-11-1-0812; USAMRDC; Baylor College of Medicine (Moved to Baylor in 2016 – had not yet started data collection) | Multiple systems | 130 GWVs: 80 with GWI; 50 healthy controls | Case definition: NR “well-characterized” sample of GWVs | Neuroimaging (MRI, fMRI, DTI), adrenal function tests, and diverse immune, inflammatory, and coagulation measures
Sutton, R. ^76^; Cross-sectional; W81XWH-11-1-0825; CDMRP GWIRP; Yale University | XMRV (retrovirus) | ~60 pts: 30 GWI vs 30 matched controls | Case definition: NR “well-characterized” cohort of GWI Veterans and closely matched controls | XMRV in serum samples: in DNA and in XMRV-related mRNA, antibody against XMRV

Abbreviations: ACh=Acetylcholine; ATP=Adenosine Triphosphate; BBB=Blood-Brain Barrier; BBRAIN=Boston Biorepository and Integrated Network; BIDMC=Beth Israel Deaconess Medical Center; BRINM=Biomedical Research Institute of New Mexico; CBF=Cerebral Blood Flow; CDC=Centers for Disease Control and Prevention; CDMRP=Congressionally Directed Medical Research Program; CFS=Chronic Fatigue Syndrome; CNS=Central Nervous System; CpG=Cytidine-phosphate Guanosine; CSF=Cerebrospinal Fluid; CSP=Cooperative Studies Program; CSRD=Clinical Sciences Research and Development Service; DKI=Diffusion Kurtosis Imaging; DNA=Deoxyribonucleic Acid; DoD=Department of Defense; DTI=Diffusion Tensor Imaging; fMRI=functional Magnetic Resonance Imaging; GW=Gulf War; GWI=Gulf War Illness; GWIC=Gulf War Illness Consortium; GWIRP=Gulf War Illness Research Program; GWV=Gulf War Veteran; HARDI=High-Angular Resolution Diffusion Imaging; Ig-G=Immunoglobulin G; LPS=Lipopolysaccharide; MN=Minnesota; MPF=Macromolecular Proton Fraction; MRI=Magnetic Resonance Imaging; mRNA=Messenger Ribonucleic Acid; MRS=Magnetic Resonance Spectroscopy; MRSI=Magnetic Resonance Spectroscopic Imaging; MSI=Multisymptom Illness; mt=Mitochondria; mtDNA=Mitochondrial Ribonucleic Acid; MVP=Million Veteran Program; NAA=N-acetyl Aspartate; NIH=National Institutes of Health; NR=Not Reported; OS=Oxidative Stress; PBMC=Peripheral Mononuclear Cell; PCr=Creatine Phosphate; PCR=Polymerase Chain Reaction; PET=Positron Emission Tomography; Pi=Inorganic phosphate; PI=Principal Investigator; PON1=Paraoxanase; RCT=Randomized Controlled Trial; RNA=Ribonucleic Acid; SFVAFRE=South Florida Veterans Affairs Foundation for Research and Education; SNP=Single-Nucleotide Polymorphism; UC=University of California; USAMRDC=United States Army Medical Research and Materiel Command; VA=Veterans Affairs; VAMC=Veterans Affairs Medical Center; VO2=Oxygen Volume; WM=White Matter; XMRV=Xenotropic Murine Leukemia Virus-related Virus