# METHODS

## TOPIC DEVELOPMENT

The key research questions for the review were as follows:

1. Which diagnostic tests (or test combinations) are candidates for distinguishing individuals diagnosed with GWI from individuals without GWI?
2. Which biological measures have been examined for their potential association with GWI, and which among them have been shown to be associated with GWI?
3. Which ongoing or unpublished research studies examine diagnostic tests or biological measures for potential association with GWI?

Our approach was guided by our process framework, which we developed in consultation with our operational partners (Figure 1). The protocol was posted to a publicly accessible website prior to commencing the review (PROSPERO registration ID: CRD42020169099).

Figure 1 Process framework

Abbreviations: GWI=Gulf War Illness

Figure 2 Biomarker development Process

Note. Reproduced from Fall et al, 2014^16^

The biomarker development process (Figure 2; reproduced from Fall et al, 2014^16^) provides a framework from which to conceptualize the biomarkers included in our report. Key Question 1, regarding the validity of diagnostic tests, fits in the Verification and Validation stage of the diagram. Key Questions 2 and 3, regarding associations of biological measures with GWI case status, fits into the stages prior to the Verification stage.

## SEARCH STRATEGY

We conducted a primary review of the literature by systematically searching, reviewing, and analyzing the scientific evidence as it pertains to the research questions. To identify relevant articles, we searched Ovid MEDLINE, and Ovid PsycINFO, and Ovid EBM Reviews (Cochrane Database of Systematic Reviews and Cochrane Central Register of Controlled Trials) through February 20, 2020. Search strategies were developed in consultation with a research librarian, and peer reviewed by a second research librarian using the instrument for Peer Review of Search Strategies (PRESS).^17^ The search strategy included terms to identify Veterans from the Gulf War era (eg, Desert Shield, Desert Storm, Kuwait War, Operation GRANBY) combined with past and present terms to identify GWI (eg, Chronic Multisymptom Illness, Chronic Fatigue, Gulf War Syndrome). We limited our search to English-language publications but did not limit by publication status or study design. To identify in-progress or unpublished studies, we searched ClinicalTrials.gov and the World Health Organization (WHO) International Clinical Trials Registry Platform (ICTRP). We reviewed the bibliographies of relevant articles, contacted experts, and reviewed lists of funded trials from the Department of Defense (DoD) and Veterans Affairs (VA) to identify additional studies.

## STUDY SELECTION

Criteria for population, interventions, comparators, outcomes, timing, setting, and study design (PICOTS; Table 1) were developed in collaboration with our operational partners and Technical Expert Panel. Two reviewers independently assessed studies for inclusion based on pre-specified criteria. All discordant results were resolved through consensus or consultation with a third reviewer. Articles meeting eligibility criteria were included for data abstraction.

We defined biomarkers broadly: we included any biological measurement across a broad variety of biological functions or systems. This could include blood tests or even imaging studies. We distinguish biological measurements from other assessments such as symptom questionnaires which were excluded. We only included studies of biomarkers in humans.

For evidence on diagnostic test accuracy (Key Question [KQ] 1), we included all studies that compared a test’s classification of GWI diagnosis with any reference standard’s classification (eg, diagnosis of GWI according to Kansas or CDC/Fukuda 1998 criteria). While we recognize that there are limitations to these reference standards, they are the currently recommended and most current, widely used definitions, and a standard case definition was required to evaluate diagnostic accuracy.

For evidence on biological measures (KQ2), we included all studies that compared the prevalence or quantity of a biological measure in Veterans clinically diagnosed with GWI with Veterans without GWI (we included studies that used any case definition for KQ2). For emerging research (KQ3), we included studies with any of the above designs that are unpublished or in progress. Again, we included cases identified using any GWI diagnostic criteria.

We included studies in which the comparator populations were deployed Gulf War Veterans (GWVs) who were either healthy or had health conditions other than GWI. These groups were prioritized as they would best control for the effects of combat and exposure present in, and associated with, the conflict area. Also, these studies would be further along the biomarker development pathway and would therefore provide results more applicable to situations in which there is diagnostic uncertainty (ie, the clinical use of biomarkers would most likely be in participants who had been deployed and therefore had the potential to have GWI).

We were particularly interested in the group of GWVs with other health conditions, as differences in biological measures between this group and the GWI group could potentially help distinguish GWI cases from cases of other health conditions. In other words, it is for the Veteran with symptoms and a history of deployment that the clinical application of a biomarker would be most relevant and, therefore, studies which enrolled GWVs with symptoms (some of whom would have GWI as the cause of symptoms and others who would have symptoms secondary to another illness) are of particular interest.

We also acknowledge that other controls groups, including healthy non-Veterans or non-deployed GWVs, can help provide information about potentially pertinent biomarkers. We therefore identified a group of lower-priority studies, excluded from the main review, that are summarized in a supplementary table (Appendix D; Table 10). These were studies whose comparator groups consisted of non-deployed Gulf War-era Veterans, Veterans who were deployed elsewhere (other than Persian Gulf) during the Gulf War, civilians with other health conditions/conditions with similar symptomology to GWI (eg, chronic fatigue syndrome, neurodegenerative disorders, or musculoskeletal problems) and healthy civilian controls. We also considered studies with 25 or fewer participants as lower priority because these were likely to be too small^18^ to determine with any confidence whether or not a given measure was associated with GWI.

Table 1 PICOTS by Key Question

Key Question | KQ1. Which diagnostic tests (or test combinations) are candidates for distinguishing individuals diagnosed with GWI from individuals without GWI? | KQ2. Which biological measures have been examined for their potential association with GWI, and which among them have been shown to be associated with GWI? | KQ3. Which ongoing or unpublished research studies examine diagnostic tests or biological measures for potential association with GWI?
Population | Case definition: Veterans and civilian contractors who were deployed to the Persian Gulf region between Aug 2, 1990 and Nov 1991, and diagnosed with GWI (ie, according to either CDC/Fukuda 1998 or Kansas criteria, or other criteria). Include studies of international Veteran populations if they use any definition of GWI (limited to English-language publications).^*^
Population | Comparator populations: Gulf War-deployed Veterans with or without medical conditions other than GWI
Population | Exclude: children and birth outcomes of Gulf War Veterans
Intervention | Measures of any of the following categories of biological functions/systems that are potential loci of dysfunction:; - Genes; - Immune activation/inflammation; - Neurodegeneration; - Autonomic nervous system; - Endocrine system; - Energy metabolism; - General brain activity (central nervous system); - Other; Exclude: Assessments that do not include biological measurements (eg, questionnaires)
Comparators | Compares a test’s classification of GWI diagnosis with a reference standard’s classification (eg, diagnosis of GWI according to Kansas or CDC/Fukuda 1998 criteria). | Compares Veterans clinically diagnosed with GWI vs any comparator group (see comparator populations above)
Outcomes | Measures of diagnostic accuracy:; - Sensitivity and specificity; - Positive and negative predicative values (PPV, NPV); - Likelihood ratio; - The area under the ROC curve (AUC) | Measure of association between biological measurement and GWI | Study objectives, status, outcome measures, and available findings.
Timing | No limits
Settings | No limits
Study Design | Non-experimental, cross-sectional study; systematic reviews of diagnostic accuracy studies. | Cross-sectional, cohort, case series, and case-control studies that compare the results of a diagnostic tool, or the prevalence or quantity of a biological measure; or systematic review of such studies. | Cross-sectional study or other comparative observational study design.

* We recognize other countries may use different case definitions

Abbreviations: AUC=Area Under the Curve; CDC=Centers for Disease Control and Prevention; GWI=Gulf War Illness; KQ=Key Question; NPV=Negative Predictive Value; PPV=Positive Predictive Value; ROC=Receiver Operating Characteristic

## DATA ABSTRACTION

Data from studies meeting inclusion criteria were abstracted by 1 Evidence Synthesis Program (ESP) reviewer and were confirmed by at least 1 additional reviewer. From each study, we abstracted the following where available: study design, sample size, population characteristics, case definition, comparator(s), participant inclusion and exclusion criteria, details of the biological measure of interest, and findings for measures of association (Table 2).

If a study had multiple comparator groups, we abstracted only data that pertained to our comparators of interest: the GWI group and control participants who were deployed to the Gulf War theater in 1990-1991.

## QUALITY ASSESSMENT

Two reviewers independently assessed the risk of bias of each study. To assess the risk of bias we used an adapted version of the Newcastle-Ottawa tool for quality assessment^19^ along with adapted elements of the risk of bias tool for cross-sectional studies using biological measure data (BIOCROSS).^20^ Had we identified any studies of the validation of diagnostic tests, we would have used the Quality Assessment of Diagnostic Accuracy Studies (QUADAS)-2 tool for those studies. Disagreements were resolved by consensus or a third reviewer.

## DATA SYNTHESIS

We qualitatively synthesized the evidence and compiled evidence tables of study characteristics and findings for each key question (Table 2). We also briefly summarized information about excluded studies in Appendix D.

We did not perform a formal certainty of evidence assessment due to the heterogeneity among studies and because the intent of the review was largely to identify areas of promise for further investigation of biological measures rather than to assess the body of evidence for clinical recommendations.