# INTRODUCTION

The setting of the 1990-1991 conflict in the Persian Gulf was fraught with potential exposure to multiple toxins and stressors, including environmental and chemical exposures (eg, solvents, depleted uranium, excessive heat, oil-well fire smoke, pesticides, nerve agents and their prophylaxis, and vaccines) and psychological stressors associated with a combat setting (eg, separation from family and work, uncertainty about presence of chemical and biological agents, and witnessing dead or wounded soldiers and citizens).^1^ After the conflict, many Gulf War Veterans began reporting numerous unexplained symptoms. These symptom clusters included fatigue, headaches, joint pain, indigestion, insomnia, dizziness, respiratory disorders, and memory problems.

Clusters of symptoms were categorized into 6 definitions between 1997 and 2009.^2–7^ In 2014, the Institutes of Medicine (IoM) determined that, together, 2 definitions best captured the symptoms—the Centers for Disease Control and Prevention (CDC) and Kansas definitions.^8^ The common symptoms in all studies reviewed by the committee in the selection of the definition included reports of fatigue, pain, and neurocognitive symptoms. The CDC definition requires at least 1 symptom from 2 of 3 categories (fatigue, mood and cognition, and musculoskeletal) for 6 months or longer.^3^ The Kansas approach defines a case as having 1 moderately severe, or 2 or more chronic symptoms in at least 3 of 6 domains (including fatigue or sleep; pain; neurologic, cognitive, or mood; gastrointestinal; respiratory; and skin).^7^ The proportion of Gulf War-deployed Veterans who meet case criteria for Gulf War Illness (GWI) is approximately 34% (based on the Kansas case definition) to 50% (based on the CDC case definition).^8^

Yet these definitions remain disputed and outdated, and GWI is still a largely medically unexplained chronic multisymptom illness, due to its widely varying symptoms, reliance on self-reported symptoms for diagnosis, and lack of understanding of its pathophysiology and etiology.^9^

The identification of promising biological markers could help to refine the illness definitions; better detect, predict, or distinguish subgroups of GWI; and ultimately lead to the development of biologically plausible treatments. Identification and treatment of GWI is a top research priority for the VA Office of Research and Development (ORD). While causes of GWI symptomology and areas of biological dysfunction are unknown, investigation of biological systems underlying GWI symptomology has been partially driven by hypotheses involving exposure to acetylcholinesterase-inhibiting toxins – such as nerve agents, Pyridostigmine bromide pills, and pesticides – that are thought to contribute to dysfunction in energy metabolism (mitochondria), leading to dysfunction in cholinergic systems^10–12^ and to chronic inflammation that damages the central nervous system (CNS).^13–15^ Most studies to date have included biological markers that have focused around the biological systems (eg, central nervous system, immune system, and autonomic nervous system, as well as genes that regulate these systems) that are involved in the aforementioned hypothesized GWI mechanisms.

This systematic review provides an overview of the state of biomarker research in GWI. It is not intended to directly guide clinical care but is intended to help future research planning efforts by summarizing what the field has already examined and by identifying any potentially promising areas of biomarker research. We examined the literature to identify studies of the use of biomarkers as a diagnostic test for GWI, and also to identify studies that evaluated the differential expression of biomarkers among participants with and without GWI.