# EXECUTIVE SUMMARY

## AIM

We conducted a systematic review to catalogue studies (both published and unpublished/ongoing) of validated biological tests for diagnosing GWI and studies of associations between biological measures and GWI for their promise as biomarkers.

## METHODS

We searched electronic databases (Ovid MEDLINE, and Ovid PsycINFO, and Ovid EBM Reviews [Cochrane Database of Systematic Reviews and Cochrane Central Register of Controlled Trials]) through February 20, 2020 for all observational studies of diagnostic tests of GWI and completed or ongoing studies of associations between biological measures and GWI. To identify in-progress or unpublished studies, we searched ClinicalTrials.gov and the World Health Organization (WHO) International Clinical Trials Registry Platform (ICTRP). We reviewed the bibliographies of relevant articles, contacted experts, and reviewed lists of funded trials from the Department of Defense (DoD) and Veterans Affairs (VA) to identify additional studies.

We included studies of biological measures that have been examined for their promise as diagnostic biomarkers for and/or their association with GWI. We included completed and ongoing/unpublished studies of Veterans with GWI, identified using any GWI diagnostic criteria, in which the comparator population members were Veterans deployed to the Persian Gulf theater during the First Gulf War who did not develop GWI, with or without comorbid conditions (eg, posttraumatic stress disorder, anxiety). We excluded studies of Veterans with GWI compared to other populations (eg, non-deployed Gulf War Veterans, civilians), and those with insufficient sample sizes (N<25) but did summarize these studies in the Appendix to the full report.

For all included studies, we abstracted data on study design, sample size, population characteristics, case definition, comparator(s), participant inclusion and exclusion criteria, details of the biological measure of interest, and findings for measures of association as available. Data abstraction was confirmed by a second reviewer. Two reviewers independently assessed the risk of bias of included studies using established methods. Discordant ratings were resolved by consensus or an additional reviewer.

## RESULTS

We identified no studies of diagnostic tests for GWI. We identified 56 studies of associations between GWI and biological measures (32 completed and 24 ongoing or unpublished).

### Key Question 1 Which diagnostic tests (or test combinations) are candidates for distinguishing individuals diagnosed with GWI from individuals without GWI?

We did not identify any studies validating tests of biomarkers that distinguish cases of GWI from non-cases, regardless of the diagnostic criteria used in the study.

### Key Question 2 Which biological measures have been examined for their potential association with GWI, and which among them have been shown to be associated with GWI?

We identified 32 studies of biological measures that have been examined for their association with GWI and grouped them broadly into categories under distinct biological systems: 10 studies of immune system biological measures; 10 central nervous system (CNS) studies; 5 studies of autonomic nervous system (ANS) biological measures; 1 of genetic biological measures; and 6 studies of biological measures in other biological systems (See Figure i). We also briefly summarized an additional 77 studies that examined biological measures, but do not include an ideal control group (n=72 studies) or had a sample size less than 25 (n=5 studies; See Appendix D of full report), indicated in the grey areas in Figure i.

Only 1 included study used a comparator population of deployed GWVs with health conditions other than GWI; in all other studies health conditions were not reported and participants were presumed healthy.

All studies had additional methodological shortcomings. Biological measures were heterogeneous across studies, even those categorized within the same biological system, with the exception of 2 studies that had 1 replication study each.

### Key Question 3 Which ongoing or unpublished research studies examine diagnostic tests or biological measures for potential association with GWI?

We did not identify any ongoing/unpublished studies examining diagnostic tests for GWI. We found 24 ongoing or unpublished studies examining biological measures for their potential association with GWI. Similar to the completed studies many are investigating measures of the immune and central nervous system (see Figure i).

Figure i Number of studies of GWI biological measures by biological system

Abbreviations: ANS=Autonomic Nervous System; CNS=Central Nervous System; KQ=Key Question

## CONCLUSION

In the current review, we sought to evaluate studies validating existing diagnostic tests for GWI, and to determine whether biological measurements with promise for further establishment as biomarkers either in completed or ongoing/upcoming studies have been demonstrated. The establishment of biological measures for GWI would allow for increased accuracy in diagnosis and potential mechanisms for treatment.

Our review indicates that there are no existing validated biological tests to determine GWI case status. It is not surprising that no such studies were found, because the case definition for GWI is still debated. In the absence of a gold standard definition or diagnostic test, the determination of biological measures to distinguish a case from a non-case is challenging.

We did identify many studies that have assessed, or are currently assessing, the potential association between a variety of biological measures and GWI. Most of the studies could be characterized as “biomarker discovery” studies and were largely designed to shed light on the potential causes of GWI. Our review indicates that biological measures within the immune and central nervous systems have more often been investigated for their potential relationship with GWI, consistent with some dominant theories of disease etiology and dysfunction, but the literature also suggests other avenues of inquiry in upcoming studies, such as the gut microbiome. More importantly, our review revealed that existing studies are insufficient for determining promising biomarkers due to the extent of heterogeneity in biological measures across studies, inadequate comparator groups, and several other methodological limitations. Future studies that employ ideal control groups, reproduce findings of existing studies, and otherwise apply rigorous methodological practices and reporting specifically appropriate for investigating potential biomarkers would contribute to the establishment of a base of targeted, highly reliable studies from which lines of investigation could grow.

## ABBREVIATIONS TABLE

Abbreviation: Definition
AA: Arachidonic Acid or African American
ACE: Angiotensin-Converting Enzyme
ACh: Acetylcholine
ADP: Adenosine Diphosphate
AHI: Apnea-Hypopnea Index
AHRQ: Agency for Healthcare Research and Quality
ANA: Antinuclear Antibody
ANS: Autonomic Nervous System
apoAI: Plasma Apolipoprotein AI
ASA: Anti-Squalene Antibody
ASL: Arterial Spin Labelling
ATP: Adenosine Triphosphate
AUC: Area Under the Curve
BBB: Blood-Brain Barrier
BBRAIN: Boston Biorepository and Integrated Network
BDNF: Brain-Derived Neurotrophic Factor
BIDMC: Beth Israel Deaconess Medical Center
BOLD: Blood-Oxygen-Level-Dependent
BP: Blood Pressure
BPM: Beats-Per-Minute
BRINM: Biomedical Research Institute of New Mexico
BuChE: Butyrylchoninesterase
CASS: Composite Autonomic Severity Score
CBF: Cerebral Blood Flow
CCEP: Comprehensive Clinical Evaluation Program
CDC: Centers for Disease Control and Prevention
CDMRP: Congressionally Directed Medical Research Program
CFS: Chronic Fatigue Syndrome
CI: Confidence Interval
CMAP: Compound Motor Action Potential
CMI: Chronic Multisymptom Illness
CNDP1: Carnosine Dipeptidase 1
CNS: Central Nervous System
CO2: Carbon Dioxide
CpG: Cytidine-Phosphateguanosine
CPTh: Cold Pressor Threshold
CRP: C-Reactive Protein
CSF: Cerebrospinal Fluid
CSP: Cooperative Studies Program
CSRD: Clinical Sciences Research and Development Service
CV: Conduction Velocity
D-GWV: Deployed Gulf War Veteran
DF: Degrees of Freedom
DHA: Docosahexaenoic Acid
DKI: Diffusion Kurtosis Imaging
DLPFC: Dorsolateral Prefrontal Cortex
DNA: Deoxyribonucleic Acid
DoD: Department of Defense
DTI: Diffusion Tensor Imaging
dUTPase: Deoxyuridine Triphosphate Diphosphatase
EBV: Epstein-Barr Virus
ECG: Electrocardiogram
ECL: Electrochemiluminescence
EEG: Electroencephalograph
ELISA: Enzyme-Linked Immunosorbent Assay
EMG: Electromyography
ERP: Event Related Potential
ESP: Evidence Synthesis Program
FM: Fibromyalgia
fMRI: Functional Magnetic Resonance Imaging
GI: Gastrointestinal
GW: Gulf War
GWI: Gulf War Illness
GWIC: Gulf War Illness Consortium
GWIRP: Gulf War Illness Research Program
GWV: Gulf War Veteran
HARDI: High-Angular Resolution Diffusion Imaging
HCMV: Human Cytomegalovirus
HDL: High-Density Lipoprotein
H-FABP: Heart-type Fatty Acid Binding Protein
HHV: Human Herpesvirus
HLA: Human Leukocyte Antigen
HPA: Hypothalamic-Pituitary-Adrenal
HPTh: Heat Pain Threshold
HR: Heart Rate
HRV: Heart Rate Variability
HUT: Head-Up Tilt
IBS: Irritable Bowel Syndrome
ICA: Independent Component Analysis
ICD-9-CM: International Classification of Diseases, Ninth Revision, Clinical Modification
IFN: Interferon
Ig: Immunoglobulin
IL: Interleukin
IoM: Institutes of Medicine
IPF: Immature Platelet Fraction
IQuESt: Center for Innovations in Quality, Effectiveness and Safety
KQ: Key Question
LF: Low Frequency
LLOD: Lowest Level of Detection
LPC: Lysophosphatidylcholines
LPE: Lysophosphatidylethanolamine
LPS: Lipopolysaccharide
MAP: Multi-Analyte Profile
MCD: Mean Consecutive Difference
ME: Myalgic Encephalitis
MEG: Magnetoencephalograph
MiRNA: Micro Ribonucleic Acid
MMP: Matrix Metalloproteinase
MN: Minnesota
MPF: Macromolecular Proton Fraction
MPV: Mean Platelet Volume
MR: Magnetic Resonance
MRI: Magnetic Resonance Imaging
mRNA: Messenger Ribonucleic Acid
MRS: Magnetic Resonance Spectroscopy
MRSI: Magnetic Resonance Spectroscopic Imaging
MSD: Meso Scale Discovery
MSI: Multisymptom Illness
mt: Mitochondria
mtDNA: Mitochondrial Deoxyribonucleic Acid
MUAP: Motor Unit Action Potential
MUFA: Monosaturated Fatty Acids
MVP: Million Veteran Program
NAA: N-acetyl Aspartate
NCM: Neurocutaneous Melanocytosis
NCT: National Clinical Trial
ND: No Difference
NIH: National Institutes of Health
NPV: Negative Predictive Value
NR: Not Reported
NREM: Non-Rapid Eye Movement
OR: Odds Ratio
ORD: Office of Research and Development
OS: Oxidative Stress
PBMC: Peripheral Mononuclear Cell
PC: Phosphatidylcholine
PCr: Creatine Phosphate
PCR: Polymerase Chain Reaction
PE: Phosphatidylethanolamine
PEF: Post Exertional Fatigue
PEM: Post Exertional Malaise
PET: Positron Emission Tomography
Pi: Inorganic Phosphate
PI: Principal Investigator or Phosphatidylinositol
PICOTS: Population, Intervention, Comparator, Outcome, Timing, Setting, and Study Design
PL: Phospholipid
PON1: Paraoxanase 1
PPV: Positive Predictive Value
PRP: Platelet-Rich Plasma
PSC: Percent Signal Change
PSG: Polysomnograph
PTSD: Posttraumatic Stress Disorder
PUFA: Polyunsaturated Fatty Acids
RCT: Randomized Controlled Trial
REM: Rapid Eye Movement
RERA: Respiratory Effort Related Arousal
RNA: Ribonucleic Acid
ROC: Receiver Operating Characteristic
SD: Standard Deviation
SEM: Standard Error of the Mean
SF-36: Short Form-36 Item
SFA: Saturated Fatty Acids
SFVAFRE: South Florida Veterans Affairs Foundation for Research and Education
SNP: Single-Nucleotide Polymorphism
SPRC: Standardized Partial Regression Coefficient
TCR: T-Cell Receptor
TEP: Technical Expert Panel
TNF: Tumor Necrosis Factor
TPO: Plasma Thrombopoietin
TRAP: Thrombin Receptor Agonist Peptide
UC: University of California
UK: United Kingdom
US: United States
USACHPPM: United States Army Center for Health Promotion and Preventive Medicine
USAMRDC: United States Army Medical Research and Materiel Command
VA: Veterans Affairs
VAMC: Veterans Affairs Medical Center
VHA: Veterans Health Administration
VLF: Very Low Frequency
VO2: Oxygen Volume
WM: White Matter
XMRV: Xenotropic Murine Leukemia Virus-Related Virus