# APPENDIX E PEER REVIEW COMMENTS/AUTHOR RESPONSES

Reviewer number | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | No - See detailed comments--needs to be clearer conceptually
4 | Yes
5 | Yes
6 | Yes
Is there any indication of bias in our synthesis of the evidence?
1 | No
4 | No
5 | No
6 | No
Are there any published or unpublished studies that we may have overlooked?
1 | Yes - I don’t know, but I would guess that requiring the 2 IOM-approved definitions might exclude the best studies, which would be done in a very sick group of GWI patients vs controls. It is impossible to get anywhere with GWI using the Kansas and CDC definitions because they include a very diverse, mostly not very sick, very large groups of veterans. | Regardless of case definition restrictions, we found no studies that could answer KQ1, so no studies were excluded based on case definition for KQ1. We agree that the CDC and Kansas definitions include a heterogeneous group of symptoms and do not specify symptom severity. Also, a larger challenge that restricts our review and the GWI research is that CDC and Kansas case definitions are currently recommended for use in research to identify GWI, so the preponderance of studies use one of these as their criteria. We acknowledge this challenge in the discussion.
4 | No
5 | Yes; - VA Million Veterans Program consisting of biological samples and clinical data from thousands of GW veterans.; - VA Cooperative Studies Program 585 - various studies using a repository including blood specimens (serum, buffy coat, DNA) from hundreds of GW veterans. | We identified one study^58^ from the VA Million Veterans Program. This study was also part of the VA CSP 2007.; Unfortunately, upon reviewing publications and products from the CSP 585 program, we were unable to identify published studies meeting our selection criteria.
6 | No
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
1 | OVERVIEW; Clearly a thorough report and largely a good review of the included studies. However, the report could be improved in several ways, and some of the methods used are not well-justified. More detail might help, but the biggest concern is that the report is conceptually weak.; Some concerns are: | Thank you.
1 | 1) using adherence to the CDC and Kansas definitions as a criterion for inclusion; conceptually, if you are after a biomarker related to “symptoms” or severity or course, you would not want to use a general sample of the very nonspecific CDC and Kansas definitions | Our justification for this requirement was that there needs to be a gold standard of case definition to evaluate diagnostic accuracy. We recognize that there are limitations to these case definitions, but they are currently what is recommended and widely used. Because we did not find any studies to include for KQ1, this restriction of case definition did not result in the exclusion of any studies. For KQ2, we were very inclusive of diagnostic criteria.
1 | 2) as above, the investigators do not seem to have a coherent conceptual approach to evaluating biomarkers. The conceptual framework (Figure 1) is not really conceptual--it is merely a graphic saying who the populations, interventions, and measures are. | We have clarified that Figure 1 is not a conceptual model, rather a graphic showing our PICOTS and KQs. We have added an additional figure (Figure 2), which provides an overview of the diagnostic test/biomarker development process, which guided our conceptualization of how our KQs and report fit into the biomarker development pipeline.
1 | The use of “measures of diagnostic accuracy” as an outcome is out of date; diagnostic tests should be evaluated based on a framework that considers technical, diagnostic, and therapeutic impacts, not just “measures of diagnostic accuracy”. | We agree that a diagnostic test should be able to both accurately diagnose a condition as well as give insight to potential therapies to use and therapeutic impacts. The latter two, however, are far beyond the discovery phase of how a given biomarker (or group of biomarkers) are associated with the presence or absence Gulf War Illness. While conceptually including therapeutic impacts would be an important property of a biomarker practically, there were no studies that were far enough along the diagnostic test development pipeline to be able to comment on clinical utility.
1 | Similarly, “association between symptoms and biological measures” is not a valid basis for evaluating a biomarker. (This sentence is also in the background section, p7) What does “association with symptoms” mean? Association with the severity of illness? Association with the types of symptoms? This is conceptually unclear and incomplete. | To date there have only been studies that have taken a biological measurement and assessed its association with GWI or its symptoms. The literature is not at a stage where we can evaluate the diagnostic and clinical utility of biomarkers for GWI. Furthermore, studies were somewhat broad in how they identified GWI and examined associations. For example, some studies may simply categorize as “symptomatic” GWV. For clarity, we have changed “symptoms” to “GWI” in the report.
1 | Because the report isn’t clear about the type of evaluation they are interested in, it is also unclear what an ideal study of the question they have in mind would be. Would it evaluate a biomarker to predict a response to treatments or the risk of a complication? Before criticizing the studies that were included (and excluded) it is important to lay out what the target is, and I could not figure out what the target was. | KQ1: Target was accurate case identification between those with GWI and those with some other illness (which no studies existed, so we could not critique them). We specified in the Study Selection which studies we included which identifies which studies we were interested in.; KQ2 : Target was biological markers that are associated with GWI case status and should thus be validated or researched further for potential GWI diagnostic test candidates (many of these studies existed so we could critique them on methodological rigor). The parameters of the included studies for KQ2/3 are also described in the Study Selection section.; The inclusion criteria lay out specifically what types of studies we were looking for.
1 | The background section, then, should provide a much clearer description of what the authors are looking for in a biomarker--the sentence “…studies of associations between biological measures and GWI status for potential development of biomarker tests..” should end with at least one possible use of a biomarker other than distinguishing GWI from non-GWI. I think a reasonable goal would be to find a marker that was associated with the severity of illness, its course, or suitability for various treatments, but I cannot tell what the authors had in mind. | Severity of illness, illness course, and suitability for various treatments are all important outcomes, but per the agreed upon a priori KQ?s, we were focused on a test’s ability to identify the presence or absence of GWI, not to predict its course.
1 | Conceptually, the report should also distinguish between “discovery” studies and validation studies of biomarkers. | We agree, this is an important distinction and have added language and a figure to help us clarify this difference.
1 | 1. p12 line 7 “meeting inclusion criteria” line 45 “initial inclusion criteria” : Why “initial” criteria? Were there additional versions of the criteria? It is unclear what “initial” is meant to convey. | Thank you for pointing this out. We have removed “initial” so that the sentence now reads: “Those studies that met inclusion criteria other than including a priority comparator group (72 studies), and/or…”
1 | 2. p14 line 11 “We did not identify any studies that met the criteria for inclusion for Key Question 1.” This may be the least informative way to convey the results of search and selection! For anyone but systematic reviewers, this sentence would make more sense if it spelled out what you mean--eg, “We did not find any studies that compared a test’s classification of GWI to a reference standard and reported measures of diagnostic accuracy.” As it stands, the literature flow chart provides no information about which studies were candidates for KQ1 and why they didn’t qualify--the KQs are not distinguished until the last step in the flow diagram. The audience for this report needs to understand whether there were studies that aspired to be about diagnosis but did not meet your criteria, and why. A clearer type of flow for KQ1 would itemize the characteristics of these candidate studies so a reader could see, eg, that among studies in the right population, that evaluated an intervention, how many dropped because of a lack of an appropriate comparator or measure (outcomes). Also, it is concerning that the “comparator” is a disputed reference standard. Where there is no adequate gold standard test or diagnostic criteria, a better “comparator” is what happened to the patient over time. | Thank you. We spelled out, as suggested, and indicated that no studies addressing the validity of diagnostic tests, regardless of comparator type, were found.; We agree that the lack of an agreed upon gold standard makes finding the ideal comparator group difficult. We did identify one prospective case-control study, all others were cross-sectional.; We have also updated the literature flow chart to more clearly portray the studies removed for lack of priority comparator or small sample size.
1 | 3. The section about quality assessment lacks important details. It would be helpful for the authors to describe the ideal study for each of the key questions. Then explain or justify the choice of instrument they used. For KQ1, the relevance of the Newcastle-Ottawa tool escapes me. If the plan was to evaluate diagnostic accuracy studies, why wouldn’t something like QUADAS-2 be appropriate? Also, BIOCROSS is not a quality appraisal (“risk of bias”) tool, it assesses the quality of reporting, not of the science or study itself, so it should not be described as “the quality appraisal tool for cross-sectional studies using biological…” Overall I could not make out how the tool (Newcastle-Ottawa+items from BIOCROSS) could be used to assess the quality of either diagnostic accuracy studies or cross sectional studies of biomarkers. Considering that the end of the report summarizes limitations of the studies, there seems to be a mismatch between the instruments you used to assess the studies and the problems you found with them. The mismatch might be because you included studies that might be described as “discovery” studies but assessed “risk of bias” as if they were clinical studies.; Regarding the ideal study, the material on pp54ff describing the problems of the literature would be much stronger if, up front, you described a study that would be strong. | The QUADAS-2 tool is used for diagnostic tests, though none of our studies actually examined a diagnostic test, so the QUADAS-2 would be largely irrelevant. We added to the Quality Assessment section indicating that had we found studies of validity of diagnostic tests, we would have used the QUADAS-2.; We modified the language associated with BIOCROSS, as suggested.; Most of the studies that were identified were cross-sectional or case-control studies and looked for associations between GWI case status and a specified set of biomarkers. For this reason, we believe the Newcastle-Ottawa items were the most applicable. We did note some limitations with the Newcastle-Ottawa tool, which is why we used this descriptive approach rather than a definitive rating of ROB.; We agree with your comment about describing the ideal study and have added a description of what an ideal diagnostic test study would like.
1 | 4. The report doesn’t give me confidence that what was excluded was not of interest and what was included was of interest; that is, the authors need to show why applying these PICOTS does not exclude material of interest. It is by no means obvious that these PICOTS make sense. Why would studies that don’t relate to CDC or Kansas be excluded? Wouldn’t that close off research that could demonstrate there is a better definition? Those instruments are said to be the “best” for what the IOM was interested in, but case definition, research definition, and other criteria might be best for studying biomarkers.; The approach of “included” studies vs “excluded” studies also doesn’t serve the purpose of the review very well, at least without more detail about what was excluded. A landscape of the 270 potentially relevant studies could be useful--make a table of how many of these evaluated each biomarker (similar to Figure 3, but for the 270 studies). In a review intended to inform a state of the science conference, it is important to describe what has been studied. You might show, eg, that there were 30 studies of energy metabolism, only 2 of which were included. | For KQ1, we did not find any studies testing validity of diagnostic tests, regardless of the case definition used for the comparator group, so we did not miss any studies by using these criteria. We have added language in the report to describe this as well.; For KQ2/3, we have expanded upon the table of 72 studies that were not included in the body of the report either due to n<25, a non-ideal comparator group (i.e., comparator groups other than deployed GWV without GWI and with or without other health conditions. We have added to the table heading this description of what was included.
1 | 5. p54 “To establish a biological metric capable of making this distinction would require biological measures to be compared between cases versus individuals without GWI and with other health conditions with overlapping symptomology with GWI. The ability of a biologic measure to distinguish GWI when comparing patients with symptoms to healthy patients without symptoms may not translate to its ability to distinguish GWI from another illness in patients presenting with symptoms (which is more typically the context in which a diagnostic test would be used).” These sentences are confusing. You have 2 goals here--one is to explain when healthy controls are not appropriate, and the other is what to do instead. Again, this section should start with your view of what a good study would look like, then contrast what you found with it. This must be done because putting out there what a good study would look like will establish conceptually what you are measuring the actual studies against. Do healthy controls have any role in evaluation at all? I would say they do--as an early test, a discovery test, it could be useful to see which markers differ from sick and well people. Next, you would want to do a different kind of study, perhaps still retrospective, with comparisons to other illnesses (as you say). Then, if a biomarker passes these phases, the best design is prospective and in a prospective study one doesn’t pick cases and controls at all--one identifies a cohort of patients in whom GWI is suspected, and then applies the marker, and then follows up to see who is actually diagnosed with GWI (preferably without knowledge of the biomarker result). The people who are not diagnosed with GWI may be diagnosed with something else or may be undiagnosed. So these sentences are really only about studies that pick cases and controls, and they imply that instead of healthy controls, investigators should pick people with (known) other illnesses. That isn’t really always the case--it is only a step in the early evaluation of a biomarker. | We have added to the description of the ideal study. We also added a description of the potential utility of the table of other studies.
1 | Minor comments; 1. p24 lines 13-17. Do phospholipids come in “species”? This may be the right term but it is new to me. | Thank you. Yes, it seems that different phospholipids can be referred to as “species”. This was the terminology used in the study.
1 | 2. The actual writeups of studies on pages 23-24 and pp29-30 is quite good, but some studies, particularly ref 28 and 42, merit a more detailed critique in the text. | For reference 28 and 42 we have added additional detail.
1 | 3. p24 line 42 “reporting’ should be ‘report” I think | Thank you. We changed “reporting” to “reported” where indicated.
4 | 1. I’m concerned you threw some of the baby out with the bath water by excluding the 72 studies with non-priority comparator groups. Is there nothing that can be learned by including those studies in this review, perhaps in a separate category and then triangulating the findings with findings from the studies with better comparator groups? This is especially important in the field of GWI research given the paucity of data, the frustration with the lack of progress in its understanding, and the amount of resources expended. | We have expanded on the table of 76 studies to include study findings and indication of whether or not there were statistically significant findings related to associations between GWI and biological measures.
4 | 2. Almost all included studies were cited for not providing adequate power calculations. When differences were reported between groups (KQ2), was there not, empirically speaking, adequate power to detect a difference? When there was no difference, I understand how a power calculation is critical in assessing whether the study contributes to our understanding. Also, is it sometimes possible to calculate the power from the results and methods reported in the publication? If so, did the review team do this? | We request from future studies certain information that would increase the consumer’s ability to determine level of confidence in the findings. Our conclusions were not greatly influenced by lack of methodological information like this. More heavily weighted factors were the great heterogeneity in biological measures and the comparator group.
4 | 3. I concur that subgroup analysis is a vital strategy to better understanding the diverse symptoms afflicting Gulf War Veterans with Gulf War Illness. I do not think the Haley subsyndromes should be promoted as a standard approach for doing this, however. The subsyndromes were developed on a small cohort and have not been replicated. I do not recall exactly at the moment, but I believe the sample size was so small that even if randomly selected from the population (which they may not have been), they are likely not representative of the population. The 2014 VA/DoD Clinical Practice Guideline for the Management of Chronic Multisymptom Illness used the labels fatigue-, GI- and pain-predominant CMI which correspond to CFS, IBS, and FM. This labelling has been abandoned in the current draft of the 2020 update to that CPG, but still has clinical relevance. I’m not suggesting this approach, but merely highlight that the subgroups of GWI are also far from settled. | Thank you. We changed the language to recommend a stratification similar to the Haley categorizations, without recommending Haley categorizations specifically.
4 | 4. I appreciate the discussion (pp. 54-55) of the need for a comparison group with similar symptoms to GWI, but have some questions. Many such potential comparison groups have biomarkers that would differentiate them from GWI. Why then would a biomarker for GWI established compared to a healthy group, not be of value if it is different from the biomarker for a condition with similar symptoms? For example, if we were to select multiple sclerosis (MS) as the appropriate symptomatic comparison group for GWI, there are already biomarkers that differentiate GWI from MS. If we found a marker for GWI compared to healthy comparators that is different from the markers for MS, we wouldn’t confuse GWI and MS with that biomarker any more than we currently do. It would be a remarkable advance in the diagnosis and care of Veterans with GWI. Also, what other conditions would be suitable comparison groups for GWI in general? Using this approach, one would likely only find a biomarker for pain, or fatigue, or cognitive deficits or whatever the symptom of focus is in GWI, not for the constellation of chronic multiple symptoms. Do your findings lead you to conclude that is the best approach? | We agree that a study to examine a healthy control compared to GWI could shed some light on biomarkers that could be researched further for a diagnostic biomarker for GWI. Thus, we have expanded upon the Appendix Table D to provide more information about studies including healthy controls, including findings. Still, we prioritized studies with comparators that would give us the most useful information about a biomarker as a GWI diagnostic tool. Specifically, an ideal biomarker would enable us to differentiate GWI from another illness.
4 | 5. On p. 55 there is a discussion of the general lack of information in the included studies about the distribution of the data and outliers and how they were handled. I assume this is a matter of degree, but most of these were peer reviewed; are you holding these studies to too high a standard? Or are you extracting information from studies that focused on reporting other findings and therefore these were not held to a high enough standard? In other fields/conditions, are comparable studies reported in a manner more consistent with the standards you applied? | We hope that our synthesis provides some guidance for how biological marker research might be more transparent in their reporting, that would increase the consumer’s ability to determine level of confidence in the findings. Our conclusions were not greatly influenced by lack of methodological information such as the handling of outliers. More heavily weighted factors were the great heterogeneity in biological measures and the comparator groups included in the studies
4 | 6. Finally, are there NO specific areas that seem promising for differentiating, even at a group level, Veterans with GWI from Veterans without GWI after this review? If you had to pick one or two where we should invest resources, which would they be? | The emphasis of our review was to map out what biomarkers have been studied. Had there been strong enough evidence in any one direction, we would highlight that. We attempted to synthesize the larger biological systems in which the majority of the extant research had focused,, but we were unable to identify any specific biomarkers with sufficient strength of evidence.
5 | Minor correction on p.51 row 37, NR should be Steele, L. | Thank you. We made the suggested adjustment.
5 | Minor correction on p.56 row 57, The US Army Medical Research and Material Command should read The US Army Medical Research and Development Command. | Thank you. We made the suggested adjustment.
5 | General Comments:; Included studies were limited to those with 1) a comparator population of deployed healthy or deployed with health conditions other than GWI and 2) greater than 25 participants. The following are concerns with this limitation:
5 | 1) Because there is currently no objective, evidenced-based case definition of GWI, selection of the reported “ideal” comparator group (GWV without GWI and with a condition with overlapping symptoms) is problematic. | We agree the lack of a gold standard is problematic and has both hindered the field’s ability to develop and validate a biological test for GWI and hindered our ability to comment on the ability of such a biomarker to distinguish those with GWI from those without GWI (KQ1). We were very inclusive of case definitions of GWI for KQ2 and 3. Further, we have expanded upon the table of excluded studies to provide additional information such as findings from studies that included a comparator besides a healthy, deployed GWV.
5 | 2) Participants selected from the same battalion was considered a limitation; however, given reported exposure differences depending on deployment location, branch of service, etc. subgrouping may in fact be a reasonable approach to biomarker research rather than a one size fits all approach to this multi-symptom illness. It is likely there will not be a single diagnostic criteria or tool. Future consideration of further GW Veteran subgrouping, including by molecular characteristics, may facilitate biomarker discovery and would allow for use of smaller sample sizes. | Thank you. We agree that inclusion of individuals from the same battalion, some who developed GWI and sone who did not, could provide important and nuanced insights about how GWI develops, etc. Our rationale for calling this a limitation, was in the context of considering how the findings of one study might be applicable or generalizable to a larger group (in evidence synthesis, this is known as applicability). We do acknowledge in the discussion, the importance of subgrouping this complex and heterogenous illness.
5 | 3) Many clinical biomarker studies in the GWI field are exploratory, as the underlying pathobiology of the illness is still being discovered (primarily in preclinical systems). An evidence-based framework is necessary prior to pursuing larger scale clinical validation. Therefore, a goal of many early clinical biomarker investigations is refinement of existing hypotheses rather than testing validity. These investigations provide a platform to generate preliminary data and give direction to future investigations. It would be worthwhile to pursue an evaluation of excluded studies that did not meet the comparator and group size threshold, but that show promise for replication and future validation. This would allow prioritization of the most promising pathways/potential diagnostics going forward. | We have expanded upon the table of excluded studies to include findings and indication of statistical significance in the association between biological measures and GWI.
5 | 4) The GW Veteran population is limited with respect to recruitment. Unlike disease fields where there are new cases each year, the deployed 1990-1991 Gulf War population is relatively small and difficult to recruit. Compounding effects of aging in this population create additional obstacles. These confounding variables should be taken into consideration when determining an appropriate sample size, particularly for exploratory and pilot translational studies. Again, appropriate subgrouping (and potentially smaller group sizes) may be the most reasonable approach. | We have expanded upon the table of excluded studies to include findings and indication of statistical significance in the association between biological measures and GWI.
5 | Observation - The lack of outcome assessor blinding may reflect financial shortfalls in technical expertise, database management, and biostatistical assistance. This is an important consideration for GWI research funders. | Thank you for this insight. We have added a comment about this in our discussion.
5 | The strategic and specific funding mechanism pipeline implemented by the DoD CDMRP GWIRP in FY19 will aid translation of research in this area. A description of this strategy could be considered for the Future Research section. FY20 and beyond, the GWIRP will be continuing this funding pipeline composed of 1) a discovery stage representing innovative biomarker research that is in the earliest stages of development; 2) a qualification stage representing research already supported by preliminary or published data in the GWI field that is ready for validation through expansion, replication, or comparative studies; 3) a verification stage representing clinical translation (testing in a GW Veteran population) of concepts previously replicated and validated; and 4) a confirmation stage representing large-scale confirmatory and pivotal trials that will transform and revolutionize the clinical management of GWI. Objective biomarkers to measure the biological effect of an intervention or predictive/cohort-selective biomarkers are required in the conformation stage. This promotes biomarker and diagnostic assay development and validation simultaneously with testing of new treatments instead of as separate steps in the development process. | Thank you for notifying us of this strategic funding pipeline. We have added this in the future research section of the discussion.
6 | This report is a comprehensive review of studies of potential biomarkers of the Gulf War Illness, reviewing studies of GWI patients compared to deployed veterans without GWI. The report is very well written, easy to follow, and detailed and concise enough. Intro and methods look good to me. I just have a few suggestions re results and discussion: | Thank you.
6 | Results:; In table 2, all the fMRI studies measure the same thing: BOLD signal during a task, which is an indicator of changes in the activation in different areas of the brain in response to a task. So for avoiding confusion, “The biological measures examined” should be the same for all those, and can be “brain activation.” | Thank you. We have modified so that the data collection column for all fMRI studies refers to ‘brain activation’.
6 | Unsure why Zhou et al, examining pain is classified under “ANS”. There are several different mechanisms involved in pain tolerance, and ANS does not seem to be the major one. This work can come under the “Other Biological Systems” | Thank you. We moved the Zhou et al study from the ANS section to the Other Biological Systems section, as suggested.
6 | Weiner 2011, An spectroscopy study should be under “CNS” category, and not genes. | We have moved Weiner 2011 from the genetic to the CNS category, as suggested.
6 | Nagelkirk, 2003, could come under ANS. | We have moved Nagelkirk, 2003 into the ANS category.
6 | Results:; It might be helpful to add a brief paragraph in the beginning of each section (or in the intro) about why researching each of these systems (immune, ANS, CNS, etc) sounded reasonable for this illness. | We agree that it is important to put into context the involved biological systems, we included a sentence and some additional language in the introduction about the rationale and hypotheses about the involvement of each of these systems in GWI.
6 | Similarly, it might be helpful to add a couple sentences about each (or some of the less commonly known by general readers) measure addressed here. For instance: what is squalene antibody? Or what is the function of the candidate genes in genetic studies, and why were they selected? | Due to the extensive heterogeneity of studies, this level of information was not feasible to include.
6 | Discussion:; I understand the studied biomarkers are all over the place and the findings are inconsistent, but it will be helpful to address the consistencies in findings of these limited studies. For instance, HRV and ANS seem more consistent, although very limited number of studies. | As you point out, there were very few studies of any one biological measure. Because of that, the review is meant to be a map of what has been studied.
6 | Since the ongoing studies are mentioned in this report, it might be helpful to discuss how those studies might be informed by, and following (or not following) trajectory of the published studies. Is there a direction where the research seem to have been following? And what are the new areas which have not been addressed before, and why are those selected? To me there seems to be a heavier focus on neuroinflammation, plus addition of mitochondrial and gut microbiome studies. I think the above is important as an aim of this report is to help inform the future research. | We agree and have tried to synthesize this by listing the respective frequency of extant studies for each of the biological systems, to provide insight to what has and has not been studied thus far.
6 | I think one of the inherent limitations of such studies, and challenges of this field which might be worth mentioning is the time x illness interaction. The chronic illness over many years since the Persian Gulf War might have led to differences in health behaviors and lifestyle (e.g. chronically reduced activity and exercise due to fatigue, medications side effects, etc.) among GWI veterans compared to healthy controls. These differences could lead to some of the current or future detected differences (e.g. cardiovascular) which could not have been a part of the illness itself, but a consequence. In that sense, it will be important for future studies to consider such confounding variables (BMI, level of activity, comorbid psychiatric and cardiovascular disorder, medications) when researching differences between GWI and control groups. | Thank you. This is a good suggestion; we have added a sentence about this in the future research section. In addition, one of our quality assessment rating questions examined whether important confounders such as the presence of other chronic illnesses were considered during sample selection. For the immune section, there were many exclusions of those who might have chronic health conditions that would muddy the interpretation of the immunological measures included in the study. On the other hand, exclusion of those with comorbid chronic illness might become increasingly challenging as this populations ages and may miss an important part of the diagnostic test utility, which is to differentiate GWI from other conditions.