# APPENDIX D SUPPLEMENTAL MATERIAL

Table 10 Studies of Gulf War Illness Biological Measures Using Lower-priority Comparator Groups^*^ or No Comparator

Author, year | Title | Biological Measure/Outcome Measure | Findings | Findings promising?^†^
IMMUNE SYSTEM
Abou-Donia, 2017^83^ | Screening for novel central nervous system biological measures in Veterans with Gulf War Illness | Autoantibodies reactive to specified proteins | GWVs with GWI had higher had higher levels of autoantibody reactivity in all proteins examined except S-100B comparted to healthy, non-Veterans with low back pain (GFAP p b 0.001; Tau p b 0.001; MAP p b 0.002; MAG; p b 0.001; PNF p b 0.006; Tubulin p b 0.003; MBP p b 0.01; S-100B; p = 0.31) | Yes
Brimacombe, 2002^84^ | Immunological variables mediate cognitive dysfunction in Gulf War Veterans but not civilians with chronic fatigue syndrome | Patterns of cytokine/symptom relationships | A type 2 cluster of chronic fatigue syndrome plus a T and B cell factor predicted CFS cases for GWVs but not civilians with CFS, which was modulated by reaction time | Yes
Broderick, 2011^85^ | Altered immune pathway activity under exercise challenge in Gulf War Illness: an exploratory analysis | Gene expression pathways, cytokines in plasma, lymphocytes, cytotoxicity, with exercise challenge | Mutual information networks linking immune markers in GWI had more abundant connections but were less organized than non-Veteran health controls during and after exercise. | Yes
Broderick, 2018^86^ | A pilot study of immune network remodeling under challenge in Gulf War Illness | Immune markers, with exercise challenge | GWI compared to control networks of immune signaling during exercise had more abundant connections but were less organized. NPY, IL-1α, TNF-α and CD2+/CD26+ nodes were better integrated in the GWI network at rest. Under effort (t₁) these differences were replaced by significant restructuring around nodes for CD19+ B cell population, IL-5, IL-6 and soluble CD26 concentrations. | No
Diaz-Torne, 2007^87^ | Absence of histologic evidence of synovitis in patients with Gulf War Veterans’ illness with joint pain | Synovial biopsy samples | GWVI synovia (synovitis, osteoarthritis, and rheumatoid arthritis scores) did not differ from normal controls. | No
Everson, 2002^88^ | Immunological responses are not abnormal in symptomatic Gulf War Veterans | Humoral immune responses | Immune response measures in antigen presenting cells, T cells, type 1-2 T-helper cells, and B cells did not differ between GWI-symptomatic GWVs vs matched controls (asymptomatic Veterans, non-Gulf War Veterans | No
Golomb, 2019^89^ | Depressed prostaglandins and leukotrienes in Veterans with Gulf leukotrienes | Eicosanoids - prostaglandins and War Illness | Several plasma eicosanoid levels were lower in GWI vs non-Veteran controls. | Yes
Halpin, 2017^90^ | Myalgic encephalomyelitis/chronic fatigue syndrome and Gulf War Illness patients exhibit increased humoral responses to the herpesviruses-encoded dUTPase: Implications in disease pathophysiology | Antibodies against multiple human herpesviruses-encoded dUTPases and/or the human dUTPase | GWI participants had higher levels of antibodies to the HHV-6 and human dUTPases than healthy controls (p=0.0053 and p=0.0036, respectively). | Yes
Hannan, 2000^91^ | Activation of the coagulation system in Gulf War Illness: a potential pathophysiologic link with chronic fatigue syndrome. A laboratory approach to diagnosis | Coagulation and platelet activation | More GWVs with GWI (23/33) than healthy controls (0/33) had 2 or more positive scores on the Immune System Activation of Coagulation panel (p<0.001), the laboratory criterion for activation of coagulation. | Yes
Khaiboullina, 2015^92^ | Cytokine expression provides clues to the pathophysiology of Gulf War Illness and myalgic encephalomyelitis | 77 serum cytokines | A group of 77 cytokines identified myalgic encephalomyelitis (ME) and GWI with sensitivities of 92.5% and 64.9%, respectively. When ME and GWI were compared to healthy controls, the specificity was 33.3%. | No
Klaustermeyer, 1998^93^ | Allergic and immunologic profile of symptomatic Persian Gulf War Veterans | Total serum IgE levels | GWVs with allergy symptoms had higher mean IgE level (88.7 I/U/mL) than GWVs without allergy symptoms (47.5 IU/mL) | No
O’Bryan, 2003^94^ | Human leukocyte antigens in Gulf War Veterans with chronic unexplained multiple symptoms | Frequency of antigens: HLA-A, -B, -DR, -DQ | Human Leukocyte Antigen-A28 was present in 21.9% of symptomatic Veterans and 6.9% of the healthy population (p=0.01), but not significant when corrected for number of antigens determined. | No
Parkitny, 2015^95^ | Evidence for abnormal cytokine expression in Gulf War Illness: A preliminary analysis of daily immune monitoring data | Serum cytokine and chemokine concentrations | No difference in serum cytokine concentrations between GWI and healthy GWV. GWI associated with higher variability in the expression of eotaxin-1 than healthy GWVs (p<0.001). | Yes
Skowera, 2002^96^ | Antinuclear autoantibodies (ANA) in Gulf War-related illness and chronic fatigue syndrome (CFS) patients | Antinuclear Autoantibodies | No difference in prevalence of antinuclear autoantibodies between symptomatic GWV, healthy GWV, symptomatic Bosnia and Era Veterans, chronic fatigue syndrome patients, and health control subjects. | No
Smylie, 2013^97^ | A comparison of sex-specific immune signatures in Gulf War Illness and chronic fatigue syndrome | Cytokine markers with exercise challenge | No differences between GWI and controls indicated. Differences in cytokine markers by sex. | No
Tsilibary, 2018^98^ | Human Immunoglobulin G (IgG) Neutralizes Adverse Effects of Gulf War Illness (GWI) Serum in Neural Cultures: Paving the Way to Immunotherapy for GWI | Human IgG | Cell spreading was lower in GWI than control (p=4.4 × 10^−34^). GWI apoptosis was higher than control (=−6.91 × 10^−24^) | Yes
Vojdani, 2004^99^ | Cellular and humoral immune abnormalities in Gulf War Veterans | Percentage of immunological markers | Percentage of T cells in symptomatic GWV(sGWV) v. controls not different. More sGWVs had elevated T cells than controls. More B cells in sGWVs v controls. Natural Killer cell activity decreased in patients (24.8 ± 16.5 lytic unit) v controls (37.3 ± 26.4 lytic unit). Immune complexes increased in patients (53.1 ± 18.6, mean ± SD) v controls (34.6 ± 14.3). Autoantibody titers directed against myelin basic protein and striated or smooth muscle greater in sGWVs v control. | Yes
Whistler, 2009^100^ | Impaired immune function in Gulf War Illness | Immune cell function with exercise challenge | Differences for 3 Natural Killer cell subsets and Natural Killer cytotoxicity between GWI and controls (p<0.05). | Yes
Zhang, 1999^101^ | Changes in immune parameters seen in Gulf War Veterans but not in civilians with chronic fatigue syndrome | Lymphocyte subpopulations, cytokine gene expression | Veterans with chronic fatigue syndrome had more total T cells and MHC II^+^ T cells and higher percentage of these lymphocyte subpopulations, and lower percentage of Natural Killer cells, than controls. Also had higher levels of IL-2, IL-10, IL-10, IFN- (symbol), and TNF-(alpha symbol) than controls. | Yes
CENTRAL NERVOUS SYSTEM
Alshelh, 2020^102^ | In-vivo imaging of neuroinflammation in Veterans with Gulf War Illness | [11C]PBR28 PET/MRI | GWI had higher cortical [11C]PBR28 PET signal in precuneus, prefrontal, primary motor, and somatosensory cortices compared to both healthy non-Veterans and healthy Veterans. No group differences in inflammatory cytokines. | Yes
Baraniuk, 2005^103^ | A Chronic Fatigue Syndrome - related proteome in human cerebrospinal fluid | Proteomes in cerebrospinal fluid | Pooled chronic fatigue syndrome and GWI samples contained proteins in the cerebrospinal fluid not detected in the control sample: α-1-macroglobulin, amyloid precursor-like protein 1, keratin 16, orosomucoid 2 and pigment epithelium-derived factor. | Yes
Chao, 2014^104^ | Associations between subjective sleep quality and brain volume in Gulf War Veterans | Cortical, lobar gray matter, and hippocampal volumes | Global Pittsburgh Sleep Quality Index was associated with total cortical and frontal gray matter volume in GWV, and, in the frontal lobe, total Global Pittsburgh Sleep Quality Index was inversely associated with the superior and middle frontal, orbitofrontal, anterior cingulate, and frontal pole volumes. | No
Chao, 2019^105^ | Do Gulf War Veterans with high levels of deployment-related exposures display symptoms suggestive of Parkinson’s disease? | Total basal ganglia volume | GWI had lower total basal ganglia volume than healthy deployed Veterans. | Yes
Christova, 2017^106^ | Subcortical brain atrophy in Gulf War Illness | Subcortical brain atrophy | GWI had subcortical brain atrophy compared to healthy controls. | Yes
Clarke, 2019^107^ | Connectivity differences between Gulf War Illness (GWI) phenotypes during a test of attention | Exercise challenge: brain activation (fMRI BOLD response) | Unique brain activation connectivity patterns between control and GWI groups. Controls had an exercise task related network of right dorsolateral and left ventrolateral prefrontal cortex, dorsal anterior cingulate cortex, posterior insulae and frontal eye fields. GWI subgroup with brain stem atrophy and postural tachycardia after exercise had activity in the dorsal anterior cingulate cortex with direct links to basal ganglia, anterior insulae, and right dorsolateral prefrontal cortex notes. GWI subgroup with stress test originated phantom perception had submodules of basal ganglia-anterior insulae, and dorsolateral prefrontal executive control regions. | Yes
Concato, 2007^108^ | Acetylcholinesterase activity in Veterans of the first Gulf War | Acetylcholinesterase activity | Acetylcholinesterase activity was similar for Veterans with versus without GWI. | No
Engdahl, 2016^109^ | A Magnetoencephalographic (MEG) Study of Gulf War Illness (GWI) | Synchronous neural interactions | Differences in synchronous neural interactions between GWI and healthy controls centered in the cerebellum and frontal cortex. | Yes
Georgopoulos, 2017^110^ | Gulf War Illness (GWI) as a neuroimmune disease | Synchronous neural interactions | GWI synchronous neural interactions did not differ from relapse-remitting multiple sclerosis, Sjogren’s syndrome, or rheumatoid arthritis, but did differ from control, schizophrenia, Alzheimer’s disease, post-traumatic stress disorder, and major depressive disorder. | Yes
Gopinath, 2019^111^ | Exploring brain mechanisms underlying Gulf War Illness with group ICA based analysis of fMRI resting state networks | Resting state fMRI | Impaired functional connectivity in GWI between language networks, sensory input networks, motor output networks, between different sensory perception and motor networks, and between different networks in the sensorimotor domain. | Yes
Haley, 1997^112^ | Evaluation of neurologic function in Gulf War Veterans. A blinded case-control study | Neurophysiological, audiovestibular, neuroradiological, blood cell count, erythrocyte sedimentation rate | GWI had greater inter-side asymmetry of the wave I to wave III interpeak latency of brain stem auditory evoked potentials, greater interocular asymmetry of nystagmic velocity on rotational testing, increased asymmetry of saccadic velocity, more prolonged interpeak latency of the lumbar-to-cerebral peaks on posterior tibial somatosensory evoked potentials, and diminished nystagmic velocity after caloric stimulation bilaterally. | Yes
Haley, 2000^113^ | Brain abnormalities in Gulf War syndrome: evaluation with 1H MR spectroscopy | N-acetyl aspartate-to-creatine ratio, measuring neuronal mass | N-acetyl aspartate-to creatine (NAA/Cr) ratio (functional neuronal mass) was lower in the basal ganglia and brainstem of GWVs than in control participants (p=0.007). | Yes
Haley, 2009^114^ | Abnormal brain response to cholinergic challenge in chronic encephalopathy from the 1991 Gulf War | Brain response to cholinergic challenge; normalized regional cerebral blood flow | Baseline normalized regional cerebral blood flow in chronically ill GWVs was lower than controls throughout deep structures. | Yes
Hubbard, 2014^115^ | Central Executive Dysfunction and Deferred Prefrontal Processing in Veterans with Gulf War Illness | Brain activation (BOLD fMRI) during working memory task | GWI deferred prefrontal cortex activity from encoding to retrieval for high demand conditions. | Yes
Jamal, 1996^116^ | The “Gulf War syndrome”. Is there evidence of dysfunction in the nervous system? | Peripheral nerve function | Three measures of peripheral nerve function were abnormal in Veterans compared to controls: cold threshold (p=0.0002), sural nerve latency (p=0.034), and median nerve sensory action potential (p=0.030). | Yes
James, 2017^117^ | Human Leukocyte Antigen (HLA) and Gulf War Illness (GWI): HLA-DRB1 13:02 Spares Subcortical Atrophy in Gulf War Veterans | Volume of cerebellar gray matter | Human leukocyte allele DRB1^*^12:02 spared subcortical brain atrophy in GWVs and subcortical volume was higher in carriers of the allele, and in cerebellar grey matter. | Yes
Li, 2011^118^ | Hippocampal dysfunction in Gulf War Veterans: investigation with ASL perfusion MR imaging and physostigmine challenge | Hippocampal regional cerebral blood flow | Decreased hippocampal regional cerebral blood flow with physostigmine challenge in control subjects (p<0.0005) and Veterans with syndrome 1 (impaired cognition) (p<0.05), and increased in syndrome 2 (confusion-ataxia) (p<0.005) and syndrome 3 (central neuropathic pain) (p<0.002). | Yes
Menon, 2004^119^ | Hippocampal dysfunction in Gulf War Syndrome. A proton MR spectroscopy study | N-acetyl aspartate to creatine and choline to creatine ratios | The N-acetyl aspartate/creatine ratio of the GWI group was lower that control group. | Yes
Moffett, 2015^120^ | Word-finding impairment in Veterans of the 1991 Persian Gulf War | Brain activation (BOLD signal fMRI) during cognitive task | GWI group had reduced activity in the thalamus, putamen, and amygdala, and increased activity in the right hippocampus relative to controls | Yes
Rayhan, 2013^121^ | Prefrontal lactate predicts exercise-induced cognitive dysfunction in Gulf War Illness | Brain activation with exercise challenge | GWI who had decreased working memory performance after exercise had elevated prefrontal lactate levels compared to GWI who had increased performance. | Yes
Rayhan, 2013^122^ | Exercise challenge in Gulf War Illness reveals 2 subgroups with altered brain structure and function | Brain activation (BOLD fMRI) with exercise challenge | GWI subgroup with orthostatic tachycardia correlated with brainstem atrophy, baseline working and memory compensation in the cerebellar vermis. The other GWI subgroup that developed exercise- induced hyperalgesia was associated with cortical atrophy and baseline working memory compensation in the basal ganglia. | Yes
Rayhan, 2013^123^ | Increased brain white matter axial diffusivity associated with fatigue, pain and hyperalgesia in Gulf War Illness | White matter diffusivity properties | GWI had increased axial diffusivity in the right inferior frontal-occipital fasciculus, but not in controls. | Yes
Rayhan, 2019^124^ | Exercise challenge alters Default Mode Network dynamics in Gulf War Illness | Brain activation patterns with exercise | GWI had increase in deactivation patterns within the Default Mode Network following exercise that was not seen in controls. | Yes
Tillman, 2017^125^ | Electrophysiological correlates of semantic memory retrieval in Gulf War Syndrome 2 patients | Brain activation (ERP) with cognitive task | GWI had an event-related potential difference between memory retrieval and no memory retrieval stimuli at the midline parietal region that had a scalp voltage polarity opposite from that recorded at the left temporal area that was not present in controls. | Yes
Turner, 2016^126^ | Cognitive Slowing in Gulf War Illness Predicts Executive Network Hyperconnectivity: Study in a Population-Representative Sample | Brain activation (BOLD fMRI) during cognitive task | Bilateral dorsolateral prefrontal cortex connectivity with task-relevant notes was altered in GWI participants compared to healthy controls during processing speed task. | Yes
Washington, 2020^127^ | Exercise alters cerebellar and cortical activity related to working memory in phenotypes of Gulf War Illness | Brain activity with working memory task/exercise | GWI with stress test associated reversible tachycardia has post-exertional deactivation of cerebellar dentate nucleus and vermis regions associated with working memory. GWI stress tests originated phantom perception had activation of the anterior supplementary motor area. | Yes
Wylie, 2019^128^ | Fatigue in Gulf War Illness is associated with tonically high activation in the executive control network | Brain activation (BOLD fMRI) with cognitive challenge | GWI had greater activation than healthy controls in frontal and parietal areas for less difficult cognitive tasks. | Yes
AUTONOMIC NERVOUS SYSTEM
Falvo, 2018^129^ | Dynamic cerebral autoregulation is impaired in Veterans with Gulf War Illness: A case-control study | Cerebral blood flow responses to physostigmine challenge | Greater decreases in cerebral blood flow both a nadir and after standing and during steady state standing in GWI vs controls. Dynamic autoregulation was lower in GWI than controls. Cerebrovascular reactivity was not different between groups. | Yes
Fiedler, 2004^130^ | Responses to controlled diesel vapor exposure among chemically sensitive Gulf War Veterans | Responses to diesel vapor exposure: Heart rate, blood pressure, respiration rate, end-tidal CO(2) | GWI had reduced end-tidal CO2 after exposure to diesel and petrochemical fumes compared to controls and were physiologically hyporeactive in response to behavioral tasks administered during, but not before, exposure. | Yes
Haley, 2004^131^ | Blunted circadian variation in autonomic regulation of sinus node function in Veterans with Gulf War syndrome | Heart-rate variability by 24-hr electrocardiography, ambulatory blood pressure, Valsalva ratio, sympathetic skin response, sweat imprint test measures | GWI had less increase (1.2-fold) in high-frequency spectral power of heart rate variability during sleep compared to normal increase (2.2-fold) in controls. In GWI, it was lower at night, higher in morning, but no difference from controls during rest of the day. GWI heart rate declined less at night and corrected QT intervals were longer over 24 hours, particularly at night. | Yes
Peckerman, 2000^132^ | Cardiovascular stress responses and their relation to symptoms inGulf War Veterans with fatiguing illness | Hemodynamic responses to stressors | Veterans with chronic fatigue had diminished blood pressure responses during cognitive stress tests due to unusually small increases in total peripheral resistance. Similar blood pressureresponses to cold pressor test in Veterans with chronic fatigue and healthy Veterans. | Yes
Stein, 2004^133^ | Sex effects on heart rate variability in fibromyalgia and Gulf War Illness | Heart rate variability | No group differences in heart rate variability. | No
GENETIC
Baraniuk, 2017^134^ | Exercise-induced changes in cerebrospinal fluid miRNAs in Gulf War Illness, Chronic Fatigue Syndrome and sedentary control subjects | MicroRNAs in cerebrospinal fluid | No group differences in microRNAs in cerebrospinal fluid. After exercise, GWI Stress Test Originated Phantom Perception participants had lower miR-22-3p than control and GWI Stress Test Activated Reversible Tachycardia, but higher miR-9-3p than Stress Test Originated Phantom Perception participants. | Yes
Craddock, 2015^135^ | Using gene expression signatures to identify novel treatment strategies in Gulf War Illness | Gene Expression Signatures | Found 19 functional modules with significantly altered gene expression patterns in GWI. | Yes
Liu, 2018^136^ | Detecting Chromosome Condensation Defects in Gulf War Illness Patients | Chromosome condensation defects | In GWI, 3 subtypes of Defective Mitotic Figures. Another type of condensation defect identified as sticky chromosomes were observed. | Yes
Mackness, 2000^137^ | Low paraoxonase in Persian Gulf War Veterans self-reporting Gulf War Syndrome | Paraoxonase | GWVs paraoxon hydrolysis was less than 50%of that found in controls. Serum PON1 concentration was lower in GWV. No group difference in rate of diazoxon hydrolysis. | Yes
NCT00810225, 2008^138^ | Study of Gulf War Illness (GWI) by Comparing GWI and Healthy Veterans | CNDP1 gene, cerebrospinal fluid proteome contents | N/A | N/A
Steele, 2015^139^ | Butyrylcholinesterase genotype and enzyme activity in relation to Gulf War Illness: preliminary evidence of gene-exposure interaction from a case-control study of 1991 Gulf War Veterans | Butyrylcholinesterase Genotype and Enzyme Activity | No difference between GWI and controls in mean butyrylcholinesterase (BChE) enzyme activity level or BChE genotype. | No
Trivedi, 2019^140^ | Alterations in DNA Methylation Status Associated with Gulf War Illness | DNA methylation patterns in peripheral blood mononuclear cells | Global DNA methylation levels not different in GWI v controls. Genome-wide assessment indicated hypermethylation in GWI in 88% of CpG sites across gene regulatory elements and within coding regions. | Yes
Urnovitz, 1999^141^ | RNAs in the sera of Persian Gulf War Veterans have segments homologous to chromosome 22q11.2 | Amplicons | Genetic alterations in the 22q11.2 region in GWI. | Yes
Vladutiu, 2004^142^ | Association of medically unexplained fatigue with ACE insertion/deletion polymorphism in Gulf War Veterans | Frequency of mutant alleles associated with metabolic myopathies or genetic variation associated with physical performance | Increased risk for chronic fatigue syndrome/idiopathic chronic fatigue was associated with alterations of the insertion/deletion polymorphism in the angiotensin-converting enzyme gene in GWV. The I allele frequency was decreased in affected vs unaffected Veterans. The II genotype was decreased 4-fold in affected Veterans DD genotype was increased 2-fold. | Yes
OTHER
Bacterial
Nicolson, 2003^143^ | High prevalence of Mycoplasma infections in symptomatic (chronic fatigue syndrome) family members of Mycoplasma-positive Gulf War Illness patients | Presence of bacterial infection | Over 80% of GWI who were positive for blood mycoplasma infections had only 1 Mycoplasma spp., M. Fermentans, vs healthy controls with 8.5% incidence of mycoplasma | Yes
Biochemical Pathways
Naviaux, 2019^144^ | Metabolic features of Gulf War Illness | Abnormalities in biochemical pathways, surveyed via broad-spectrum serum metabolomics | GWI, compared to healthy controls, had abnormalities in 8 of 46 biochemical pathways. Lipid abnormalities accounted for 78% of the metabolic impact. | Yes
Circulatory System
Falvo, 2018^145^ | Abnormal rheological properties of red blood cells as a potential marker of Gulf War Illness: A preliminary study | Red blood cell deformability and aggregation | Red blood cells were more deformable in GWI, as indicated by higher elongation indices particularly at higher shear stress values when compared to matched controls. | Yes
Energy Metabolism
Chen, 2017^146^ | Role of mitochondrial DNA damage and dysfunction in Veterans with Gulf War Illness | Mitochondrial DNA damage and dysfunction | Mitochondrial DNA lesion frequency and mitochondrial DNA copy number were elevated in GWI vs controls. | Yes
Koslik, 2014^12^ | Mitochondrial dysfunction in Gulf War Illness revealed by Phosphorus Magnetic Resonance Spectroscopy: a case-control study | Calf muscle phosphocreatine | Post-exercise phosphocreatine-recovery time constant was prolonged in GWI vs controls. | Yes
Gastrointestinal
Lin, 2009^147^ | Bacterial Overgrowth Associated with Chronic Multisymptom Illness Complex | Hydrogen and methane in breath | The proportion of Fusobacteria in the was increased in GWI vs controls in the jejunum. In the ileum, Proteobacteria were reduced in GWI vs controls. | Yes
Nervous System
Fletcher, 2010^148^ | Plasma neuropeptide Y: a biological measure for symptom severity in chronic fatigue syndrome | Neuropeptide Y in plasma | Plasma neuropeptide Y elevated in chronic fatigue syndrome participants vs controls and GWI. | Yes
Khan, 2004^149^ | Peripheral cholinergic function in humans with chronic fatigue syndrome, Gulf War syndrome and with illness following organophosphate exposure | Skin blood flow responses to iontophoresis of acetylcholine and of methacholine | Response to acetylcholine was higher in participants with chronic fatigue syndrome than controls, but normal in GWI and those exposed to organophosphates. The methacholine response was higher than acetylcholine response in all patient groups compared to controls except for those with chronic fatigue syndrome. | Yes
Respiratory
Lindheimer, 2019^150^ | Veterans with Gulf War Illness exhibit distinct respiratory patterns during maximal cardiopulmonary exercise | Ventilatory variables (minute ventilation, respiratory frequency, tidal volume) in response to maximal cardiopulmonary exercise | Ventilator variables measured during exercise stress test indicated minute ventilation was not different but tidal volume was greater and respiratory frequency was lower in GWI than controls. | Yes
Skeletal
Compston, 2002^151^ | Reduced bone formation in UK Gulf War Veterans: a bone histomorphometric study | Bone measures: cancellous bone area, mineral apposition rate, mean wall width, bone formation rate at tissue level | Measures from iliac crest bone biopsies showed that cancellous bone area was lower in GWVs vs healthy controls, and this was associated with reduced mineral apposition rate, mean wall width, and bone formation rate at the tissue level. | Yes
Pessler, 2008^152^ | A histomorphometric analysis of synovial biopsies from individuals with Gulf War Veterans’ Illness and joint pain compared to normal and osteoarthritis synovium | Histologic, immunohistochemical, and vascular measures in synovial biopsies | Measures from synovial biopsies indicated no difference between GWI and healthy controls in histologic appearance. | No
Various
NCT00810329, 2008^153^ | Proteomics of Cerebrospinal Fluid in Chronic Fatigue Syndrome | Proteins in cerebrospinal fluid, cerebrospinal pressure, ANS function, pulmonary function, pain threshold, allergic response | N/A - ongoing | N/A - ongoing

* Priority comparator groups=Deployed GWVs without GWI, with or without other health conditions. See main report for studies using priority comparator groups. This table includes studies of biological measures in GWVs with GWI (loosely defined) compared to other groups, or with no comparator group.

† Yes=Indication by statistical significance of association of a biological measure with GWI case status; No=No indication by statistical significance of association of a biological measure with GWI case status

Abbreviations: ACE=Angiotensin-Converting Enzyme; ANA=Antinuclear Antibody; ANS=Autonomic Nervous System; ASL=Arterial Spin Labelling; BOLD=Blood-Oxygen-Level-Dependent; CFS=Chronic Fatigue Syndrome; CNDP1=Carnosine Dipeptidase 1; CO_2_=Carbon Dioxide; dUTPase=Deoxyuridine Triphosphate Diphosphatase; DNA=Deoxyribonucleic Acid; ERP=Event Related Potential; fMRI=functional Magnetic Resonance Imaging; GWI=Gulf War Illness; HLA=Human Leukocyte Antigen; ICA=Independent Component Analysis; IgE=Immunoglobulin E; IgG=Immunoglobulin G; MEG= Magnetoencephalograph; miRNA=Micro Ribonucleic Acid; MR=Magnetic Resonance; MRI=Magnetic Resonance Imaging; NCT=National Clinical Trial; PET=Positron Emission Tomography; UK=United Kingdom

Table 11 Gulf War Illness Biological Measure Studies with Insufficient Sample Size (N<25)

Study Author, Year | Title | Biological Measure/Outcome Measure | Findings | Findings promising?^*^
IMMUNE SYSTEM
Broderick, 2013^154^ | Exploring the Diagnostic Potential of Immune Biomarker Co-expression in Gulf War Illness | Projection model based on markers of endocrine and immune function | Increases in neuroendocrine-immune signaling and inflammatory activity in GWI with decreased apoptotic signaling associated with exercise stress test. | Yes
CENTRAL NERVOUS SYSTEM
Bunegin, 2001^155^ | Cognitive performance and cerebrohemodynamics associated with the Persian Gulf Syndrome | Middle cerebral artery blood flow velocity with acetone challenge | No difference in pulmonary function tests between GWI and controls breathing clean air or 40 ppm acetone in air. Middle cerebral artery blood flow velocity increases for each of clean air, clean air placebo, and mixture of air and acetone were different between groups. | Yes
Haley, 2000^156^ | Effect of basal ganglia injury on central dopamine activity in Gulf War syndrome: correlation of proton magnetic resonance spectroscopy and plasma homovanillic acid levels | Functioning neuronal mass (N-acetyl-aspartate to creatine ratio) | Homovanillic acid: 3-methoxy-4-hydroxyphenlyglycol was inversely associated with functioning neuronal mass in the left basal ganglia but not the right. | Yes
GENETIC
Latimer, 2020^157^ | Preliminary Evidence for a Hormetic Effect on DNA Nucleotide Excision Repair in Veterans with Gulf War Illness | DNA nucleotide excision repair capacity | Total gene expression and nucleotide excision repair differed between GWI and controls. | Yes
OTHER
Janulewicz, 2019^158^ | The Gut-Microbiome in Gulf War Veterans: A Preliminary Report | Gut microbiome patterns | GW controls had more but firmicutes and the GWI plus gastrointestinal symptoms had more phyla bacteroidetes, actinobacteria, euryarchaeota, and proteobacteria, and Bacteroidaceae, Erysipelotrichaceae, and Bifidobacteriaceae. GWI plus gastrointestinal symptoms also showed greater plasma levels of the inflammatory cytokine TNF-RI. | Yes

* Yes=Indication by statistical significance of association of a biological measure with GWI case status; No=No indication by statistical significance of association of a biological measure with GWI case status.

Abbreviations: DNA=Deoxyribonucleic Acid, GWI=Gulf War Illness; TNF-RI=Tumor Necrosis Factor-Receptor 1