# APPENDIX C QUALITY ASSESSMENT

Table 9 Quality Assessment of Studies of Biological Measures for Gulf War Illness

Study | Assessment Criteria^*^
Study | #1 | #2 | #3 | #4 | #5 | #6 | #7 | #8 | #9 | #10 | #11
Amin, 2011^48^ | a (1) | b (0) | a (1) | a (1) | c (0) | a (1) | a (1) | a (1) | b (0) | c (0) | a (1)
Asa, 2000^23^ | a (1) | b (0) | a (1) | a (1) | c (0) | d (0) | a (1) | b (0) | d (0) | c (0) | b (0)
Blanchard, 2019^42^ | a (1) | d (0) | a (1) | a (1) | a (1) | a (1) | a (1) | a (1) | d (0) | d (0) | b (0)
Butterick, 2019^28^ | a (1) | d (0) | a (1) | a (1) | c (0) | d (0) | a (1) | a (1) | d (0) | c (0) | b (0)
Calley, 2010^32^ | b (0) | b (0) | a (1) | a (1) | c (0) | a (1) | a (1) | b (0) | c (0) | c (0) | b (0)
Cooper, 2016^33^ | b (0) | b (0) | a (1) | b (0) | c (0) | a (1) | a (1) | b (0) | c (0) | c (0) | a (1)
Davis, 2000^43^ | b (0) | b (0) | a (1) | a (1) | c (0) | a (1) | a (1) | d (0) | d (0) | c (0) | a (1)
Emmerich, 2017^24^ | a (1) | d (0) | a (1) | a (1) | c (0) | a (1) | a (1) | a (1) | a (1) | c (0) | a (1)
Georgopoulos, 2016^25^ | d (0) | d (0) | a (1) | a (1) | c (0) | a (1) | a (1) | a (1) | d (0) | c (0) | b (0)
Gopinath, 2012^34^ | a (1) | b (0) | a (1) | a (1) | c (0) | a (1) | a (1) | b (0) | a (1) | c (0) | a (1)
Haines, 2017^21^ | b (0) | a (1) | a (1) | a (1) | c (0) | d (0) | a (1) | b (0) | c (0) | c (0) | b (0)
Haley, 2013^44^ | b (0) | a (1) | a (1) | a (1) | c (0) | a (1) | a (1) | a (1) | a (1) | c (0) | a (1)
Hotopf, 2003^47^ | b (0) | a (1) | b (0) | a (1) | a (0) | a (1) | a (1) | a (1) | d (0) | b (0) | a (1)
James, 2016^27^ | a (1) | a (1) | a (1) | a (1) | c (0) | b (1) | a (1) | a (1) | c (0) | c (0) | b (0)
Johnson, 2013^26^ | a (1) | b (0) | a (1) | a (1) | c (0) | d (0) | a (1) | a (1) | d (0) | c (0) | b (0)
Johnson, 2016^29^ | a (1) | b (0) | a (1) | a (1) | c (0) | c (0) | a (1) | a (1) | b (0) | c (0) | b (0)
Li, 2014^45^ | b (0) | b (0) | a (1) | a (1) | c (0) | c (0) | a (1) | a (1) | a (1) | b (0) | b (0)
Liu, 2011^35^ | a (1) | b (0) | a (1) | b (0) | c (0) | a (1) | a (1) | b (0) | a (1) | c (0) | b (0)
Lo, 2000^22^ | b (0) | a (1) | b (0) | a (1) | c (0) | a (1) | a (1) | b (0) | c (0) | c (0) | a (1)
Nagelkirk, 2003^46^ | a (1) | d (0) | a (1) | b (0) | c (0) | b (1) | a (1) | b (0) | d (0) | c (0) | a (1)
Odegard, 2013^36^ | b (0) | b (0) | a (1) | b (0) | c (0) | a (1) | a (1) | a (1) | d (0) | c (0) | b (0)
Phillips, 2009^30^ | a (1) | b (0) | a (1) | b (0) | c (0) | b (1) | a (1) | b (0) | c (0) | c (0) | a (1)
Roland, 2000^49^ | b (0) | b (0) | a (1) | b (0) | c (0) | a (1) | a (1) | a (1) | d (0) | c (0) | b (0)
Sharief, 2002^50^ | b (0) | a (1) | a (1) | a (1) | c (0) | c (0) | a (1) | a (1) | a (1) | b (0) | a (1)
Skowera, 2004^31^ | b (0) | a (1) | a (1) | a (1) | c (0) | a (1) | a (1) | a (1) | d (0) | a (1) | a (1)
Tillman, 2010^37^ | b (0) | d (0) | a (1) | a (1) | c (0) | a (1) | a (1) | b (0) | d (0) | c (0) | b (0)
Tillman, 2012^38^ | b (0) | b (0) | a (1) | a (1) | c (0) | d (0) | a (1) | a (1) | a (1) | c (0) | b (0)
Tillman, 2013^39^ | b (0) | d (0) | a (1) | b (0) | c (0) | a (1) | a (1) | b (0) | d (0) | c (0) | b (0)
Tillman, 2019^40^ | b (0) | a (1) | a (1) | a (1) | c (0) | d (0) | a (1) | a (1) | a (1) | c (0) | b (0)
Wallace, 1999^51^ | a (1) | d (0) | a (1) | a (1) | c (0) | a (1) | a (1) | b (0) | b (0) | c (0) | a (1)
Weiner, 2011^41^ | a (1) | d (0) | a (1) | a (1) | c (0) | b (1) | a (1) | a (1) | d (0) | c (0) | b (0)
Zhou, 2018^52^ | b (0) | b (0) | a (1) | a (1) | c (0) | b (1) | a (1) | b (0) | d (0) | c (0) | b (0)

* Quality Assessment Criteria (adapted from Newcastle-Ottawa^19^ and BIOCROSS^20^):

1. Is the case definition adequate?
  a. Yes: CDC or Kansas definition (+1)
  b. All other definitions (0)
2. Representativeness of cases and controls:
  a. Truly representative of the population of both GWI+ and GWI− Veterans (ie, total pop[census] or random sampling) (+1)
  b. Non-random selection of either GWI+ or GWI− subjects (0)
  c. No description of the sampling strategy (0)
3. Selection of controls: Were D-GWVs controls selected or recruited from the same population as cases (including the same time period)?
  a. Yes (+1)
  b. No (0)
4. Were inclusion and exclusion criteria for being in the study prespecified and applied uniformly to all participants?
  a. Yes (+1)
  b. No/unclear (0)
5. Sample size/power calculation:
  a. Reported having conducted a power analysis, and then used an appropriate sample size based on that analysis (+1)
  b. Reported having conducted a power analysis, but were not able to/did not use an appropriate sample size (0)
  c. Did not report having conducted a power analysis (0)
6. Comparability of cases and controls on the basis of the design or analysis:
  a. Study controls for important confounders like demographics (age, gender, comorbidity, etc) through matching participants or statistical adjustment (+1)
  b. Did not match by age or gender, nor adjust for confounders in analysis, but demographic analysis found no statistically significant differences on these variables (+1).
  c. There were significant descriptive differences that were not adjusted for (0)
  d. No matching and/or demographics not reported (0)
7. Were the biological measure measurements (independent variables) clearly defined, valid, reliable, and implemented consistently across all study participants?
  a. Yes (+1)
  b. No (0)
8. Biological measure data modeling: Was the distribution of biological measure data reported (if non-normal were statistical approaches used to standardize it)? Were methods of outlier detection and handling used? Were any possible errors resulting from measurement inaccuracies discussed?
  a. Any of the above were addressed (+1)
  b. Unclear/did not report (0)
  c. Reported but inadequate (0)
9. If there were multiple comparisons, did they adjust appropriately (eg, Bonferroni)?
  a. Yes (1)
  b. No (0)
  c. N/A (no penalty, 0)
  d. Not reported (0)
10. Non-Response rate (for enrollment):
  a. Same rate for both groups, or rate differs but is weighted statistically (+1)
  b. Unequal response rate, non-respondents are described (with no statistical adjustment) (0)
  c. Unclear/not reported (0)
11. Blinding: Were the assessors of the outcome measurement (biological measure) blinded to the (case or control) status of participants?
  a. Yes (+1)
  b. No/not reported (0)